# RdRp enzymatic activity

Target Category | Viral replication
Target | SARS-CoV-2 RNA-dependent RNA-polymerase activity
Assay Type | Biochemical
Cell Line | N/A
Detection Type | Fluorescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

## Assay Overview

SARS-CoV-2 is a positive-sense single stranded RNA virus. Viral genome replication is mediated by the viral replication complex, which includes an RNA-dependent RNA polymerase (RdRp), helicase, exonucleaseN, and other accessory proteins. As replication from an RNA template does not normally occur within eukaryotic cells, this divergent, essential process is often targeted for inhibiting viral replication. Nucleoside analogues represent a class of antiviral agents that has proven efficacious against several viruses, including hepatitis B and C as well as HIV. Generally, these fall into three general classes: mutagenic nucleosides, obligate chain terminators, or delayed chain terminators. Evidence supports that remdesivir, which has shown efficacy in treating SARS-CoV-2 infected patients, acts though a delayed chain termination mechanism. The purpose of this biochemical assay is to identify novel compounds that inhibit SARS-CoV-2 RdRP enzyme activity using fluorescent labeled substrates.

## Protocol

Under development

## Normalization/Assay interpretation

Under development