# Human fibroblast toxicity

Target Category | Counterscreen
Target | N/A
Assay Type | Cell viability
Cell Line | Hh-Wt
Detection Type | Luminescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

## Assay Overview

Cell viability screen to assess general human cell toxicity of compounds, measuring host cell ATP content as a readout for cytotoxicity.

## Protocol

1 Dispense 5 μL of Hh-WT fibroblast cells, density of 1,000 cells per well in culture medium into 1536-well plates (Greiner, white, solid bottom, tissue culture treated) using a Multidrop Combi dispenser (Thermo Fisher)Note: Cells cultured in MEMalpha (ThermoFisher Scientific) supplemented with 15% FBS (Hyclone, GE Healthcare) and 1% Pen/Strep (100 U/mL penicillin and 100 μg/mL streptomycin; ThermoFisher Scientific).
2 Incubate at 37°C, 5% CO_2_, under a humidified atmosphere for 5 hr.
3 Transfer 23 nL library compounds in DMSO into assay plate using an automated pintool workstation (Kalypsys). Bortezomib dispensed to columns 1 and 2 (final concentration 2.3 μM), DMSO dispensed to columns 3 and 4.
4 Incubate at 37°C, 5% CO_2_, under a humidified atmosphere for 5 hr.
5 Dispense 3 μL CellTiter-Glo reagent (Promega) with Multidrop dispenser.
6 Incubate 15 min at room temperature.
7 Read on ViewLux plate reader, 1 sec exposure (PerkinElmer).

## Normalization/Assay interpretation

Data was normalized plate-wise to corresponding intra-plate controls (high-signal negative control DMSO and low-signal positive control Bortezomib). A high signal, approaching zero on a normalized plot, indicates no cell death. A low signal, (approaching -100 on a normalized plot), would be equivalent to cell death, similar to that elicited by the Bortezomib control.