# HEK293 cell line toxicity

Target Category | Counterscreen
Target | N/A
Assay Type | Cell viability
Cell Line | HEK293
Detection Type | Luminescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened – Not Available

## Assay Overview

Cell viability screen to assess general human cell toxicity of compounds, measuring host cell ATP content as a readout for cytotoxicity.

## Protocol

1 Dispense 5 μL HEK293 cells, density of 250 cells per well in culture medium into 1536-well plates (Greiner, white, solid bottom, tissue culture treated) using a Multidrop Combi dispenser (Thermo Fisher); skip columns 1 and 2 which were dispensed 2 μL medium only.Note: Cells cultured in Dulbecco's Modified Eagle Medium (DMEM; ThermoFisher Scientific) supplemented with 10% fetal bovine serum (FBS; HyClone), 100 U/ml penicillin and 100 μg/ml streptomycin (ThermoFisher Scientific).
2 Transfer 23 nL library compounds in DMSO into assay plate using an automated pintool workstation (Kalypsys). DMSO dispensed to columns 3 and 4.
3 Incubate at 37°C, 5% CO_2_ and 85% humidity.
4 Dispense 2.5 μL CellTiter-Glo reagent (Promega) with Multidrop dispenser
5 Incubate 10-15 min at room temperature
6 Read on ViewLux plate reader, 1 sec exposure (PerkinElmer).

## Normalization/Assay interpretation

Data was normalized plate-wise to corresponding intra-plate controls (high-signal negative control DMSO and low-signal positive control, wells without cell inoculation). A high signal, approaching zero on a normalized plot, indicates no cell death. A low signal, (approaching -100 on a normalized plot), would be equivalent to cell death, similar to that elicited no cell inoculated wells.