# Combination Screening Background

NCATS’s matrix combination screening platform (https://ncats.nih.gov/matrix/about) can rapidly test the effect of different drug combinations on cellular, molecular or biochemical processes that are relevant to a disease of interest, including COVID-19. To better elucidate the dose-dependent activities in two-dimensional space, we have developed a state-of-the-art, high-throughput drug combination screening system in 6x6 or 10x10 dose matrix format using a highly integrated robotics system and custom data analysis software.

## Dataset 1: Discovery of synergistic and antagonistic drug combinations against SARS-CoV-2 in vitro

VIEW DATA (https://tripod.nih.gov/matrix-client/?project=2961)

Cell Line: | Vero E6
Detection Type: | Luminescence
No. Unique Combinations: | 73
Date Screened: | 6/4/20

### Description:

SARS-CoV-2 cytopathic effect in 6x6 dose matrix

SARS-CoV-2 cytopathic effect (host tox counterscreen) in 6x6 dose matrix

### Associated Counterscreens:

SARS-CoV-2 cytopathic effect (host tox counterscreen) in 6x6 dose matrix (https://opendata.ncats.nih.gov/covid19/assay?aid=14)

### Normalization:

CPE assay data was normalized using host cell viability under vehicle treatment (DMSO) in the presence/absence of SARS-CoV-2 virus, so that 100 = DMSO + virus (high cell killing/no rescue of CPE) and 0 = DMSO - virus (no cell killing/complete rescue of CPE). CPEcytoxcicity counterscreen assay data was normalized using host cell viability under vehicle treatment (DMSO) or cell-free controls, so that 100 = cells + DMSO (no cell killing) and 0 = no cells (complete cell killing).

### Highlights:

We identified 16 synergistic and 8 antagonistic combinations, 4 of which were both synergistic and antagonistic in a dose-dependent manner. Particularly, undesirable antagonism between remdesivir and lyososomotropic agents, such as hydroxychloroquine, amodiaquine, mefloquine was found in vitro. Meanwhile, several promising synergistic combinations were discovered (e.g. nitazoxanide + remdesivir).

### Collaborators:

Eugene Muratov (The University of North Carolina at Chapel Hill)

### Associated Publications:

https://www.biorxiv.org/content/10.1101/2020.06.29.178889v1

## Dataset 2: In vitro SARS-CoV-2 evaluation of drug combinations for exploring chemical biology and potential therapeutic use

VIEW DATA (https://tripod.nih.gov/matrix-client/?project=2983)

Cell Line: | Vero E6
Detection Type: | Luminescence
No. Unique Combinations: | 95
Date Screened: | 6/15/20

### Description:

SARS-CoV-2 cytopathic effect in 6x6 dose matrix

SARS-CoV-2 cytopathic effect (host tox counterscreen) in 6x6 dose matrix

### Associated Counterscreens:

SARS-CoV-2 cytopathic effect (host tox counterscreen) in 6x6 dose matrix (https://opendata.ncats.nih.gov/covid19/assay?aid=14)

### Normalization:

CPE assay data was normalized using host cell viability under vehicle treatment (DMSO) in the presence/absence of SARS-CoV-2 virus, so that 100 = DMSO + virus (high cell killing/no rescue of CPE) and 0 = DMSO - virus (no cell killing/complete rescue of CPE). CPEcytoxcicity counterscreen assay data was normalized using host cell viability under vehicle treatment (DMSO) or cell-free controls, so that 100 = cells + DMSO (no cell killing) and 0 = no cells (complete cell killing).

### Highlights:

Preliminary result (N = 1). Confirmatory screen is ongoing

### Collaborators:

NCATS

### Associated Publications:

N/A