# ACE2 enzymatic activity

Target Category | Viral Entry
Target | Human ACE2 receptor protein
Assay Type | Biochemical
Cell Line | N/A
Detection Type | Fluorescence
Date Screened | N/A
Throughput | 1536-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened

## Assay Overview

Surface ACE2 receptor protein has been shown to be the primary host factor recognized and targeted by SARS-CoV-2 virions. This binding event between SARS-CoV-2 Spike protein and host ACE2 initiates binding of the viral capsid and eventually leads to viral entry into host cells. The primary function of ACE2 is to act as a counter-balance to ACE, which cleaves angiotensin I hormone into the vasoconstricting angiotensin II. ACE2 in turn cleaves the carboxyl-terminal amino acid phenylalanine from angiotensin II and hydrolyzes it into the vasodilator angiotensin 1-7. Though disruption of this Spike:ACE2 interaction may inhibit SARS-CoV-2 entry, off-target effects on endogenous ACE2 function could result in disruption of critical vasodilation pathways. This ACE2 enzymatic assay serves to measure inhibition of human ACE2 to identify compounds with the potential to disrupt endogenous enzyme function.

## Protocol

1 Compounds, DMSO (neutral control) and MLN-4760 (positive control) solutions (25 nL) were transferred to the 1536-well assay plate (Greiner, solid black medium-binding plates) using Echo 650 (Labcyte Inc.) acoustic dispenser.
2 Three μL/well of 0.27 nM ACE2 (0.2 nM final concentration) suspension in assay buffer (PBS, pH 7.4, 0.01% Tween-20) or assay buffer was dispensed into assay plate with Aurora Discovery BioRAPTR Dispenser (FRD; Beckton Dickenson) and incubated 15 min at room temperature (RT).
3 One μL/well of 60 μM ACE2 substrate (15 μM final concentration) in assay buffer was then added yielding a total reaction volume of 4 μL/well.
4 Plate was centrifuged at 1000 rpm for 15 sec.
5 Fluorescence was detected with the PHERAstar plate reader (BMG Labtech) equipped with Module 340/440 at t1=0 min and t2=15 min at RT.

Reagents:

1 Recombinant human ACE2 protein (Cat#: 933-ZN-010, R&D Systems or Cat#: 10108-H08H, Sino Biological)
2 ACE2 substrate (Cat #: AS-60757, AnaSpec)
3 ACE2 inhibitor – MLN-4760 (CAS #: 305335-31-3, Cat #: 5306160001, Sigma-Aldrich)

## Normalization/Assay interpretation

Data was normalized to enzyme activity in presence of DMSO, set as 0%, and in presence of 6.2 µM MLN-4760, set as -100% inhibition. MLN-4760 is a known ACE2 inhibitor with IC50 of 0.4 nM. The resulting percent of inhibition data were fitted to a sigmoidal dose response curve using four-parameter Hill equation.