# ACE2 binding

Target Category | Viral Entry
Target | Human ACE2 receptor protein
Assay Type | Biophysical
Cell Line | N/A
Detection Type | Microscale thermophoresis
Date Screened | N/A
Throughput | 384-well
Status | Screening complete

Download Assay Protocol

Export Screening Data

Libraries Screened – Not Available

## Assay Overview

Surface ACE2 receptor protein has been shown to be the primary host factor recognized and targeted by SARS-CoV-2 virions. This binding event between SARS-CoV-2 spike protein and host ACE2 initiates binding of the viral capsid and eventually leads to viral entry in host cells. This ACE2 microscale thermophoresis (MST) assay serves for discovery of ACE2 small molecule binders, which could eventually interfere binding of SARS-CoV-2 to host cells.

## Protocol

1. His-tagged recombinant human ACE2 protein was labeled with RED-tris-NTA 2^nd^ generation dye (Nanotemper Technologies GmbH, Cat #: MO-L018) following manufacturers’ protocol. In brief, 150 μL of 200 nM ACE2 in PBS-T (PBS, pH 7.4, 0.005% Tween-20) was incubated with 150 μL of 100 nM dye in PBS-T for 30 min at room temperature (RT). After a centrifugation for 10 min at 15,000 x g, 4°C labeled ACE2 was diluted in PBS-T to a final concentration of 2 nM.

2. 200 nL of library compounds, 500μM MLN-4760 as positive control and DMSO as reference were transferred to 384-well compound plate (Greiner, Cat #: 784201-1B) using Echo 650 series acoustic dispenser (Labcyte Inc.).

3. 10 μL of labeled ACE2 was transferred to each well, mixed with compounds and incubated for 15 min at RT.

4. MST traces were collected using Monolith NT.Automated (Nanotemper Technologies GmbH) unit and standard treated capillary chip (Cat #: MO AK002, Nanotemper Technologies GmbH) with following setting: 45% excitation power, medium MST power and MST periods of 3s/10s/1s.

Reagents:

1. Recombinant human ACE2 protein (Cat #: 10108-H08H, Sino Biological)

2. RED-tris-NTA 2^nd^ generation dye(Cat #: MO-L018, Nanotemper Technologies)

3. ACE2 inhibitor – MLN-4760 (MilliporeSigma, Cat #: 5306160001)

## Normalization/Assay interpretation

Data was analyzed with MO.Screening Analysis software (Nanotemper Technologies GmbH). The area of insignificant (delta)Fnorm corresponds to three standard deviations from the signal recorded from all DMSO references. Compounds with signals that fall within this area are categorized as non-binders. The positive control MLN-4760 is used as quality check for signal amplitude variability throughout the single-dose screen. The analysis software has integrated quality check based on the fluorescence signal of each sample and can automatically identify compounds with autofluorescence and aggregation.