# Science Brief: SARS-CoV-2 and Surface (Fomite) Transmission for Indoor Community Environments

The principal mode by which people are infected with SARS-CoV-2 (the virus that causes COVID-19) is through exposure to respiratory droplets carrying infectious virus. It is possible for people to be infected through contact with contaminated surfaces or objects (fomites), but the risk is generally considered to be low.

## Background

SARS-CoV-2, the virus that causes COVID-19, is an enveloped virus, meaning that its genetic material is packed inside an outer layer (envelope) of proteins and lipids. The envelope contains structures (spike proteins) for attaching to human cells during infection. The envelope for SARS-CoV-2, as with other enveloped respiratory viruses, is labile and can degrade quickly upon contact with surfactants contained in cleaning agents and under environmental conditions. The risk of fomite-mediated transmission is dependent on:

- The infection prevalence rate in the community
- The amount of virus infected people expel (which can be substantially reduced by wearing masks)
- The deposition of expelled virus particles onto surfaces (fomites), which is affected by air flow and [underlined: ventilation] (https://www.cdc.gov/coronavirus/2019-ncov/community/ventilation.html)
- The interaction with environmental factors (e.g., heat and evaporation) causing damage to virus particles while airborne and on fomites
- The time between when a surface becomes contaminated and when a person touches the surface
- The efficiency of transference of virus particles from fomite surfaces to hands and from hands to mucous membranes on the face (nose, mouth, eyes)
- The dose of virus needed to cause infection through the mucous membrane route

Because of the many factors affecting the efficiency of environmental transmission, the relative risk of fomite transmission of SARS-CoV-2 is considered low compared with direct contact, droplet transmission, or airborne transmission ^[1, 2]^. However, it is not clear what proportion of SARS-CoV-2 infections are acquired through surface transmission. There have been few reports of COVID-19 cases potentially attributed to fomite transmission [1, 2]. Infections can often be attributed to multiple transmission pathways. Fomite transmission is difficult to prove definitively, in part because respiratory transmission from asymptomatic people cannot be ruled out [3, 4, 5]. Case reports indicate that SARS-CoV-2 is transmitted between people by touching surfaces an ill person has recently coughed or sneezed on, and then directly touching the mouth, nose, or eyes ^[3, 4, 5]^. Hand hygiene is a barrier to fomite transmission and has been associated with lower risk of infection ^[6]^.

Quantitative microbial risk assessment (QMRA) studies have been conducted to understand and characterize the relative risk of SARS-CoV-2 fomite transmission and evaluate the need for and effectiveness of prevention measures to reduce risk. Findings of these studies suggest that the risk of SARS-CoV-2 infection via the fomite transmission route is low, and generally less than 1 in 10,000, which means that each contact with a contaminated surface has less than a 1 in 10,000 chance of causing an infection ^[7, 8, 9]^. Some studies estimated exposure risks primarily using outdoor environmental SARS-CoV-2 RNA quantification data. They noted that their QMRA estimates are subject to uncertainty that can be reduced with additional data to improve the accuracy and precision of information that is entered into the models. Concentrations of infectious SARS-CoV-2 on outdoor surfaces could be expected to be lower than indoor surfaces because of air dilution and movement, as well as harsher environmental conditions, such as sunlight. One QMRA study also evaluated the effectiveness of prevention measures that reduce the risk of fomite transmission and found that hand hygiene could substantially reduce the risk of SARS-CoV-2 transmission from contaminated surfaces, while surface disinfection once- or twice-per-day had little impact on reducing estimated risks ^[9]^.

## Surface survival

Numerous researchers have studied how long SARS-CoV-2 can survive on a variety of porous and non-porous surfaces ^[10, 11, 12, 13, 14, 15]^. On porous surfaces, studies report inability to detect viable virus within minutes to hours; on non-porous surfaces, viable virus can be detected for days to weeks. The apparent, relatively faster inactivation of SARS-CoV-2 on porous compared with non-porous surfaces might be attributable to capillary action within pores and faster aerosol droplet evaporation ^[16]^.

Data from surface survival studies indicate that a 99% reduction in infectious SARS-CoV-2 and other coronaviruses can be expected under typical indoor environmental conditions within 3 days (72 hours) on common non-porous surfaces like stainless steel, plastic, and glass ^[10, 11, 12, 13, 15]^. However, experimental conditions on both porous and non-porous surfaces do not necessarily reflect real-world conditions, such as initial virus amount (e.g., viral load in respiratory droplets) and factors that can remove or degrade the virus, such as ventilation and changing environmental conditions ^[8, 9]^. They also do not account for inefficiencies in transfer of the virus between surfaces to hands and from hands to mouth, nose, and eyes ^[8, 9]^. In fact, laboratory studies try to optimize the recovery of viruses from surfaces (e.g., purposefully swabbing the surface multiple times or soaking the contaminated surface in viral transport medium before swabbing). When accounting for both surface survival data and real-world transmission factors, the risk of fomite transmission after a person with COVID-19 has been in an indoor space is minor after 3 days (72 hours), regardless of when it was last cleaned ^[8, 9, 10, 11, 12, 13, 15]^.

## Effectiveness of cleaning and disinfection

Both cleaning (use of soap or detergent) and disinfection (use of a product or process designed to inactivate SARS-CoV-2) can reduce the risk of fomite transmission. Cleaning reduces the amount of soil (e.g., dirt, microbes and other organic agents, and chemicals) on surfaces, but efficacy varies by the type of cleaner used, cleaning procedure, and how well the cleaning is performed. No reported studies have investigated the efficacy of surface cleaning (with soap or detergent not containing a [underlined: registered disinfectant] (https://www.epa.gov/pesticide-registration/list-n-disinfectants-coronavirus-covid-19)) for reducing concentrations of SARS-CoV-2 on non-porous surfaces. From studies of cleaning focused on other microbes, a 90–99.9% reduction of microbe levels could be possible depending on the cleaning method and the surface being cleaned ^[17, 18]^. In addition to physical removal of SARS-CoV-2 and other microbes, surface cleaning can be expected to degrade the virus. Surfactants in cleaners can disrupt and damage the membrane of an enveloped virus like SARS-CoV-2 ^[19, 20, 21]^.

To substantially inactivate SARS-CoV-2 on surfaces, the surface must be treated with a [underlined: disinfectant product] (https://www.epa.gov/pesticide-registration/list-n-disinfectants-coronavirus-covid-19) registered with the Environmental Protection Agency’s (EPA’s) [underlined: List N] (https://www.epa.gov/pesticide-registration/list-n-disinfectants-coronavirus-covid-19) or technology that has been shown to be effective against the virus ^[22]^. Disinfectant products might also contain cleaning agents, so they are designed to clean by both removing soil and inactivating microbes. Cleaners and disinfectants [underlined: should be used safely,] (https://www.cdc.gov/coronavirus/2019-ncov/community/disinfecting-building-facility.html) following the manufacturer guidance. There have been increases in poisonings and injuries from unsafe use of cleaners and disinfectants since the start of the COVID-19 pandemic ^[23]^. Some types of disinfection applications, particularly those including fogging or misting, are neither safe nor effective for inactivating the virus unless properly used ^[24]^.

Surface disinfection has been shown to be effective for preventing secondary transmission of SARS-CoV-2 between an infected person and other people within households ^[25]^. However, there is little scientific support for routine use of disinfectants in community settings, whether indoor or outdoor, to prevent SARS-CoV-2 transmission from fomites. In public spaces and community settings, available epidemiological data and QMRA studies indicate that the risk of SARS-CoV-2 transmission from fomites is low—compared with risks from direct contact, droplet transmission or airborne transmission ^[8, 9]^. Routine cleaning performed effectively with soap or detergent, at least once per day, can substantially reduce virus levels on surfaces. When focused on high-touch surfaces, cleaning with soap or detergent should be enough to further reduce the relatively low transmission risk from fomites in situations when there has not been a suspected or confirmed case of COVID-19 indoors. In situations when there has been a suspected or confirmed case of COVID-19 indoors within the last 24 hours, the presence of infectious virus on surfaces is more likely and therefore high-touch surfaces should be disinfected ^[26]^.

## Response to a case in an indoor environment

When a person with suspected or confirmed COVID-19 has been indoors, virus can remain suspended in the air for minutes to hours. The length of time virus remains suspended and is infectious depends on numerous factors, including viral load in respiratory droplets or in small particles, disturbance of air and surfaces, ventilation, temperature, and humidity ^[27, 28, 29, 30, 31]^. Wearing masks consistently and correctly can substantially reduce the amount of virus indoors, including the amount of virus that lands on surfaces ^[32]^.

Based on limited epidemiologic and experimental data, the risk of infection from entering a space where a person with COVID-19 has been is low after 24 hours. During the first 24 hours, the risk can be reduced by [underlined: increasing ventilation] (https://www.cdc.gov/coronavirus/2019-ncov/community/ventilation.html) and waiting as long as possible before entering the space (at least several hours, based on documented airborne transmission cases), and using personal protective equipment (including any protection needed for the cleaning and disinfection products) to reduce risk. [underlined: Certain techniques] (https://www.cdc.gov/coronavirus/2019-ncov/prevent-getting-sick/mask-fit-and-filtration.html) can improve the fit and filtration effectiveness of masks ^[32]^.

After a person with suspected or confirmed COVID-19 has been in an indoor space, the risk of fomite transmission from any surfaces is minor after 3 days (72 hours). Researchers have found that 99% reduction in infectious SARS-CoV-2 on non-porous surfaces can occur within 3 days ^[8, 9, 10, 11, 12, 13]^. In indoor settings, risks can be reduced by wearing masks (which reduces droplets that can be deposited on surfaces), routine cleaning, and consistent hand hygiene.

## Conclusion

People can be infected with SARS-CoV-2 through contact with surfaces. However, based on available epidemiological data and studies of environmental transmission factors, surface transmission is not the main route by which SARS-CoV-2 spreads, and the risk is considered to be low. The principal mode by which people are infected with SARS-CoV-2 is through exposure to respiratory droplets carrying infectious virus. In most situations, cleaning surfaces using soap or detergent, and not disinfecting, is enough to reduce risk. Disinfection is recommended in indoor community settings where there has been a suspected or confirmed case of COVID-19 within the last 24 hours. The risk of fomite transmission can be reduced by wearing masks consistently and correctly, practicing hand hygiene, cleaning, and taking other measures to maintain healthy facilities.

## References

1 Meyerowitz E. A., Richterman A., Gandhi R. T., Sax P. E. (2020). Transmission of SARS-CoV-2: a review of viral, host, and environmental factors. Annals of internal medicine.
2 Kampf G., Brüggemann Y., Kaba H., Steinmann J., Pfaender S., Scheithauer S., Steinmann E. (2020). Potential sources, modes of transmission and effectiveness of prevention measures against SARS-CoV-2. Journal of Hospital Infection.
3 Bae S., Shin H., Koo H., Lee S., Yang J. (2020). Emerg Infect Dis.
4 Cai J., Sun W., Huang J., Gamber M., Wu J., He G. (2020). Indirect virus transmission in cluster of COVID-19 cases, Wenzhou, China, 2020. Emerging infectious diseases.
5 Xie C., Zhao H., Li K., Zhang Z., Lu X., Peng H., Wang D., Chen J., Zhang X., Wu D., Gu Y., Yuan J., Zhang L., Lu J. (2020). The evidence of indirect transmission of SARS-CoV-2 reported in Guangzhou, China. BMC Public Health.
6 Doung-Ngern P., Suphanchaimat R., Panjangampatthana A., Janekrongtham C., Ruampoom D., Daochaeng N., Eungkanit N., Pisitpayat N., Srisong N., Yasopa O., Plernprom P., Promduangsi P., Kumphon P., Suangtho P., Watakulsin P., Chaiya S., Kripattanapong S., Chantian T., Bloss E. (2020). Case-Control Study of Use of Personal Protective Measures and Risk for SARS-CoV 2 Infection, Thailand. Emerging Infectious Diseases.
7 A. M. Wilson, M. H. Weir, S. F. Bloomfield, E. A. Scott and K. A. Reynold, “Modeling COVID-19 infection risks for a single hand-to-fomite scenario and potential risk reductions offered by surface disinfection,” American Journal of Infection Control, vol. Article In Press, pp. 1-3, 2020.
8 Harvey A. P., Fuhrmeister E. R., Cantrell M. E., Pitol A. K. (2020). S. J. M, J. E. Powers, M. L. Nadimpalli, T. R. Julian and A. J. Pickering, “Longitudinal monitoring of SARS-CoV-2 RNA on high-touch surfaces in a community setting. Environmental Science & Technology Letters.
9 Pitol A. K., Julian T. R. (2020). Community transmission of SARS-CoV-2 by fomites: Risks and risk reduction strategies. Environmental Science and Technology Letters.
10 Biryukov J., Boydston J. A., Dunning R. A. (2020). J. J. Yeager and e. al., “Increasing temperature and relative humidity accelerates inactivation of SARS-CoV-2 on surfaces. mSphere.
11 Chin A., Chu J., Perera M., Hui K., Yen H. L., Chan M., Peiris M., Poon L. (2020). Stability of SARS-CoV-2 in different environmental conditions. Lancet Microbe.
12 Kratzel A., Steiner S., Todt D., V’kovski P., Brueggemann Y., Steinmann J., Steinmann E., Thiel V., Pfaender S. (2020). Temperature-dependent surface stability of SARS-CoV-2. Journal of Infection.
13 Liu Y., Li T., Deng Y., Liu S., Zhang D., Li H., Wang X., Jia L., Han J., Bei Z., Li L. (2021). Stability of SARS-CoV-2 on environmental surfaces and in human excreta. Journal of Hospital Infection.
14 Riddell S., Goldie S., Hill A., Eagles D., Drew T. W. (2020). The effect of temperature on persistence of SARS-CoV-2 on common surfaces. Virology Journal.
15 van Doremalen N., Bushmaker T., Morris D. H., Holbrook M. G., Gamble A., Williamson B. N., Tamin A., Harcourt J. L., Thornburg N. J., Gerber S. I., Lloyd-Smith J. O. (2020). Aerosol and surface stability of SARS-CoV-2 as compared with SARS-CoV-1. New England Journal of Medicine.
16 S. Chatterjee, J. S. Murallidharan, A. Agrawal and R. and Bhardwaj, “Why coronavirus survives longer on impermeable than porous surfaces,” Physics of Fluids, vol. 33, 2021.
17 Delhalle L., Taminiau B., Fastrez S., Fall A., Ballesteros M., Burteau S., Daube G. (2020). Evaluation of Enzymatic Cleaning on Food Processing Installations and Food Products Bacterial Microflora. Frontiers in Microbiology.
18 Gibson H., Taylor J., Hall K., Holah J. (1999). Effectiveness of cleaning techniques used in the food industry in terms of the removal of bacterial biofilms. Journal of Food Protection.
19 Dehbandi R., Zazouli M. A. (2020). Stability of SARS-CoV-2 in different environmental conditions. The Lancet Microbe.
20 Jahromi R., Mogharab V., Jahromi H., Avazpour A. (2020). Synergistic effects of anionic surfactants on coronavirus (SARS-CoV-2) virucidal efficiency of sanitizing fluids to fight COVID-19. Food and Chemical Toxicology.
21 Gerlach M., Wolff S., Ludwig S., Schaefer W., Keiner B., Roth N. J., Widmer E. (2020). Rapid SARS-CoV-2 inactivation by commonly available chemicals on inanimate surfaces. Journal of Hospital Infection.
22 Environmental Protection Agency, “List N: Disinfectants for Coronavirus (COVID-19),” [Online]. Available: https://www.epa.gov/pesticide-registration/list-n-disinfectants-coronavirus-covid-19. [Accessed 12 February 2021].
23 Chang A., Schnall A. H., Law R., Bronstein A. C., Marraffa J. M., Spiller H. A., Hays H. L., Fun A. R., Mercurio-Zappala M., Calello D. P., Aleguas A., Borys D. J., Boehmer T., Svendsen E. (2020). Cleaning and Disinfectant Chemical Exposures and Temporal Associations with COVID-19 — National Poison Data System, United States, January 1, 2020–March 31, 2020. Morbidity and Mortality Weekly Report.
24 EPA, “Can I use fogging, fumigation, or electrostatic spraying or drones to help control COVID-19?,” 7 January 2021. [Online]. Available: https://www.epa.gov/coronavirus/can-i-use-fogging-fumigation-or-electrostatic-spraying-or-drones-help-control-covid-19. [Accessed 17 February 2021].
25 Wang Y., Tian H., Zhang L. (2020). M. Zhang and e. al., “Reduction of secondary transmission of SARS-CoV-2 in households by face mask use, disinfection and social distancing: a cohort study in Beijing, China. BMJ Global Health.
26 Santarpia J. L., Rivera D. N., Herrera V. L., Morwitzer M. J., Creager H. M., Santarpia G. W., Crown K. K., Brett-Major D. M., Schnaubelt E. R., Broadhurst M. J., Lawler J. V. (2020). Aerosol and surface contamination of SARS-CoV-2 observed in quarantine and isolation care. Scientific Reports.
27 Corsi R. L., Siegel J. A., Chiang C. (2008). Particle resuspension during the use of vacuum cleaners on residential carpet. Journal of Occupational and Environmental Hygiene.
28 Jones R. M., Brosseau L. M. (2015). Aerosol transmission of infectious disease. J Occup Environ Med.
29 Zheng S., Zhang J., Mou J., Du W., Yu Y., Wang L. (2019). The influence of relative humidity and ground material on indoor walking-induced particle resuspension. Journal of Environmental Science and Health.
30 Vejerano E. P., Marr L. C. (2018). Physico-chemical characteristics of evaporating respiratory fluid droplets. J. R. Soc. Interface.
31 Casanova L. M., Jeon S., Rutala W. A., Weber D. J., Sobsey M. D. (2010). Effects of air temperature and relative humidity on coronavirus survival on surfaces. Appl Environ Microbiol.
32 J. T. Brooks, D. H. Beezhold, J. D. Noti, C. J. P, R. C. Derk, F. M. Blachere and W. G. Lindsley, “Morbidity and Mortality Weekly Report,” Centers for Disease Control and Prevention, 10 February 2021. [Online]. Available: https://www.cdc.gov/mmwr/volumes/70/wr/mm7007e1.htm?s_cid=mm7007e1_w. [Accessed 12 February 2021].
33 Chan K. H., Peiris J. M., Lam S. Y., Poon L. L., Yuen K. Y., Seto W. H. (2011). The effects of temperature and relative humidity on the viability of the SARS coronavirus. Advances in Virology.
34 Duan S. M., Zhao X. S., Wen R. F., Huang J. J., Pi G. H., Zhang S. X., Han J., Bi S. L., Ruan L., Dong X. P. (2003). Stability of SARS coronavirus in human specimens and environment and its sensitivity to heating and UV irradiation. Biomed Environ Sci.
35 Lai M. Y., Cheng P. K., Lim W. W. (2005). Survival of severe acute respiratory syndrome coronavirus. Clinical Infectious Diseases.
36 Rabenau H. F., Cinatl J., Morgenstern B., Bauer G., Preiser W., Doerr H. W. (2005). Stability and inactivation of SARS coronavirus. Med Microbiol Immunol.