# Acknowledgements

I have had the opportunity to work with and learn from hundreds of people during my many years as a cancer epidemiologist. To thank everyone by name is impossible. Please know that I learn something from everyone with whom I speak, and that I am grateful to all who have approached me with questions as well as arguments.

Polly Newcomb was the first epidemiologist in my life. Without her support and encouragement at the beginning of my career, it is unlikely that I would have been afforded many opportunities, including the chance to learn about cancer screening in such detail. Many thanks go to my leaders at the National Cancer Institute; they gave me the time, support, and space to bring this primer to fruition. And thanks to my students and mentees: whether they believe it or not, I learn more from them than they learn from me.

Thanks also are due to the friends and colleagues who kept me on schedule, reviewed drafts of the primer, and provided invaluable input. Danielle Durham, John Gohagan, Beth Hoffman, Tony Miller, Phil Prorok, Amy Sayle, and Mark Schiffman were reviewers of a nearly complete draft. Jennifer Croswell, V. Paul Doria-Rose, Richard Fagerstrom, Beth Hoffman, and Robert Hoffman reviewed the complete draft. Rachel Eisenger-Baskin and Anne Julian assisted with reference formatting and copy editing. Stacy Lathrop and Diana Jordon of the National Library of Medicine supported me in this venture.

This primer is dedicated to the memories of Robert Craft Millikan and Seymour Marcus.