# References

1 National Institute of Diabetes and Digestive and Kidney Diseases. NIDDK Strategic Plan for Research. Dec. 2021. Available at: https://www.niddk.nih.gov/about-niddk/strategic-plans-reports/niddk-strategic-plan-for-research. Accessed July 2023.
2 Everhart JE. Overview. In: Everhart JE, ed. Digestive diseases in the United States: epidemiology and impact. Washington, DC: US Government Printing Office; NIH publication no. 94–1447, 1994:1–50.
3 Opportunities and challenges in digestive diseases research: recommendations of the National Commission on Digestive Diseases. NIH publication no. 08–6514, Mar. 2009. Available at: https://www.niddk.nih.gov/about-niddk/strategic-plans-reports/opportunities-challenges-digestive-diseases-research-recommendations-national-commission. Accessed July 2023.
4 Everhart JE, editor. The burden of digestive diseases in the United States. US Department of Health and Human Services, Public Health Service, National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases. Washington, DC: US Government Printing Office, 2008; NIH Publication No. 09–6443. https://www.niddk.nih.gov/about-niddk/strategic-plans-reports/burden-of-digestive-diseases-in-united-states. Accessed July 2023.
5 Everhart JE, Ruhl CE. Burden of digestive diseases in the United States part I: overall and upper gastrointestinal diseases. Gastroenterology 2009 Feb;136(2):376–86.19124023
6 Everhart JE, Ruhl CE. Burden of digestive diseases in the United States part II: lower gastrointestinal diseases. Gastroenterology 2009 Mar;136(3):741–54.19166855
7 Everhart JE, Ruhl CE. Burden of digestive diseases in the United States Part III: Liver, biliary tract, and pancreas. Gastroenterology 2009 Apr;136(4):1134–44.19245868