# Methods

Digestive disease morbidity was identified by an International Classification of Diseases (ICD), Tenth Revision, Clinical Modification (ICD-10-CM) codes and digestive disease mortality by ICD, Tenth Revision (ICD-10) codes (Appendix 1). The first-listed diagnosis was considered the primary diagnosis and all remaining diagnoses were considered secondary and included under ‘all-listed’. For national event-level data sources, diagnoses were counted only once under the all-listed category, irrespective of the number of actual diagnoses listed on a medical record or death certificate.

The National Ambulatory Medical Care Survey (NAMCS), Healthcare Cost and Utilization Project (HCUP) Nationwide Emergency Department Sample (NEDS), HCUP National Inpatient Sample (NIS), Vital Statistics of the U.S., Surveillance, Epidemiology, and End Results (SEER) Program, Optum Clinformatics^®^ Data Mart (CDM), and Centers for Medicare and Medicaid Services (CMS) Medicare 5% Sample databases were used to estimate medical care, mortality, years of potential life lost, cancer incidence, and claims-based prevalence with primary or other digestive disease diagnoses. These data sources are described in more detail in Appendix 2. Estimates for the total population and demographic groups were calculated for the most recent year of data available. Rates were age-adjusted (for national databases) and shown per 100,000 population. For national data sources, ambulatory care, emergency department, and hospital numbers and rates represent events, not persons with an event. Statistical methodology is described in more detail in Appendix 3.