# Chapter 9 Hemorrhoids

Table 109 Hemorrhoids: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 4 | 8
Age (years) | 12 to 24 | 81 | 144 | 112 | 200
Age (years) | 25 to 44 | 421 | 498 | 888 | 1,051
Age (years) | 45 to 54 | 546 | 1,267 | 1,079 | 2,505
Age (years) | 55 to 64 | 418 | 1,025 | 789 | 1,933
Age (years) | 65 to 74 | 306 | 1,111 | 660 | 2,397
Age (years) | 75 plus | 215 | 1,063 | 504 | 2,492
Race | White | 1,426 | 522 | 2,948 | 1,054
Race | Black | 200 | 452 | 619 | 1,392
Race | Other | 360 | 1,503 | 469 | 1,966
Ethnicity | Hispanic | 561 | 1,217 | 839 | 1,787
Ethnicity | Not Hispanic | 1,425 | 483 | 3,197 | 1,064
Sex | Female | 900 | 503 | 2,052 | 1,158
Sex | Male | 1,086 | 672 | 1,983 | 1,195
Total | | 1,986 | 584 | 4,036 | 1,176

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hemorrhoids contributed to 4.0 million ambulatory visits (2015) (Table 109). Ambulatory care visit rates (all-listed diagnoses) were similar among middle-aged and older adults. Age-adjusted rates were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 110 Hemorrhoids: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 2 | 2 | 4
Age (years) | 12 to 24 | 23 | 41 | 36 | 65
Age (years) | 25 to 44 | 77 | 89 | 140 | 161
Age (years) | 45 to 54 | 30 | 72 | 81 | 194
Age (years) | 55 to 64 | 22 | 52 | 94 | 221
Age (years) | 65 to 74 | 17 | 55 | 100 | 329
Age (years) | 75 plus | 23 | 106 | 149 | 681
Sex | Female | 91 | 53 | 316 | 166
Sex | Male | 102 | 64 | 287 | 170
Total | | 193 | 58 | 603 | 169

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hemorrhoids contributed to 603,000 emergency department visits in 2018 (Table 110). Emergency department visit rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among men compared with women.

Table 111 Hemorrhoids: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 1 | 1
Age (years) | 12 to 24 | 0 | 0 | 4 | 8
Age (years) | 25 to 44 | 4 | 4 | 35 | 40
Age (years) | 45 to 54 | 3 | 8 | 40 | 95
Age (years) | 55 to 64 | 4 | 10 | 65 | 153
Age (years) | 65 to 74 | 5 | 15 | 82 | 268
Age (years) | 75 plus | 9 | 40 | 121 | 552
Race | White | 19 | 6 | 270 | 86
Race | Black | 5 | 11 | 58 | 137
Race | Other | 2 | 9 | 24 | 97
Ethnicity | Hispanic | 3 | 8 | 40 | 96
Ethnicity | Not Hispanic | 22 | 7 | 311 | 92
Sex | Female | 13 | 6 | 184 | 89
Sex | Male | 12 | 7 | 163 | 93
Total | | 25 | 7 | 347 | 91

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hemorrhoids contributed to 347,000 hospital discharges in 2018 (Table 111). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by 12% from 104 to 91.(4,6)

Table 112 Hemorrhoids: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | . | . | . | . | . | .
Age (years) | 25 to 44 | 4 | 0.0 | 0.2 | 7 | 0.0 | 0.3
Age (years) | 45 to 54 | 1 | 0.0 | 0.0 | 5 | 0.0 | 0.1
Age (years) | 55 to 64 | 2 | 0.0 | 0.0 | 20 | 0.0 | 0.5
Age (years) | 65 to 74 | 6 | 0.0 | 0.1 | 18 | 0.1 | 0.3
Age (years) | 75 plus | 11 | 0.0 | 0.1 | 41 | 0.2 | 0.2
Race | White | 19 | 0.0 | 0.3 | 69 | 0.0 | 1.0
Race | Black | 2 | 0.0 | 0.0 | 12 | 0.0 | 0.2
Race | Other | 3 | 0.0 | 0.1 | 10 | 0.0 | 0.2
Ethnicity | Hispanic | 4 | 0.0 | 0.1 | 11 | 0.0 | 0.2
Ethnicity | Not Hispanic | 20 | 0.0 | 0.3 | 80 | 0.0 | 1.2
Sex | Female | 11 | 0.0 | 0.2 | 47 | 0.0 | 0.7
Sex | Male | 13 | 0.0 | 0.2 | 44 | 0.0 | 0.7
Total | | 24 | 0.0 | 0.4 | 91 | 0.0 | 1.4

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Hemorrhoids contributed to <1,000 deaths in 2019 (Table 112). Mortality from hemorrhoids was rare, but occasionally occurred among older adults. Between 2004 and 2019, mortality with hemorrhoids as underlying or other cause remained uncommon.(4)

Table 113 Hemorrhoids: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 188 | 0.0% | 545 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 2,079 | 0.1% | 4,756 | 0.3%
Age (years) | 25 to 44 | 2,656,672 | 14,761 | 0.6% | 36,906 | 1.4%
Age (years) | 45 to 54 | 1,452,320 | 9,720 | 0.7% | 50,138 | 3.5%
Age (years) | 55 to 64 | 1,640,216 | 10,428 | 0.6% | 70,544 | 4.3%
Age (years) | 65 to 74 | 2,840,615 | 16,936 | 0.6% | 130,407 | 4.6%
Age (years) | 75 plus | 2,576,241 | 13,195 | 0.5% | 76,797 | 3.0%
Race-ethnicity | White | 8,657,702 | 43,330 | 0.5% | 249,109 | 2.9%
Race-ethnicity | Black | 1,242,477 | 6,838 | 0.6% | 37,975 | 3.1%
Race-ethnicity | Hispanic | 1,493,457 | 8,416 | 0.6% | 42,185 | 2.8%
Race-ethnicity | Asian | 607,284 | 3,201 | 0.5% | 14,031 | 2.3%
Race-ethnicity | Unknown | 1,719,014 | 5,522 | 0.3% | 26,793 | 1.6%
Sex | Female | 7,199,363 | 35,481 | 0.5% | 199,197 | 2.8%
Sex | Male | 6,520,571 | 31,826 | 0.5% | 170,896 | 2.6%
Region | Northeast | 1,526,275 | 8,670 | 0.6% | 49,981 | 3.3%
Region | Midwest | 3,322,846 | 13,463 | 0.4% | 81,198 | 2.4%
Region | South | 5,619,435 | 29,700 | 0.5% | 160,730 | 2.9%
Region | West | 3,251,378 | 15,474 | 0.5% | 78,184 | 2.4%
Total | | 13,719,934 | 67,307 | 0.5% | 370,093 | 2.7%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of hemorrhoids (based on all-listed diagnoses) was 2.7% (Table 113). Prevalence increased with age until the oldest age group and was higher among women. It was highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. It was highest in the Northeast, followed by the South, and lowest in the Midwest and West.

Table 114 Hemorrhoids: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 210 | 19 | 622 | 56
Age (years) | 12 to 24 | 2,522 | 174 | 6,006 | 414
Age (years) | 25 to 44 | 20,127 | 758 | 50,760 | 1,911
Age (years) | 45 to 54 | 13,584 | 935 | 62,938 | 4,334
Age (years) | 55 to 64 | 14,470 | 882 | 85,964 | 5,241
Age (years) | 65 to 74 | 23,232 | 818 | 153,968 | 5,420
Age (years) | 75 plus | 17,528 | 680 | 91,249 | 3,542
Race-ethnicity | White | 59,473 | 687 | 299,544 | 3,460
Race-ethnicity | Black | 9,000 | 724 | 46,033 | 3,705
Race-ethnicity | Hispanic | 11,336 | 759 | 54,596 | 3,656
Race-ethnicity | Asian | 4,478 | 737 | 18,241 | 3,004
Race-ethnicity | Unknown | 7,386 | 430 | 33,093 | 1,925
Sex | Female | 47,481 | 660 | 242,347 | 3,366
Sex | Male | 44,192 | 678 | 209,160 | 3,208
Region | Northeast | 11,352 | 744 | 59,390 | 3,891
Region | Midwest | 17,992 | 541 | 93,257 | 2,807
Region | South | 41,273 | 734 | 202,711 | 3,607
Region | West | 21,056 | 648 | 96,149 | 2,957
Total | | 91,673 | 668 | 451,507 | 3,291

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with hemorrhoids (all-listed diagnoses) increased with age until 75 years and were higher among women compared with men (Table 114). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics, then Whites, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 115 Hemorrhoids: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 29 | 2 | 110 | 8
Age (years) | 25 to 44 | 345 | 13 | 1,135 | 43
Age (years) | 45 to 54 | 231 | 16 | 1,098 | 76
Age (years) | 55 to 64 | 346 | 21 | 1,600 | 98
Age (years) | 65 to 74 | 665 | 23 | 1,470 | 52
Age (years) | 75 plus | 925 | 36 | 1,990 | 77
Race-ethnicity | White | 1,551 | 18 | 4,879 | 56
Race-ethnicity | Black | 399 | 32 | 946 | 76
Race-ethnicity | Hispanic | 305 | 20 | 778 | 52
Race-ethnicity | Asian | 66 | 11 | 232 | 38
Race-ethnicity | Unknown | 220 | 13 | 568 | 33
Sex | Female | 1,459 | 20 | 4,222 | 59
Sex | Male | 1,082 | 17 | 3,181 | 49
Region | Northeast | 362 | 24 | 1,030 | 67
Region | Midwest | 513 | 15 | 1,602 | 48
Region | South | 1,216 | 22 | 3,483 | 62
Region | West | 450 | 14 | 1,288 | 40
Total | | 2,541 | 19 | 7,403 | 54

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with hemorrhoids (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among women compared with men (Table 115). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 116 Hemorrhoids: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | 18 | 2
Age (years) | 12 to 24 | 2 | 0 | 82 | 6
Age (years) | 25 to 44 | 45 | 2 | 648 | 24
Age (years) | 45 to 54 | 65 | 4 | 909 | 63
Age (years) | 55 to 64 | 91 | 6 | 2,225 | 136
Age (years) | 65 to 74 | 264 | 9 | 6,183 | 218
Age (years) | 75 plus | 516 | 20 | 10,050 | 390
Race-ethnicity | White | 600 | 7 | 13,006 | 150
Race-ethnicity | Black | 154 | 12 | 2,988 | 240
Race-ethnicity | Hispanic | 142 | 10 | 2,209 | 148
Race-ethnicity | Asian | 28 | 5 | 454 | 75
Race-ethnicity | Unknown | 59 | 3 | 1,458 | 85
Sex | Female | 507 | 7 | 11,142 | 155
Sex | Male | 476 | 7 | 8,973 | 138
Region | Northeast | 156 | 10 | 2,860 | 187
Region | Midwest | 189 | 6 | 4,323 | 130
Region | South | 427 | 8 | 9,160 | 163
Region | West | 211 | 6 | 3,772 | 116
Total | | 983 | 7 | 20,115 | 147

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with hemorrhoids (all-listed diagnoses) increased with age and were higher among women compared with men (Table 116). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 117 Hemorrhoids: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 60,360 | 0.7% | 371,360 | 4.6%
Age (years) | 70 to 74 | 6,936,940 | 54,280 | 0.8% | 328,060 | 4.7%
Age (years) | 75 to 79 | 4,894,060 | 39,600 | 0.8% | 214,980 | 4.4%
Age (years) | 80 to 84 | 3,335,340 | 27,400 | 0.8% | 116,980 | 3.5%
Age (years) | 85+ | 3,578,120 | 27,880 | 0.8% | 94,840 | 2.7%
Race | White | 22,023,800 | 168,740 | 0.8% | 912,080 | 4.1%
Race | Black | 1,861,660 | 14,040 | 0.8% | 80,880 | 4.3%
Race | Other | 2,925,320 | 26,740 | 0.9% | 133,260 | 4.6%
Sex | Female | 14,975,560 | 123,040 | 0.8% | 637,020 | 4.3%
Sex | Male | 11,835,220 | 86,480 | 0.7% | 489,200 | 4.1%
Region | Northeast | 4,748,700 | 40,860 | 0.9% | 227,920 | 4.8%
Region | Midwest | 6,069,800 | 38,780 | 0.6% | 225,160 | 3.7%
Region | South | 10,595,900 | 83,420 | 0.8% | 460,680 | 4.3%
Region | West | 5,396,380 | 46,460 | 0.9% | 212,460 | 3.9%
Total | | 26,810,780 | 209,520 | 0.8% | 1,126,220 | 4.2%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of hemorrhoids (based on all-listed diagnoses) was 4.2% (Table 117). Prevalence peaked among persons 70–74 years and was higher among women and Blacks. It was highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 118 Hemorrhoids: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 84,720 | 1,050 | 452,640 | 5,611
Age (years) | 70 to 74 | 75,080 | 1,082 | 397,100 | 5,724
Age (years) | 75 to 79 | 52,700 | 1,077 | 254,780 | 5,206
Age (years) | 80 to 84 | 36,140 | 1,084 | 140,780 | 4,221
Age (years) | 85+ | 31,780 | 888 | 110,980 | 3,102
Race | White | 226,420 | 1,028 | 1,090,980 | 4,954
Race | Black | 16,600 | 892 | 92,220 | 4,954
Race | Other | 37,400 | 1,278 | 173,080 | 5,917
Sex | Female | 160,360 | 1,071 | 772,560 | 5,159
Sex | Male | 120,060 | 1,014 | 583,720 | 4,932
Region | Northeast | 53,140 | 1,119 | 268,380 | 5,652
Region | Midwest | 50,780 | 837 | 254,440 | 4,192
Region | South | 114,000 | 1,076 | 566,500 | 5,346
Region | West | 62,500 | 1,158 | 266,960 | 4,947
Total | | 280,420 | 1,046 | 1,356,280 | 5,059

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with hemorrhoids (all-listed diagnoses) peaked among persons 70 to 74 years, were higher among women compared with men, and did not differ by race (Table 118). Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 119 Hemorrhoids: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 4,260 | 53 | 22,740 | 282
Age (years) | 70 to 74 | 4,580 | 66 | 26,720 | 385
Age (years) | 75 to 79 | 4,560 | 93 | 28,560 | 584
Age (years) | 80 to 84 | 4,780 | 143 | 26,400 | 792
Age (years) | 85+ | 6,800 | 190 | 33,240 | 929
Race | White | 19,360 | 88 | 107,760 | 489
Race | Black | 2,980 | 160 | 15,480 | 832
Race | Other | 2,640 | 90 | 14,420 | 493
Sex | Female | 16,200 | 108 | 82,140 | 548
Sex | Male | 8,780 | 74 | 55,520 | 469
Region | Northeast | 4,840 | 102 | 27,600 | 581
Region | Midwest | 5,440 | 90 | 29,720 | 490
Region | South | 10,240 | 97 | 56,040 | 529
Region | West | 4,460 | 83 | 24,300 | 450
Total | | 24,980 | 93 | 137,660 | 513

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with hemorrhoids (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 119). Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 120 Hemorrhoids: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 1,200 | 15 | 18,860 | 234
Age (years) | 70 to 74 | 1,400 | 20 | 22,600 | 326
Age (years) | 75 to 79 | 1,500 | 31 | 25,040 | 512
Age (years) | 80 to 84 | 1,820 | 55 | 22,800 | 684
Age (years) | 85+ | 2,220 | 62 | 26,520 | 741
Race | White | 6,400 | 29 | 91,580 | 416
Race | Black | 1,040 | 56 | 12,680 | 681
Race | Other | 700 | 24 | 11,560 | 395
Sex | Female | 5,140 | 34 | 67,460 | 450
Sex | Male | 3,000 | 25 | 48,360 | 409
Region | Northeast | 1,840 | 39 | 22,880 | 482
Region | Midwest | 1,780 | 29 | 25,580 | 421
Region | South | 3,420 | 32 | 48,020 | 453
Region | West | 1,100 | 20 | 19,340 | 358
Total | | 8,140 | 30 | 115,820 | 432

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with hemorrhoids (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 120). Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.