# Chapter 8 Diverticular Disease

Table 97 Diverticular Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 3 | 6 | 6 | 11
Age (years) | 25 to 44 | 71 | 84 | 229 | 271
Age (years) | 45 to 54 | 218 | 507 | 482 | 1,119
Age (years) | 55 to 64 | 609 | 1,492 | 1,157 | 2,836
Age (years) | 65 to 74 | 458 | 1,666 | 985 | 3,579
Age (years) | 75 plus | 289 | 1,430 | 721 | 3,567
Race | White | 1,365 | 415 | 3,184 | 1,006
Race | Black | 250 | 494 | 313 | 645
Race | Other | 33 | 115 | 85 | 331
Ethnicity | Hispanic | 266 | 633 | 529 | 1,485
Ethnicity | Not Hispanic | 1,382 | 383 | 3,052 | 888
Sex | Female | 1,077 | 498 | 2,232 | 1,074
Sex | Male | 572 | 311 | 1,349 | 765
Total | | 1,649 | 412 | 3,581 | 936

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Diverticular disease contributed to 3.6 million ambulatory visits (2015) (Table 97). Ambulatory care visits were uncommon among children and then rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and Hispanics compared with non-Hispanics.

Table 98 Diverticular Disease: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 0
Age (years) | 12 to 24 | 4 | 7 | 8 | 14
Age (years) | 25 to 44 | 99 | 113 | 165 | 189
Age (years) | 45 to 54 | 114 | 274 | 213 | 512
Age (years) | 55 to 64 | 130 | 308 | 290 | 686
Age (years) | 65 to 74 | 119 | 391 | 329 | 1,079
Age (years) | 75 plus | 131 | 596 | 471 | 2,149
Sex | Female | 344 | 173 | 844 | 409
Sex | Male | 253 | 151 | 632 | 369
Total | | 597 | 163 | 1,476 | 391

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Diverticular disease contributed to 1.5 million emergency department visits in 2018 (Table 98). Emergency department visits were uncommon among children and then rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men.

Table 99 Diverticular Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 0
Age (years) | 12 to 24 | 1 | 2 | 2 | 3
Age (years) | 25 to 44 | 34 | 39 | 57 | 65
Age (years) | 45 to 54 | 44 | 106 | 90 | 217
Age (years) | 55 to 64 | 61 | 144 | 160 | 378
Age (years) | 65 to 74 | 64 | 211 | 218 | 716
Age (years) | 75 plus | 89 | 407 | 353 | 1,608
Race | White | 248 | 81 | 745 | 231
Race | Black | 37 | 90 | 106 | 260
Race | Other | 13 | 51 | 39 | 164
Ethnicity | Hispanic | 31 | 71 | 91 | 225
Ethnicity | Not Hispanic | 266 | 80 | 800 | 230
Sex | Female | 165 | 79 | 492 | 228
Sex | Male | 129 | 76 | 387 | 223
Total | | 294 | 78 | 880 | 227

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Diverticular disease contributed to 880,000 hospital discharges in 2018 (Table 99). Hospitalizations were uncommon among children and then hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by 18% from 278 to 227.(4,6)

Table 100 Diverticular Disease: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 1 | 0.0 | 0.1 | 1 | 0.0 | 0.1
Age (years) | 12 to 24 | . | . | . | . | . | .
Age (years) | 25 to 44 | 24 | 0.0 | 1.0 | 42 | 0.0 | 1.7
Age (years) | 45 to 54 | 72 | 0.2 | 2.2 | 127 | 0.3 | 3.9
Age (years) | 55 to 64 | 276 | 0.7 | 6.3 | 445 | 1.0 | 10.2
Age (years) | 65 to 74 | 532 | 1.7 | 8.4 | 908 | 2.9 | 14.3
Age (years) | 75 plus | 2,014 | 8.9 | 13.6 | 3,262 | 14.4 | 22.0
Race | White | 2,616 | 0.8 | 27.7 | 4,283 | 1.2 | 45.9
Race | Black | 234 | 0.6 | 3.2 | 385 | 1.0 | 4.9
Race | Other | 69 | 0.3 | 0.8 | 117 | 0.5 | 1.3
Ethnicity | Hispanic | 176 | 0.5 | 2.5 | 299 | 0.8 | 4.2
Ethnicity | Not Hispanic | 2,743 | 0.7 | 29.1 | 4,486 | 1.2 | 48.0
Sex | Female | 1,932 | 0.8 | 20.4 | 3,043 | 1.3 | 32.0
Sex | Male | 987 | 0.6 | 11.2 | 1,742 | 1.0 | 20.2
Total | | 2,919 | 0.7 | 31.6 | 4,785 | 1.2 | 52.1

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Diverticular disease contributed to 5,000 deaths in 2019 (Table 100). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among women, Whites, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with diverticular disease as underlying or other cause decreased by 40% from 2.0 to 1.2.(4)

Table 101 Diverticular Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 3 | 0.0% | 5 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 105 | 0.0% | 237 | 0.0%
Age (years) | 25 to 44 | 2,656,672 | 4,503 | 0.2% | 9,600 | 0.4%
Age (years) | 45 to 54 | 1,452,320 | 7,584 | 0.5% | 32,872 | 2.3%
Age (years) | 55 to 64 | 1,640,216 | 13,447 | 0.8% | 69,544 | 4.2%
Age (years) | 65 to 74 | 2,840,615 | 30,538 | 1.1% | 163,451 | 5.8%
Age (years) | 75 plus | 2,576,241 | 27,365 | 1.1% | 122,218 | 4.7%
Race-ethnicity | White | 8,657,702 | 57,637 | 0.7% | 282,746 | 3.3%
Race-ethnicity | Black | 1,242,477 | 9,319 | 0.8% | 41,745 | 3.4%
Race-ethnicity | Hispanic | 1,493,457 | 9,900 | 0.7% | 40,954 | 2.7%
Race-ethnicity | Asian | 607,284 | 1,439 | 0.2% | 7,557 | 1.2%
Race-ethnicity | Unknown | 1,719,014 | 5,250 | 0.3% | 24,925 | 1.4%
Sex | Female | 7,199,363 | 50,411 | 0.7% | 219,713 | 3.1%
Sex | Male | 6,520,571 | 33,134 | 0.5% | 178,214 | 2.7%
Region | Northeast | 1,526,275 | 10,640 | 0.7% | 52,947 | 3.5%
Region | Midwest | 3,322,846 | 16,723 | 0.5% | 88,908 | 2.7%
Region | South | 5,619,435 | 39,790 | 0.7% | 179,935 | 3.2%
Region | West | 3,251,378 | 16,392 | 0.5% | 76,137 | 2.3%
Total | | 13,719,934 | 83,545 | 0.6% | 397,927 | 2.9%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of diverticular disease (based on all-listed diagnoses) was 2.9% (Table 101). Diverticular disease was uncommon in childhood and adolescence and then prevalence increased with age until the oldest age group. Prevalence was higher among women. It was highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. It was highest in the Northeast, followed by the South and Midwest, and lowest in the West.

Table 102 Diverticular Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 5 | 0 | 6 | 1
Age (years) | 12 to 24 | 138 | 10 | 291 | 20
Age (years) | 25 to 44 | 7,493 | 282 | 15,481 | 583
Age (years) | 45 to 54 | 11,583 | 798 | 44,056 | 3,033
Age (years) | 55 to 64 | 19,257 | 1,174 | 90,523 | 5,519
Age (years) | 65 to 74 | 39,645 | 1,396 | 207,668 | 7,311
Age (years) | 75 plus | 33,865 | 1,315 | 161,268 | 6,260
Race-ethnicity | White | 78,162 | 903 | 365,328 | 4,220
Race-ethnicity | Black | 11,392 | 917 | 54,212 | 4,363
Race-ethnicity | Hispanic | 13,575 | 909 | 57,396 | 3,843
Race-ethnicity | Asian | 1,834 | 302 | 9,553 | 1,573
Race-ethnicity | Unknown | 7,023 | 409 | 32,804 | 1,908
Sex | Female | 68,669 | 954 | 297,017 | 4,126
Sex | Male | 43,317 | 664 | 222,276 | 3,409
Region | Northeast | 14,339 | 939 | 68,647 | 4,498
Region | Midwest | 22,706 | 683 | 109,536 | 3,296
Region | South | 52,688 | 938 | 241,917 | 4,305
Region | West | 22,253 | 684 | 99,193 | 3,051
Total | | 111,986 | 816 | 519,293 | 3,785

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with diverticular disease (all-listed diagnoses) increased with age until 75 years and were higher among women compared with men (Table 102). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 103 Diverticular Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 2 | 0 | 5 | 0
Age (years) | 25 to 44 | 218 | 8 | 444 | 17
Age (years) | 45 to 54 | 485 | 33 | 1,169 | 80
Age (years) | 55 to 64 | 1,277 | 78 | 2,981 | 182
Age (years) | 65 to 74 | 5,894 | 207 | 9,379 | 330
Age (years) | 75 plus | 6,125 | 238 | 10,503 | 408
Race-ethnicity | White | 9,583 | 111 | 16,888 | 195
Race-ethnicity | Black | 1,659 | 134 | 2,816 | 227
Race-ethnicity | Hispanic | 1,639 | 110 | 2,792 | 187
Race-ethnicity | Asian | 177 | 29 | 357 | 59
Race-ethnicity | Unknown | 943 | 55 | 1,628 | 95
Sex | Female | 9,545 | 133 | 15,880 | 221
Sex | Male | 4,456 | 68 | 8,601 | 132
Region | Northeast | 2,011 | 132 | 3,182 | 208
Region | Midwest | 3,025 | 91 | 5,073 | 153
Region | South | 6,073 | 108 | 11,059 | 197
Region | West | 2,892 | 89 | 5,167 | 159
Total | | 14,001 | 102 | 24,481 | 178

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with diverticular disease (all-listed diagnoses) increased with age and were higher among women compared with men (Table 103). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 104 Diverticular Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | 1 | 0
Age (years) | 12 to 24 | 4 | 0 | 22 | 2
Age (years) | 25 to 44 | 686 | 26 | 1,180 | 44
Age (years) | 45 to 54 | 1,038 | 71 | 2,276 | 157
Age (years) | 55 to 64 | 1,805 | 110 | 5,443 | 332
Age (years) | 65 to 74 | 4,141 | 146 | 15,848 | 558
Age (years) | 75 plus | 6,380 | 248 | 27,816 | 1,080
Race-ethnicity | White | 9,550 | 110 | 35,948 | 415
Race-ethnicity | Black | 2,045 | 165 | 6,972 | 561
Race-ethnicity | Hispanic | 1,416 | 95 | 5,495 | 368
Race-ethnicity | Asian | 216 | 36 | 738 | 122
Race-ethnicity | Unknown | 827 | 48 | 3,433 | 200
Sex | Female | 8,325 | 116 | 30,734 | 427
Sex | Male | 5,729 | 88 | 21,852 | 335
Region | Northeast | 1,923 | 126 | 7,130 | 467
Region | Midwest | 3,206 | 96 | 11,337 | 341
Region | South | 6,374 | 113 | 24,165 | 430
Region | West | 2,551 | 78 | 9,954 | 306
Total | | 14,054 | 102 | 52,586 | 383

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with diverticular disease (all-listed diagnoses) increased with age and were higher among women compared with men (Table 104). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 105 Diverticular Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 113,280 | 1.4% | 538,180 | 6.7%
Age (years) | 70 to 74 | 6,936,940 | 122,180 | 1.8% | 546,660 | 7.9%
Age (years) | 75 to 79 | 4,894,060 | 93,540 | 1.9% | 398,100 | 8.1%
Age (years) | 80 to 84 | 3,335,340 | 61,800 | 1.9% | 232,840 | 7.0%
Age (years) | 85+ | 3,578,120 | 55,400 | 1.5% | 196,700 | 5.5%
Race | White | 22,023,800 | 375,600 | 1.7% | 1,624,300 | 7.4%
Race | Black | 1,861,660 | 30,260 | 1.6% | 121,680 | 6.5%
Race | Other | 2,925,320 | 40,340 | 1.4% | 166,500 | 5.7%
Sex | Female | 14,975,560 | 281,640 | 1.9% | 1,088,100 | 7.3%
Sex | Male | 11,835,220 | 164,560 | 1.4% | 824,380 | 7.0%
Region | Northeast | 4,748,700 | 86,540 | 1.8% | 367,820 | 7.7%
Region | Midwest | 6,069,800 | 83,660 | 1.4% | 404,820 | 6.7%
Region | South | 10,595,900 | 193,460 | 1.8% | 822,700 | 7.8%
Region | West | 5,396,380 | 82,540 | 1.5% | 317,140 | 5.9%
Total | | 26,810,780 | 446,200 | 1.7% | 1,912,480 | 7.1%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of diverticular disease (based on all-listed diagnoses) was 7.1% (Table 105). Prevalence peaked among persons 75–79 years and was higher among women and Whites. It was highest in the South and Northeast, followed by Midwest, and lowest in the West.

Table 106 Diverticular Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 134,900 | 1,672 | 675,960 | 8,380
Age (years) | 70 to 74 | 143,540 | 2,069 | 680,380 | 9,808
Age (years) | 75 to 79 | 101,580 | 2,076 | 487,080 | 9,952
Age (years) | 80 to 84 | 63,460 | 1,903 | 268,120 | 8,039
Age (years) | 85+ | 45,900 | 1,283 | 190,400 | 5,321
Race | White | 417,160 | 1,894 | 1,951,200 | 8,860
Race | Black | 28,760 | 1,545 | 141,860 | 7,620
Race | Other | 43,460 | 1,486 | 208,880 | 7,140
Sex | Female | 321,180 | 2,145 | 1,361,240 | 9,090
Sex | Male | 168,200 | 1,421 | 940,700 | 7,948
Region | Northeast | 97,220 | 2,047 | 449,880 | 9,474
Region | Midwest | 89,240 | 1,470 | 453,980 | 7,479
Region | South | 210,800 | 1,989 | 1,018,120 | 9,609
Region | West | 92,120 | 1,707 | 379,960 | 7,041
Total | | 489,380 | 1,825 | 2,301,940 | 8,586

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with diverticular disease (all-listed diagnoses) peaked among persons 75 to 79 years and were higher among women compared with men and Whites compared with Blacks (Table 106). Rates were higher in the South and Northeast compared with the Midwest and West.

Table 107 Diverticular Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 40,420 | 501 | 96,900 | 1,201
Age (years) | 70 to 74 | 43,380 | 625 | 116,860 | 1,685
Age (years) | 75 to 79 | 38,260 | 782 | 111,600 | 2,280
Age (years) | 80 to 84 | 29,660 | 889 | 96,780 | 2,902
Age (years) | 85+ | 37,200 | 1,040 | 129,400 | 3,616
Race | White | 155,900 | 708 | 457,240 | 2,076
Race | Black | 16,760 | 900 | 47,780 | 2,567
Race | Other | 16,260 | 556 | 46,520 | 1,590
Sex | Female | 123,060 | 822 | 338,580 | 2,261
Sex | Male | 65,860 | 556 | 212,960 | 1,799
Region | Northeast | 36,860 | 776 | 102,940 | 2,168
Region | Midwest | 39,420 | 649 | 117,540 | 1,936
Region | South | 81,100 | 765 | 237,100 | 2,238
Region | West | 31,540 | 584 | 93,960 | 1,741
Total | | 188,920 | 705 | 551,540 | 2,057

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with diverticular disease (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 107). Rates were highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 108 Diverticular Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 16,020 | 199 | 50,320 | 624
Age (years) | 70 to 74 | 18,800 | 271 | 66,780 | 963
Age (years) | 75 to 79 | 18,060 | 369 | 68,000 | 1,389
Age (years) | 80 to 84 | 14,980 | 449 | 60,960 | 1,828
Age (years) | 85+ | 20,520 | 573 | 81,380 | 2,274
Race | White | 71,840 | 326 | 271,200 | 1,231
Race | Black | 9,940 | 534 | 29,520 | 1,586
Race | Other | 6,600 | 226 | 26,720 | 913
Sex | Female | 56,140 | 375 | 197,740 | 1,320
Sex | Male | 32,240 | 272 | 129,700 | 1,096
Region | Northeast | 17,560 | 370 | 61,480 | 1,295
Region | Midwest | 20,160 | 332 | 75,940 | 1,251
Region | South | 38,360 | 362 | 138,440 | 1,307
Region | West | 12,300 | 228 | 51,580 | 956
Total | | 88,380 | 330 | 327,440 | 1,221

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with diverticular disease (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 108). Rates were lower in the West compared with the South, Northeast, and Midwest.