# Chapter 7 Inflammatory Bowel Disease

## Crohn's Disease

Table 73 Crohns Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 1 | 2
Age (years) | 12 to 24 | 26 | 46 | 63 | 112
Age (years) | 25 to 44 | 148 | 176 | 244 | 288
Age (years) | 45 to 54 | 110 | 255 | 257 | 596
Age (years) | 55 to 64 | 110 | 269 | 211 | 516
Age (years) | 65 to 74 | 144 | 524 | 213 | 774
Age (years) | 75 plus | 8 | 41 | 54 | 270
Race | White | 445 | 159 | 827 | 294
Race | Black | 31 | 58 | 105 | 240
Race | Other | 71 | 289 | 111 | 518
Ethnicity | Hispanic | 41 | 63 | 92 | 227
Ethnicity | Not Hispanic | 506 | 169 | 951 | 318
Sex | Female | 319 | 169 | 604 | 323
Sex | Male | 228 | 141 | 438 | 276
Total | | 547 | 156 | 1,043 | 300

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Crohn's disease contributed to 1.0 million ambulatory visits (2015) (Table 73). Ambulatory care visit rates (all-listed diagnoses) were highest among persons 65–74 years. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and non-Hispanics compared with Hispanics.

Table 74 Crohns Disease: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 2 | 3 | 6
Age (years) | 12 to 24 | 15 | 28 | 38 | 68
Age (years) | 25 to 44 | 45 | 52 | 143 | 164
Age (years) | 45 to 54 | 14 | 34 | 63 | 150
Age (years) | 55 to 64 | 10 | 22 | 53 | 124
Age (years) | 65 to 74 | 6 | 19 | 41 | 135
Age (years) | 75 plus | 3 | 16 | 35 | 160
Sex | Female | 51 | 31 | 220 | 129
Sex | Male | 44 | 28 | 155 | 95
Total | | 95 | 30 | 375 | 113

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Crohn's disease contributed to 375,000 emergency department visits in 2018 (Table 74). Emergency department visit rates (all-listed diagnoses) were highest among persons 25–44 years. Age-adjusted rates were higher among women compared with men.

Table 75 Crohns Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 2 | 1 | 3
Age (years) | 12 to 24 | 10 | 18 | 18 | 32
Age (years) | 25 to 44 | 25 | 28 | 60 | 69
Age (years) | 45 to 54 | 10 | 23 | 32 | 76
Age (years) | 55 to 64 | 7 | 18 | 35 | 83
Age (years) | 65 to 74 | 5 | 17 | 34 | 110
Age (years) | 75 plus | 3 | 14 | 27 | 124
Race | White | 49 | 19 | 177 | 64
Race | Black | 9 | 20 | 25 | 55
Race | Other | 3 | 10 | 7 | 27
Ethnicity | Hispanic | 4 | 8 | 12 | 23
Ethnicity | Not Hispanic | 57 | 21 | 197 | 67
Sex | Female | 33 | 20 | 119 | 66
Sex | Male | 28 | 18 | 88 | 52
Total | | 61 | 19 | 207 | 59

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Crohn's disease contributed to 207,000 hospital discharges in 2018 (Table 75). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by 23% from 48 to 59.(4)

Table 76 Crohns Disease: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 4 | 0.0 | 0.2 | 8 | 0.0 | 0.5
Age (years) | 25 to 44 | 57 | 0.1 | 2.4 | 141 | 0.2 | 6.0
Age (years) | 45 to 54 | 71 | 0.2 | 2.2 | 201 | 0.5 | 6.2
Age (years) | 55 to 64 | 100 | 0.2 | 2.3 | 360 | 0.8 | 8.4
Age (years) | 65 to 74 | 183 | 0.6 | 2.9 | 576 | 1.8 | 9.1
Age (years) | 75 plus | 264 | 1.2 | 2.1 | 899 | 4.0 | 6.9
Race | White | 625 | 0.2 | 10.9 | 2,002 | 0.6 | 33.2
Race | Black | 45 | 0.1 | 1.1 | 151 | 0.4 | 3.3
Race | Other | 9 | 0.0 | 0.2 | 32 | 0.1 | 0.6
Ethnicity | Hispanic | 15 | 0.0 | 0.3 | 45 | 0.1 | 0.9
Ethnicity | Not Hispanic | 664 | 0.2 | 11.8 | 2,140 | 0.6 | 36.2
Sex | Female | 394 | 0.2 | 6.8 | 1,202 | 0.5 | 20.6
Sex | Male | 285 | 0.2 | 5.3 | 983 | 0.6 | 16.5
Total | | 679 | 0.2 | 12.1 | 2,185 | 0.6 | 37.1

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Crohn's disease contributed to 2,000 deaths in 2019 (Table 76). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Whites, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with Crohn’s disease as underlying or other cause increased by 20% from 0.5 to 0.6.(4)

Table 77 Crohns Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 140 | 0.0% | 165 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 2,344 | 0.2% | 2,679 | 0.2%
Age (years) | 25 to 44 | 2,656,672 | 6,136 | 0.2% | 7,982 | 0.3%
Age (years) | 45 to 54 | 1,452,320 | 3,548 | 0.2% | 5,195 | 0.4%
Age (years) | 55 to 64 | 1,640,216 | 3,893 | 0.2% | 6,250 | 0.4%
Age (years) | 65 to 74 | 2,840,615 | 5,073 | 0.2% | 9,015 | 0.3%
Age (years) | 75 plus | 2,576,241 | 3,087 | 0.1% | 6,764 | 0.3%
Race-ethnicity | White | 8,657,702 | 18,684 | 0.2% | 29,160 | 0.3%
Race-ethnicity | Black | 1,242,477 | 2,009 | 0.2% | 3,212 | 0.3%
Race-ethnicity | Hispanic | 1,493,457 | 1,331 | 0.1% | 2,259 | 0.2%
Race-ethnicity | Asian | 607,284 | 436 | 0.1% | 685 | 0.1%
Race-ethnicity | Unknown | 1,719,014 | 1,761 | 0.1% | 2,734 | 0.2%
Sex | Female | 7,199,363 | 13,261 | 0.2% | 21,422 | 0.3%
Sex | Male | 6,520,571 | 10,960 | 0.2% | 16,628 | 0.3%
Region | Northeast | 1,526,275 | 3,252 | 0.2% | 5,026 | 0.3%
Region | Midwest | 3,322,846 | 6,776 | 0.2% | 10,225 | 0.3%
Region | South | 5,619,435 | 9,911 | 0.2% | 15,609 | 0.3%
Region | West | 3,251,378 | 4,282 | 0.1% | 7,190 | 0.2%
Total | | 13,719,934 | 24,221 | 0.2% | 38,050 | 0.3%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of Crohn's disease (based on all-listed diagnoses) was 0.3% (Table 77). Prevalence was highest in middle age and did not differ by sex. It was highest among Whites and Blacks, followed by Hispanics, and lowest among Asians. It differed little by region.

Table 78 Crohns Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 440 | 40 | 605 | 55
Age (years) | 12 to 24 | 6,537 | 450 | 9,135 | 629
Age (years) | 25 to 44 | 15,319 | 577 | 25,165 | 947
Age (years) | 45 to 54 | 8,479 | 584 | 16,955 | 1,167
Age (years) | 55 to 64 | 8,688 | 530 | 19,693 | 1,201
Age (years) | 65 to 74 | 10,558 | 372 | 25,974 | 914
Age (years) | 75 plus | 6,231 | 242 | 18,133 | 704
Race-ethnicity | White | 42,985 | 496 | 88,152 | 1,018
Race-ethnicity | Black | 4,734 | 381 | 10,239 | 824
Race-ethnicity | Hispanic | 3,188 | 213 | 6,921 | 463
Race-ethnicity | Asian | 1,144 | 188 | 2,106 | 347
Race-ethnicity | Unknown | 4,201 | 244 | 8,242 | 479
Sex | Female | 31,386 | 436 | 67,854 | 943
Sex | Male | 24,866 | 381 | 47,806 | 733
Region | Northeast | 7,753 | 508 | 15,475 | 1,014
Region | Midwest | 14,393 | 433 | 28,482 | 857
Region | South | 24,313 | 433 | 50,239 | 894
Region | West | 9,793 | 301 | 21,464 | 660
Total | | 56,252 | 410 | 115,660 | 843

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with Crohn's disease (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among women compared with men (Table 78). Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 79 Crohns Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 2 | 0 | 2 | 0
Age (years) | 12 to 24 | 40 | 3 | 67 | 5
Age (years) | 25 to 44 | 308 | 12 | 663 | 25
Age (years) | 45 to 54 | 231 | 16 | 421 | 29
Age (years) | 55 to 64 | 147 | 9 | 328 | 20
Age (years) | 65 to 74 | 170 | 6 | 473 | 17
Age (years) | 75 plus | 106 | 4 | 382 | 15
Race-ethnicity | White | 738 | 9 | 1,761 | 20
Race-ethnicity | Black | 115 | 9 | 242 | 19
Race-ethnicity | Hispanic | 59 | 4 | 129 | 9
Race-ethnicity | Asian | 13 | 2 | 24 | 4
Race-ethnicity | Unknown | 79 | 5 | 180 | 10
Sex | Female | 568 | 8 | 1,446 | 20
Sex | Male | 436 | 7 | 890 | 14
Region | Northeast | 126 | 8 | 368 | 24
Region | Midwest | 231 | 7 | 551 | 17
Region | South | 496 | 9 | 1,036 | 18
Region | West | 151 | 5 | 381 | 12
Total | | 1,004 | 7 | 2,336 | 17

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with Crohn's disease (all-listed diagnoses) peaked among persons 45 to 54 years and were higher among women compared with men (Table 79). Among persons with known race-ethnicity, rates were highest among Whites and Blacks, followed by Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South and Midwest, and lowest in the West.

Table 80 Crohns Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 18 | 2 | 23 | 2
Age (years) | 12 to 24 | 208 | 14 | 378 | 26
Age (years) | 25 to 44 | 512 | 19 | 1,418 | 53
Age (years) | 45 to 54 | 268 | 18 | 1,031 | 71
Age (years) | 55 to 64 | 286 | 17 | 1,536 | 94
Age (years) | 65 to 74 | 319 | 11 | 2,414 | 85
Age (years) | 75 plus | 231 | 9 | 2,412 | 94
Race-ethnicity | White | 1,302 | 15 | 6,853 | 79
Race-ethnicity | Black | 198 | 16 | 988 | 80
Race-ethnicity | Hispanic | 113 | 8 | 531 | 36
Race-ethnicity | Asian | 40 | 7 | 118 | 19
Race-ethnicity | Unknown | 189 | 11 | 722 | 42
Sex | Female | 1,043 | 14 | 5,429 | 75
Sex | Male | 799 | 12 | 3,783 | 58
Region | Northeast | 256 | 17 | 1,208 | 79
Region | Midwest | 458 | 14 | 2,272 | 68
Region | South | 815 | 15 | 4,042 | 72
Region | West | 313 | 10 | 1,690 | 52
Total | | 1,842 | 13 | 9,212 | 67

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with Crohn's disease (all-listed diagnoses) increased with age until 65 years and were higher among women compared with men (Table 80). Among persons with known race-ethnicity, rates were highest among Blacks and Whites, followed by Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 81 Crohns Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 21,000 | 0.3% | 33,780 | 0.4%
Age (years) | 70 to 74 | 6,936,940 | 17,420 | 0.3% | 28,860 | 0.4%
Age (years) | 75 to 79 | 4,894,060 | 11,540 | 0.2% | 20,140 | 0.4%
Age (years) | 80 to 84 | 3,335,340 | 6,400 | 0.2% | 12,200 | 0.4%
Age (years) | 85+ | 3,578,120 | 3,780 | 0.1% | 8,360 | 0.2%
Race | White | 22,023,800 | 53,380 | 0.2% | 92,340 | 0.4%
Race | Black | 1,861,660 | 2,520 | 0.1% | 4,360 | 0.2%
Race | Other | 2,925,320 | 4,240 | 0.1% | 6,640 | 0.2%
Sex | Female | 14,975,560 | 34,860 | 0.2% | 60,900 | 0.4%
Sex | Male | 11,835,220 | 25,280 | 0.2% | 42,440 | 0.4%
Region | Northeast | 4,748,700 | 14,000 | 0.3% | 22,860 | 0.5%
Region | Midwest | 6,069,800 | 14,120 | 0.2% | 24,700 | 0.4%
Region | South | 10,595,900 | 22,580 | 0.2% | 39,340 | 0.4%
Region | West | 5,396,380 | 9,440 | 0.2% | 16,440 | 0.3%
Total | | 26,810,780 | 60,140 | 0.2% | 103,340 | 0.4%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of Crohn's disease (based on all-listed diagnoses) was 0.4% (Table 81). Prevalence differed little by age, did not differ by sex, and was higher among Whites. It was highest in the Northeast and lowest in the West.

Table 82 Crohns Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 63,380 | 786 | 127,640 | 1,582
Age (years) | 70 to 74 | 53,740 | 775 | 109,200 | 1,574
Age (years) | 75 to 79 | 32,420 | 662 | 72,000 | 1,471
Age (years) | 80 to 84 | 18,900 | 567 | 41,500 | 1,244
Age (years) | 85+ | 9,180 | 257 | 26,100 | 729
Race | White | 157,740 | 716 | 335,440 | 1,523
Race | Black | 7,100 | 381 | 15,620 | 839
Race | Other | 12,780 | 437 | 25,380 | 868
Sex | Female | 100,300 | 670 | 223,340 | 1,491
Sex | Male | 77,320 | 653 | 153,100 | 1,294
Region | Northeast | 39,740 | 837 | 85,980 | 1,811
Region | Midwest | 39,720 | 654 | 84,440 | 1,391
Region | South | 70,520 | 666 | 147,480 | 1,392
Region | West | 27,640 | 512 | 58,540 | 1,085
Total | | 177,620 | 662 | 376,440 | 1,404

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with Crohn's disease (all-listed diagnoses) decreased with age and were higher among women compared with men and Whites compared with Blacks (Table 82). Rates were highest in the Northeast, followed by the South and Midwest, and lowest in the West.

Table 83 Crohns Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 2,000 | 25 | 13,420 | 166
Age (years) | 70 to 74 | 1,580 | 23 | 12,240 | 176
Age (years) | 75 to 79 | 1,300 | 27 | 10,540 | 215
Age (years) | 80 to 84 | 960 | 29 | 7,500 | 225
Age (years) | 85+ | 340 | 10 | 5,740 | 160
Race | White | 5,280 | 24 | 43,680 | 198
Race | Black | 420 | 23 | 2,800 | 150
Race | Other | 480 | 16 | 2,960 | 101
Sex | Female | 4,080 | 27 | 30,940 | 207
Sex | Male | 2,100 | 18 | 18,500 | 156
Region | Northeast | 1,560 | 33 | 11,340 | 239
Region | Midwest | 1,260 | 21 | 12,000 | 198
Region | South | 2,520 | 24 | 18,820 | 178
Region | West | 840 | 16 | 7,280 | 135
Total | | 6,180 | 23 | 49,440 | 184

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with Crohn's disease (all-listed diagnoses) increased with age until 85 years and were higher among women compared with men and Whites compared with Blacks (Table 83). Rates were highest in the Northeast, followed by the Midwest, then the South, and lowest in the West.

Table 84 Crohns Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 1,500 | 19 | 9,540 | 118
Age (years) | 70 to 74 | 1,280 | 18 | 9,600 | 138
Age (years) | 75 to 79 | 860 | 18 | 8,720 | 178
Age (years) | 80 to 84 | 600 | 18 | 5,360 | 161
Age (years) | 85+ | 380 | 11 | 4,500 | 126
Race | White | 4,000 | 18 | 33,520 | 152
Race | Black | 280 | 15 | 2,060 | 111
Race | Other | 340 | 12 | 2,140 | 73
Sex | Female | 2,700 | 18 | 23,340 | 156
Sex | Male | 1,920 | 16 | 14,380 | 122
Region | Northeast | 1,200 | 25 | 8,380 | 176
Region | Midwest | 1,000 | 16 | 9,760 | 161
Region | South | 1,860 | 18 | 14,200 | 134
Region | West | 560 | 10 | 5,380 | 100
Total | | 4,620 | 17 | 37,720 | 141

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with Crohn's disease (all-listed diagnoses) peaked among persons 75 to 79 years and were higher among women compared with men and Whites compared with Blacks (Table 84). Rates were highest in the Northeast, followed by the Midwest, then the South, and lowest in the West.

## Ulcerative Colitis

Table 85 Ulcerative Colitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 38 | 67 | 110 | 196
Age (years) | 25 to 44 | 64 | 76 | 128 | 152
Age (years) | 45 to 54 | 343 | 795 | 372 | 864
Age (years) | 55 to 64 | 240 | 587 | 358 | 878
Age (years) | 65 to 74 | 65 | 235 | 269 | 976
Age (years) | 75 plus | 39 | 195 | 68 | 338
Race | White | 565 | 203 | 1,011 | 351
Race | Black | 188 | 385 | 248 | 510
Race | Other | 36 | 218 | 47 | 288
Ethnicity | Hispanic | 259 | 598 | 339 | 807
Ethnicity | Not Hispanic | 530 | 167 | 968 | 304
Sex | Female | 418 | 235 | 796 | 431
Sex | Male | 370 | 211 | 510 | 285
Total | | 789 | 221 | 1,306 | 357

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Ulcerative colitis contributed to 1.3 million ambulatory visits (2015) (Table 85). Ambulatory care visit rates (all-listed diagnoses) were highest among persons 65–74 years. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 86 Ulcerative Colitis: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 1 | 1 | 3
Age (years) | 12 to 24 | 8 | 15 | 16 | 28
Age (years) | 25 to 44 | 21 | 24 | 46 | 53
Age (years) | 45 to 54 | 7 | 18 | 22 | 54
Age (years) | 55 to 64 | 7 | 17 | 25 | 60
Age (years) | 65 to 74 | 5 | 17 | 25 | 81
Age (years) | 75 plus | 5 | 24 | 29 | 132
Sex | Female | 30 | 18 | 91 | 50
Sex | Male | 24 | 15 | 74 | 44
Total | | 55 | 16 | 164 | 47

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Ulcerative colitis contributed to 164,000 emergency department visits in 2018 (Table 86). Emergency department visit rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men.

Table 87 Ulcerative Colitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 2 | 1 | 2
Age (years) | 12 to 24 | 6 | 11 | 11 | 19
Age (years) | 25 to 44 | 12 | 14 | 29 | 33
Age (years) | 45 to 54 | 5 | 12 | 16 | 38
Age (years) | 55 to 64 | 6 | 13 | 21 | 51
Age (years) | 65 to 74 | 5 | 15 | 23 | 77
Age (years) | 75 plus | 4 | 20 | 27 | 122
Race | White | 32 | 12 | 110 | 38
Race | Black | 4 | 10 | 12 | 27
Race | Other | 2 | 9 | 6 | 24
Ethnicity | Hispanic | 5 | 9 | 11 | 22
Ethnicity | Not Hispanic | 34 | 12 | 118 | 38
Sex | Female | 21 | 12 | 68 | 36
Sex | Male | 18 | 11 | 59 | 35
Total | | 39 | 11 | 128 | 36

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Ulcerative colitis contributed to 128,000 hospital discharges in 2018 (Table 87). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by 29% from 28 to 36.(4)

Table 88 Ulcerative Colitis: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 3 | 0.0 | 0.2 | 13 | 0.0 | 0.8
Age (years) | 25 to 44 | 15 | 0.0 | 0.6 | 55 | 0.1 | 2.4
Age (years) | 45 to 54 | 24 | 0.1 | 0.8 | 83 | 0.2 | 2.6
Age (years) | 55 to 64 | 54 | 0.1 | 1.3 | 186 | 0.4 | 4.3
Age (years) | 65 to 74 | 104 | 0.3 | 1.6 | 329 | 1.0 | 5.2
Age (years) | 75 plus | 224 | 1.0 | 1.6 | 800 | 3.5 | 5.8
Race | White | 377 | 0.1 | 5.2 | 1,346 | 0.4 | 18.7
Race | Black | 36 | 0.1 | 0.7 | 92 | 0.2 | 1.8
Race | Other | 11 | 0.0 | 0.2 | 28 | 0.1 | 0.6
Ethnicity | Hispanic | 12 | 0.0 | 0.3 | 47 | 0.1 | 1.2
Ethnicity | Not Hispanic | 412 | 0.1 | 5.8 | 1,419 | 0.4 | 19.8
Sex | Female | 227 | 0.1 | 3.3 | 708 | 0.3 | 10.3
Sex | Male | 197 | 0.1 | 2.8 | 758 | 0.4 | 10.7
Total | | 424 | 0.1 | 6.1 | 1,466 | 0.4 | 21.0

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Ulcerative colitis contributed to 1,000 deaths in 2019 (Table 88). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Whites, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with ulcerative colitis as underlying or other cause increased by a third from 0.3 to 0.4.(4)

Table 89 Ulcerative Colitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 87 | 0.0% | 116 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 1,472 | 0.1% | 1,786 | 0.1%
Age (years) | 25 to 44 | 2,656,672 | 6,106 | 0.2% | 8,123 | 0.3%
Age (years) | 45 to 54 | 1,452,320 | 3,496 | 0.2% | 5,809 | 0.4%
Age (years) | 55 to 64 | 1,640,216 | 4,142 | 0.3% | 7,532 | 0.5%
Age (years) | 65 to 74 | 2,840,615 | 6,725 | 0.2% | 13,668 | 0.5%
Age (years) | 75 plus | 2,576,241 | 4,823 | 0.2% | 11,445 | 0.4%
Race-ethnicity | White | 8,657,702 | 19,962 | 0.2% | 36,053 | 0.4%
Race-ethnicity | Black | 1,242,477 | 2,035 | 0.2% | 3,814 | 0.3%
Race-ethnicity | Hispanic | 1,493,457 | 2,143 | 0.1% | 3,916 | 0.3%
Race-ethnicity | Asian | 607,284 | 828 | 0.1% | 1,369 | 0.2%
Race-ethnicity | Unknown | 1,719,014 | 1,883 | 0.1% | 3,327 | 0.2%
Sex | Female | 7,199,363 | 14,240 | 0.2% | 26,375 | 0.4%
Sex | Male | 6,520,571 | 12,611 | 0.2% | 22,104 | 0.3%
Region | Northeast | 1,526,275 | 3,787 | 0.2% | 6,600 | 0.4%
Region | Midwest | 3,322,846 | 6,812 | 0.2% | 11,922 | 0.4%
Region | South | 5,619,435 | 10,843 | 0.2% | 19,811 | 0.4%
Region | West | 3,251,378 | 5,409 | 0.2% | 10,146 | 0.3%
Total | | 13,719,934 | 26,851 | 0.2% | 48,479 | 0.4%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of ulcerative colitis (based on all-listed diagnoses) was 0.4% (Table 89). Prevalence increased with age until the oldest age group and was higher among women. It was highest among Whites, similar among Blacks and Hispanics, and lowest among Asians. It differed little by region.

Table 90 Ulcerative Colitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 215 | 20 | 318 | 29
Age (years) | 12 to 24 | 3,718 | 256 | 5,202 | 358
Age (years) | 25 to 44 | 12,849 | 484 | 19,957 | 751
Age (years) | 45 to 54 | 6,578 | 453 | 12,739 | 877
Age (years) | 55 to 64 | 7,490 | 457 | 16,090 | 981
Age (years) | 65 to 74 | 11,765 | 414 | 27,889 | 982
Age (years) | 75 plus | 8,109 | 315 | 23,147 | 898
Race-ethnicity | White | 37,168 | 429 | 77,927 | 900
Race-ethnicity | Black | 3,737 | 301 | 8,049 | 648
Race-ethnicity | Hispanic | 4,373 | 293 | 8,916 | 597
Race-ethnicity | Asian | 1,728 | 285 | 3,145 | 518
Race-ethnicity | Unknown | 3,718 | 216 | 7,305 | 425
Sex | Female | 26,327 | 366 | 56,748 | 788
Sex | Male | 24,397 | 374 | 48,594 | 745
Region | Northeast | 7,219 | 473 | 14,747 | 966
Region | Midwest | 11,940 | 359 | 24,443 | 736
Region | South | 21,257 | 378 | 43,552 | 775
Region | West | 10,308 | 317 | 22,600 | 695
Total | | 50,724 | 370 | 105,342 | 768

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with ulcerative colitis (all-listed diagnoses) peaked among persons 55 to 74 years and were higher among women compared with men (Table 90). Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 91 Ulcerative Colitis: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 2 | 0 | 2 | 0
Age (years) | 12 to 24 | 34 | 2 | 63 | 4
Age (years) | 25 to 44 | 232 | 9 | 444 | 17
Age (years) | 45 to 54 | 89 | 6 | 157 | 11
Age (years) | 55 to 64 | 138 | 8 | 261 | 16
Age (years) | 65 to 74 | 249 | 9 | 511 | 18
Age (years) | 75 plus | 278 | 11 | 628 | 24
Race-ethnicity | White | 727 | 8 | 1,470 | 17
Race-ethnicity | Black | 98 | 8 | 191 | 15
Race-ethnicity | Hispanic | 86 | 6 | 181 | 12
Race-ethnicity | Asian | 24 | 4 | 57 | 9
Race-ethnicity | Unknown | 87 | 5 | 167 | 10
Sex | Female | 660 | 9 | 1,343 | 19
Sex | Male | 362 | 6 | 723 | 11
Region | Northeast | 177 | 12 | 310 | 20
Region | Midwest | 228 | 7 | 436 | 13
Region | South | 436 | 8 | 918 | 16
Region | West | 181 | 6 | 402 | 12
Total | | 1,022 | 7 | 2,066 | 15

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with ulcerative colitis (all-listed diagnoses) were highest among persons 75 years and older and were higher among women compared with men (Table 91). Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, and lowest in the Midwest and West.

Table 92 Ulcerative Colitis: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 16 | 1 | 24 | 2
Age (years) | 12 to 24 | 125 | 9 | 246 | 17
Age (years) | 25 to 44 | 241 | 9 | 873 | 33
Age (years) | 45 to 54 | 126 | 9 | 529 | 36
Age (years) | 55 to 64 | 181 | 11 | 1,064 | 65
Age (years) | 65 to 74 | 332 | 12 | 2,174 | 77
Age (years) | 75 plus | 327 | 13 | 2,738 | 106
Race-ethnicity | White | 1,000 | 12 | 5,632 | 65
Race-ethnicity | Black | 126 | 10 | 724 | 58
Race-ethnicity | Hispanic | 100 | 7 | 588 | 39
Race-ethnicity | Asian | 25 | 4 | 140 | 23
Race-ethnicity | Unknown | 97 | 6 | 564 | 33
Sex | Female | 789 | 11 | 4,382 | 61
Sex | Male | 559 | 9 | 3,266 | 50
Region | Northeast | 198 | 13 | 1,130 | 74
Region | Midwest | 323 | 10 | 1,834 | 55
Region | South | 598 | 11 | 3,235 | 58
Region | West | 229 | 7 | 1,449 | 45
Total | | 1,348 | 10 | 7,648 | 56

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with ulcerative colitis (all-listed diagnoses) increased with age and were higher among women compared with men (Table 92). Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 93 Ulcerative Colitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 24,820 | 0.3% | 45,580 | 0.6%
Age (years) | 70 to 74 | 6,936,940 | 22,580 | 0.3% | 43,040 | 0.6%
Age (years) | 75 to 79 | 4,894,060 | 15,320 | 0.3% | 30,560 | 0.6%
Age (years) | 80 to 84 | 3,335,340 | 8,620 | 0.3% | 17,900 | 0.5%
Age (years) | 85+ | 3,578,120 | 6,700 | 0.2% | 15,300 | 0.4%
Race | White | 22,023,800 | 68,360 | 0.3% | 133,360 | 0.6%
Race | Black | 1,861,660 | 3,260 | 0.2% | 6,920 | 0.4%
Race | Other | 2,925,320 | 6,420 | 0.2% | 12,100 | 0.4%
Sex | Female | 14,975,560 | 43,160 | 0.3% | 85,840 | 0.6%
Sex | Male | 11,835,220 | 34,880 | 0.3% | 66,540 | 0.6%
Region | Northeast | 4,748,700 | 17,900 | 0.4% | 34,100 | 0.7%
Region | Midwest | 6,069,800 | 16,480 | 0.3% | 33,840 | 0.6%
Region | South | 10,595,900 | 29,640 | 0.3% | 58,060 | 0.5%
Region | West | 5,396,380 | 14,020 | 0.3% | 26,380 | 0.5%
Total | | 26,810,780 | 78,040 | 0.3% | 152,380 | 0.6%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of ulcerative colitis (based on all-listed diagnoses) was 0.6% (Table 93). Prevalence was highest among persons 65–79 years, did not differ by sex, and was higher among Whites. It was highest in the Northeast and lowest in the South and West.

Table 94 Ulcerative Colitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 52,380 | 649 | 110,540 | 1,370
Age (years) | 70 to 74 | 47,280 | 682 | 104,680 | 1,509
Age (years) | 75 to 79 | 31,500 | 644 | 71,660 | 1,464
Age (years) | 80 to 84 | 16,420 | 492 | 42,040 | 1,260
Age (years) | 85+ | 11,820 | 330 | 34,120 | 954
Race | White | 140,240 | 637 | 320,340 | 1,455
Race | Black | 5,940 | 319 | 14,800 | 795
Race | Other | 13,220 | 452 | 27,900 | 954
Sex | Female | 84,080 | 561 | 199,000 | 1,329
Sex | Male | 75,320 | 636 | 164,040 | 1,386
Region | Northeast | 36,380 | 766 | 82,580 | 1,739
Region | Midwest | 31,420 | 518 | 73,800 | 1,216
Region | South | 64,120 | 605 | 144,140 | 1,360
Region | West | 27,480 | 509 | 62,520 | 1,159
Total | | 159,400 | 595 | 363,040 | 1,354

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with ulcerative colitis (all-listed diagnoses) peaked among persons 70 to 74 years and were higher among men compared with women and Whites compared with Blacks (Table 94). Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 95 Ulcerative Colitis: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 1,900 | 24 | 7,820 | 97
Age (years) | 70 to 74 | 1,760 | 25 | 7,500 | 108
Age (years) | 75 to 79 | 1,440 | 29 | 6,980 | 143
Age (years) | 80 to 84 | 1,180 | 35 | 5,680 | 170
Age (years) | 85+ | 1,160 | 32 | 6,420 | 179
Race | White | 6,400 | 29 | 30,080 | 137
Race | Black | 360 | 19 | 1,820 | 98
Race | Other | 680 | 23 | 2,500 | 85
Sex | Female | 4,820 | 32 | 20,520 | 137
Sex | Male | 2,620 | 22 | 13,880 | 117
Region | Northeast | 1,860 | 39 | 8,900 | 187
Region | Midwest | 1,620 | 27 | 7,800 | 129
Region | South | 2,740 | 26 | 12,020 | 113
Region | West | 1,220 | 23 | 5,680 | 105
Total | | 7,440 | 28 | 34,400 | 128

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with ulcerative colitis (all-listed diagnoses) increased with age and were higher among women compared with men and Whites compared with Blacks (Table 95). Rates were highest in the Northeast, followed by the Midwest, then the South, and lowest in the West.

Table 96 Ulcerative Colitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 1,240 | 15 | 7,300 | 90
Age (years) | 70 to 74 | 860 | 12 | 6,420 | 93
Age (years) | 75 to 79 | 920 | 19 | 6,900 | 141
Age (years) | 80 to 84 | 740 | 22 | 5,080 | 152
Age (years) | 85+ | 660 | 18 | 5,380 | 150
Race | White | 3,800 | 17 | 27,340 | 124
Race | Black | 300 | 16 | 1,560 | 84
Race | Other | 320 | 11 | 2,180 | 75
Sex | Female | 2,720 | 18 | 17,840 | 119
Sex | Male | 1,700 | 14 | 13,240 | 112
Region | Northeast | 1,000 | 21 | 7,440 | 157
Region | Midwest | 1,280 | 21 | 8,100 | 133
Region | South | 1,560 | 15 | 10,640 | 100
Region | West | 580 | 11 | 4,900 | 91
Total | | 4,420 | 16 | 31,080 | 116

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with ulcerative colitis (all-listed diagnoses) increased with age until 85 years and were higher among women compared with men and Whites compared with Blacks (Table 96). Rates were highest in the Northeast, followed by the Midwest, then the South, and lowest in the West.

## Colorectal Cancer

Table 250 Colorectal Cancer: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | . | 0.0
Age (years) | 12 to 24 | 877 | 1.6
Age (years) | 25 to 44 | 8,814 | 10.1
Age (years) | 45 to 54 | 19,593 | 47.1
Age (years) | 55 to 64 | 29,710 | 70.3
Age (years) | 65 to 74 | 33,730 | 110.6
Age (years) | 75 plus | 43,342 | 197.6
Race | White | 106,708 | 34.3
Race | Black | 16,878 | 40.6
Race | Other | 9,409 | 34.7
Ethnicity | Hispanic | 13,543 | 33.0
Ethnicity | Not Hispanic | 115,855 | 35.3
Sex | Female | 63,289 | 31.2
Sex | Male | 68,385 | 39.4
Total | | 131,692 | 35.0

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Colorectal cancer accounted for 132,000 incident cases in 2016 (Table 250). Colorectal cancer was rare among children and incidence rates increased with age throughout adulthood. Age-adjusted incidence rates were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2016, age-adjusted incidence rates (per 100,000) decreased by 26% from 47.5 to 35.0 (4)

Table 251 Colorectal Cancer: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 0
Age (years) | 12 to 24 | 0 | 0 | 0 | 1
Age (years) | 25 to 44 | 7 | 8 | 16 | 18
Age (years) | 45 to 54 | 18 | 44 | 36 | 87
Age (years) | 55 to 64 | 29 | 68 | 59 | 139
Age (years) | 65 to 74 | 33 | 108 | 66 | 215
Age (years) | 75 plus | 38 | 175 | 73 | 333
Race | White | 103 | 32 | 202 | 63
Race | Black | 15 | 34 | 32 | 74
Race | Other | 9 | 36 | 18 | 71
Ethnicity | Hispanic | 12 | 29 | 25 | 59
Ethnicity | Not Hispanic | 114 | 33 | 227 | 66
Sex | Female | 59 | 28 | 117 | 56
Sex | Male | 66 | 37 | 133 | 74
Total | | 126 | 32 | 250 | 64

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Colorectal cancer contributed to 250,000 hospital discharges in 2018 (Table 251). Colorectal cancer hospitalization was rare among children and hospital discharge rates increased with age throughout adulthood. Age-adjusted hospital discharge rates (all-listed diagnoses) were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by 26% from 87 to 64.(4,6)

Table 252 Colorectal Cancer: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 38 | 0.1 | 2.2 | 42 | 0.1 | 2.4
Age (years) | 25 to 44 | 1,708 | 1.9 | 71.0 | 1,772 | 2.0 | 73.7
Age (years) | 45 to 54 | 4,734 | 11.6 | 146.4 | 4,988 | 12.2 | 154.1
Age (years) | 55 to 64 | 10,048 | 23.7 | 229.2 | 10,845 | 25.5 | 247.1
Age (years) | 65 to 74 | 12,684 | 40.3 | 199.8 | 14,354 | 45.6 | 225.4
Age (years) | 75 plus | 22,494 | 99.6 | 164.0 | 27,798 | 123.1 | 199.0
Race | White | 42,411 | 12.6 | 654.6 | 49,354 | 14.6 | 728.6
Race | Black | 7,024 | 16.3 | 117.8 | 7,907 | 18.5 | 129.6
Race | Other | 2,271 | 9.0 | 40.1 | 2,538 | 10.1 | 43.4
Ethnicity | Hispanic | 3,654 | 8.8 | 74.4 | 4,063 | 9.9 | 80.6
Ethnicity | Not Hispanic | 48,052 | 13.3 | 738.1 | 55,736 | 15.3 | 821.1
Sex | Female | 24,124 | 10.7 | 377.1 | 27,678 | 12.2 | 415.7
Sex | Male | 27,582 | 15.2 | 435.4 | 32,121 | 17.8 | 486.0
Total | | 51,706 | 12.8 | 812.5 | 59,799 | 14.7 | 901.6

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Colorectal cancer contributed to 60,000 deaths in 2019 (Table 252). Colorectal cancer mortality was rare among children and mortality rates increased with age throughout adulthood. Age-adjusted mortality rates (underlying or other cause) were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with colorectal cancer as underlying or other cause decreased by 31% from 21.4 to 14.7.(4)