# Chapter 6 Abdominal Wall Hernia

Table 61 Abdominal Wall Hernia: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 72 | 148 | 361 | 743
Age (years) | 12 to 24 | 128 | 228 | 146 | 261
Age (years) | 25 to 44 | 531 | 629 | 903 | 1,069
Age (years) | 45 to 54 | 711 | 1,651 | 1,022 | 2,372
Age (years) | 55 to 64 | 730 | 1,789 | 1,023 | 2,506
Age (years) | 65 to 74 | 618 | 2,243 | 895 | 3,251
Age (years) | 75 plus | 421 | 2,085 | 781 | 3,864
Race | White | 2,771 | 981 | 4,230 | 1,521
Race | Black | 361 | 789 | 722 | 1,701
Race | Other | 79 | 347 | 179 | 755
Ethnicity | Hispanic | 572 | 1,254 | 820 | 1,751
Ethnicity | Not Hispanic | 2,640 | 872 | 4,311 | 1,450
Sex | Female | 930 | 525 | 1,790 | 1,034
Sex | Male | 2,282 | 1,339 | 3,341 | 2,004
Total | | 3,212 | 910 | 5,131 | 1,484

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Abdominal wall hernia contributed to 5.1 million ambulatory visits (2015) (Table 61). Ambulatory care visit rates (all-listed diagnoses) were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 62 Abdominal Wall Hernia: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 15 | 31 | 35 | 72
Age (years) | 12 to 24 | 12 | 22 | 21 | 38
Age (years) | 25 to 44 | 82 | 94 | 159 | 183
Age (years) | 45 to 54 | 59 | 141 | 130 | 313
Age (years) | 55 to 64 | 60 | 141 | 148 | 351
Age (years) | 65 to 74 | 43 | 141 | 121 | 397
Age (years) | 75 plus | 48 | 218 | 146 | 665
Sex | Female | 115 | 64 | 304 | 165
Sex | Male | 203 | 121 | 457 | 269
Total | | 318 | 92 | 761 | 214

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Abdominal wall hernia contributed to 761,000 emergency department visits in 2018 (Table 62). Emergency department visit rates (all-listed diagnoses) were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among men compared with women.

Table 63 Abdominal Wall Hernia: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 2 | 5 | 27 | 56
Age (years) | 12 to 24 | 1 | 2 | 4 | 8
Age (years) | 25 to 44 | 16 | 18 | 51 | 58
Age (years) | 45 to 54 | 22 | 53 | 65 | 155
Age (years) | 55 to 64 | 33 | 77 | 100 | 237
Age (years) | 65 to 74 | 31 | 100 | 97 | 319
Age (years) | 75 plus | 31 | 143 | 108 | 491
Race | White | 113 | 37 | 364 | 119
Race | Black | 17 | 39 | 68 | 153
Race | Other | 6 | 25 | 23 | 92
Ethnicity | Hispanic | 17 | 37 | 57 | 122
Ethnicity | Not Hispanic | 120 | 36 | 399 | 123
Sex | Female | 71 | 36 | 210 | 108
Sex | Male | 64 | 36 | 242 | 138
Total | | 135 | 36 | 452 | 121

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Abdominal wall hernia contributed to 452,000 hospital discharges in 2018 (Table 63). Hospital discharge rates (all-listed diagnoses) were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among men compared with women and Blacks compared with Whites but did not differ by ethnicity. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by 5% from 127 to 121.(4,6)

Table 64 Abdominal Wall Hernia: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 12 | 0.0 | 0.9 | 22 | 0.0 | 1.6
Age (years) | 12 to 24 | 4 | 0.0 | 0.2 | 9 | 0.0 | 0.5
Age (years) | 25 to 44 | 34 | 0.0 | 1.4 | 51 | 0.1 | 2.1
Age (years) | 45 to 54 | 87 | 0.2 | 2.7 | 154 | 0.4 | 4.8
Age (years) | 55 to 64 | 209 | 0.5 | 4.7 | 343 | 0.8 | 7.8
Age (years) | 65 to 74 | 328 | 1.0 | 5.1 | 548 | 1.7 | 8.6
Age (years) | 75 plus | 884 | 3.9 | 6.0 | 1,345 | 6.0 | 9.2
Race | White | 1,352 | 0.4 | 17.8 | 2,124 | 0.6 | 28.9
Race | Black | 166 | 0.4 | 2.7 | 272 | 0.7 | 4.5
Race | Other | 40 | 0.2 | 0.7 | 76 | 0.3 | 1.2
Ethnicity | Hispanic | 110 | 0.3 | 1.9 | 183 | 0.5 | 3.3
Ethnicity | Not Hispanic | 1,448 | 0.4 | 19.2 | 2,289 | 0.6 | 31.2
Sex | Female | 766 | 0.3 | 9.9 | 1,133 | 0.5 | 15.3
Sex | Male | 792 | 0.5 | 11.2 | 1,339 | 0.8 | 19.3
Total | | 1,558 | 0.4 | 21.1 | 2,472 | 0.6 | 34.6

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Abdominal wall hernia contributed to 2,000 deaths in 2019 (Table 64). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Blacks, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with abdominal hernia as underlying or other cause decreased by 14% from 0.7 to 0.6.(4)

Table 65 Abdominal Wall Hernia: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 2,295 | 0.2% | 7,404 | 0.7%
Age (years) | 12 to 24 | 1,451,892 | 1,172 | 0.1% | 1,650 | 0.1%
Age (years) | 25 to 44 | 2,656,672 | 9,438 | 0.4% | 14,243 | 0.5%
Age (years) | 45 to 54 | 1,452,320 | 9,486 | 0.7% | 15,840 | 1.1%
Age (years) | 55 to 64 | 1,640,216 | 14,120 | 0.9% | 24,223 | 1.5%
Age (years) | 65 to 74 | 2,840,615 | 25,399 | 0.9% | 43,577 | 1.5%
Age (years) | 75 plus | 2,576,241 | 21,367 | 0.8% | 40,099 | 1.6%
Race-ethnicity | White | 8,657,702 | 58,240 | 0.7% | 98,395 | 1.1%
Race-ethnicity | Black | 1,242,477 | 7,471 | 0.6% | 13,666 | 1.1%
Race-ethnicity | Hispanic | 1,493,457 | 8,382 | 0.6% | 15,699 | 1.1%
Race-ethnicity | Asian | 607,284 | 1,488 | 0.2% | 2,675 | 0.4%
Race-ethnicity | Unknown | 1,719,014 | 7,696 | 0.4% | 16,601 | 1.0%
Sex | Female | 7,199,363 | 25,247 | 0.4% | 48,911 | 0.7%
Sex | Male | 6,520,571 | 58,030 | 0.9% | 98,125 | 1.5%
Region | Northeast | 1,526,275 | 10,040 | 0.7% | 17,758 | 1.2%
Region | Midwest | 3,322,846 | 19,518 | 0.6% | 33,129 | 1.0%
Region | South | 5,619,435 | 34,651 | 0.6% | 62,930 | 1.1%
Region | West | 3,251,378 | 19,068 | 0.6% | 33,219 | 1.0%
Total | | 13,719,934 | 83,277 | 0.6% | 147,036 | 1.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of abdominal wall hernia (based on all-listed diagnoses) was 1.1% (Table 65). Prevalence was higher among children compared with adolescents and younger adults and then increased with age. It was higher among men. It was similar among Whites, Blacks, and Hispanics, and lowest among Asians. It differed little by region.

Table 66 Abdominal Wall Hernia: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 3,646 | 331 | 11,690 | 1,061
Age (years) | 12 to 24 | 2,088 | 144 | 2,869 | 198
Age (years) | 25 to 44 | 17,177 | 647 | 26,042 | 980
Age (years) | 45 to 54 | 17,590 | 1,211 | 29,299 | 2,017
Age (years) | 55 to 64 | 25,941 | 1,582 | 44,819 | 2,733
Age (years) | 65 to 74 | 45,825 | 1,613 | 79,931 | 2,814
Age (years) | 75 plus | 37,007 | 1,436 | 69,688 | 2,705
Race-ethnicity | White | 105,416 | 1,218 | 178,404 | 2,061
Race-ethnicity | Black | 12,994 | 1,046 | 24,102 | 1,940
Race-ethnicity | Hispanic | 14,757 | 988 | 28,056 | 1,879
Race-ethnicity | Asian | 2,750 | 453 | 4,822 | 794
Race-ethnicity | Unknown | 13,357 | 777 | 28,954 | 1,684
Sex | Female | 41,413 | 575 | 82,451 | 1,145
Sex | Male | 107,861 | 1,654 | 181,887 | 2,789
Region | Northeast | 17,803 | 1,166 | 31,852 | 2,087
Region | Midwest | 34,524 | 1,039 | 60,305 | 1,815
Region | South | 62,477 | 1,112 | 111,778 | 1,989
Region | West | 34,470 | 1,060 | 60,403 | 1,858
Total | | 149,274 | 1,088 | 264,338 | 1,927

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with abdominal wall hernia (all-listed diagnoses) were higher among children compared with adolescents and younger adults and then increased with age until 75 years (Table 66). They were higher among men compared with women. Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 67 Abdominal Wall Hernia: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 14 | 1 | 22 | 2
Age (years) | 12 to 24 | 8 | 1 | 10 | 1
Age (years) | 25 to 44 | 161 | 6 | 315 | 12
Age (years) | 45 to 54 | 225 | 15 | 433 | 30
Age (years) | 55 to 64 | 615 | 37 | 1,156 | 70
Age (years) | 65 to 74 | 1,832 | 64 | 3,394 | 119
Age (years) | 75 plus | 2,586 | 100 | 4,676 | 182
Race-ethnicity | White | 3,588 | 41 | 6,501 | 75
Race-ethnicity | Black | 708 | 57 | 1,335 | 107
Race-ethnicity | Hispanic | 591 | 40 | 1,176 | 79
Race-ethnicity | Asian | 69 | 11 | 121 | 20
Race-ethnicity | Unknown | 485 | 28 | 873 | 51
Sex | Female | 2,042 | 28 | 4,208 | 58
Sex | Male | 3,399 | 52 | 5,798 | 89
Region | Northeast | 820 | 54 | 1,294 | 85
Region | Midwest | 1,155 | 35 | 2,020 | 61
Region | South | 2,181 | 39 | 4,319 | 77
Region | West | 1,285 | 40 | 2,373 | 73
Total | | 5,441 | 40 | 10,006 | 73

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with abdominal wall hernia (all-listed diagnoses) increased with age and were higher among men compared with women (Table 67). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics and Whites, and much lower among Asians. Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 68 Abdominal Wall Hernia: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 16 | 1 | 415 | 38
Age (years) | 12 to 24 | 10 | 1 | 53 | 4
Age (years) | 25 to 44 | 223 | 8 | 871 | 33
Age (years) | 45 to 54 | 482 | 33 | 1,635 | 113
Age (years) | 55 to 64 | 970 | 59 | 3,389 | 207
Age (years) | 65 to 74 | 1,933 | 68 | 7,179 | 253
Age (years) | 75 plus | 2,341 | 91 | 9,115 | 354
Race-ethnicity | White | 4,088 | 47 | 14,889 | 172
Race-ethnicity | Black | 683 | 55 | 2,738 | 220
Race-ethnicity | Hispanic | 671 | 45 | 2,621 | 175
Race-ethnicity | Asian | 60 | 10 | 277 | 46
Race-ethnicity | Unknown | 473 | 28 | 2,132 | 124
Sex | Female | 3,355 | 47 | 10,764 | 150
Sex | Male | 2,620 | 40 | 11,893 | 182
Region | Northeast | 798 | 52 | 2,969 | 195
Region | Midwest | 1,292 | 39 | 4,713 | 142
Region | South | 2,656 | 47 | 10,418 | 185
Region | West | 1,229 | 38 | 4,557 | 140
Total | | 5,975 | 44 | 22,657 | 165

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with abdominal wall hernia (all-listed diagnoses) were higher among children compared with adolescents and younger adults and then increased with age and were higher among men compared with women (Table 68). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics and Whites, and much lower among Asians. Rates were highest in the Northeast, followed by the South, and lowest in the Midwest and West.

Table 69 Abdominal Wall Hernia: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 97,040 | 1.2% | 172,600 | 2.1%
Age (years) | 70 to 74 | 6,936,940 | 88,460 | 1.3% | 160,700 | 2.3%
Age (years) | 75 to 79 | 4,894,060 | 64,960 | 1.3% | 124,660 | 2.5%
Age (years) | 80 to 84 | 3,335,340 | 42,360 | 1.3% | 83,440 | 2.5%
Age (years) | 85+ | 3,578,120 | 37,000 | 1.0% | 83,860 | 2.3%
Race | White | 22,023,800 | 279,360 | 1.3% | 527,980 | 2.4%
Race | Black | 1,861,660 | 17,580 | 0.9% | 36,220 | 1.9%
Race | Other | 2,925,320 | 32,880 | 1.1% | 61,060 | 2.1%
Sex | Female | 14,975,560 | 104,140 | 0.7% | 218,560 | 1.5%
Sex | Male | 11,835,220 | 225,680 | 1.9% | 406,700 | 3.4%
Region | Northeast | 4,748,700 | 61,540 | 1.3% | 121,220 | 2.6%
Region | Midwest | 6,069,800 | 71,240 | 1.2% | 134,160 | 2.2%
Region | South | 10,595,900 | 127,460 | 1.2% | 244,080 | 2.3%
Region | West | 5,396,380 | 69,580 | 1.3% | 125,800 | 2.3%
Total | | 26,810,780 | 329,820 | 1.2% | 625,260 | 2.3%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of abdominal wall hernia (based on all-listed diagnoses) was 2.3% (Table 69). Prevalence was highest among persons 75–84 years and was higher among men and Whites. It was higher in the Northeast compared to other regions.

Table 70 Abdominal Wall Hernia: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 176,900 | 2,193 | 313,600 | 3,888
Age (years) | 70 to 74 | 161,920 | 2,334 | 291,860 | 4,207
Age (years) | 75 to 79 | 116,000 | 2,370 | 218,780 | 4,470
Age (years) | 80 to 84 | 73,800 | 2,213 | 144,340 | 4,328
Age (years) | 85+ | 54,140 | 1,513 | 119,120 | 3,329
Race | White | 496,400 | 2,254 | 919,520 | 4,175
Race | Black | 27,700 | 1,488 | 57,620 | 3,095
Race | Other | 58,660 | 2,005 | 110,560 | 3,779
Sex | Female | 164,580 | 1,099 | 342,560 | 2,287
Sex | Male | 418,180 | 3,533 | 745,140 | 6,296
Region | Northeast | 109,020 | 2,296 | 211,560 | 4,455
Region | Midwest | 123,680 | 2,038 | 231,100 | 3,807
Region | South | 227,320 | 2,145 | 416,720 | 3,933
Region | West | 122,740 | 2,274 | 228,320 | 4,231
Total | | 582,760 | 2,174 | 1,087,700 | 4,057

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with abdominal wall hernia (all-listed diagnoses) peaked among persons 75 to 79 years and were over twice as high among men compared with women and Whites compared with Blacks (Table 70). Rates were highest in the Northeast, followed by the West, then the South, and lowest in the Midwest.

Table 71 Abdominal Wall Hernia: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 13,280 | 165 | 37,340 | 463
Age (years) | 70 to 74 | 13,900 | 200 | 38,220 | 551
Age (years) | 75 to 79 | 11,300 | 231 | 33,340 | 681
Age (years) | 80 to 84 | 8,900 | 267 | 27,800 | 833
Age (years) | 85+ | 12,180 | 340 | 37,160 | 1,039
Race | White | 48,080 | 218 | 141,060 | 640
Race | Black | 5,520 | 297 | 15,820 | 850
Race | Other | 5,960 | 204 | 16,980 | 580
Sex | Female | 25,280 | 169 | 76,720 | 512
Sex | Male | 34,280 | 290 | 97,140 | 821
Region | Northeast | 12,420 | 262 | 34,600 | 729
Region | Midwest | 13,420 | 221 | 37,060 | 611
Region | South | 22,140 | 209 | 69,420 | 655
Region | West | 11,580 | 215 | 32,780 | 607
Total | | 59,560 | 222 | 173,860 | 648

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with abdominal wall hernia (all-listed diagnoses) increased with age and were higher among men compared with women and Blacks compared with Whites (Table 71). Rates were highest in the Northeast, followed by the South, and lowest in the Midwest and West.

Table 72 Abdominal Wall Hernia: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 7,840 | 97 | 26,380 | 327
Age (years) | 70 to 74 | 7,780 | 112 | 26,140 | 377
Age (years) | 75 to 79 | 6,560 | 134 | 23,440 | 479
Age (years) | 80 to 84 | 5,140 | 154 | 18,140 | 544
Age (years) | 85+ | 5,640 | 158 | 21,720 | 607
Race | White | 27,220 | 124 | 95,320 | 433
Race | Black | 2,540 | 136 | 9,500 | 510
Race | Other | 3,200 | 109 | 11,000 | 376
Sex | Female | 18,060 | 121 | 55,960 | 374
Sex | Male | 14,900 | 126 | 59,860 | 506
Region | Northeast | 6,500 | 137 | 21,880 | 461
Region | Midwest | 7,380 | 122 | 25,740 | 424
Region | South | 13,520 | 128 | 47,640 | 450
Region | West | 5,560 | 103 | 20,560 | 381
Total | | 32,960 | 123 | 115,820 | 432

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with abdominal wall hernia (all-listed diagnoses) increased with age and were higher among men compared with women and Blacks compared with Whites (Table 72). Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.