# Chapter 5 Appendicitis

Table 49 Appendicitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 35 | 72 | 40 | 82
Age (years) | 12 to 24 | 135 | 240 | 155 | 277
Age (years) | 25 to 44 | 125 | 148 | 166 | 197
Age (years) | 45 to 54 | 65 | 151 | 74 | 172
Age (years) | 55 to 64 | 204 | 501 | 223 | 546
Age (years) | 65 to 74 | 75 | 274 | 77 | 281
Age (years) | 75 plus | 3 | 17 | 3 | 17
Race | White | 539 | 194 | 601 | 220
Race | Black | 39 | 83 | 70 | 152
Race | Other | 65 | 258 | 67 | 269
Ethnicity | Hispanic | 230 | 464 | 245 | 490
Ethnicity | Not Hispanic | 412 | 151 | 494 | 181
Sex | Female | 296 | 170 | 325 | 189
Sex | Male | 346 | 195 | 414 | 236
Total | | 643 | 182 | 739 | 212

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Appendicitis contributed to 739,000 ambulatory visits (2015) (Table 49). Ambulatory care visit rates (all-listed diagnoses) were highest among persons 55–64 years and lowest among those 75 years and over. Age-adjusted ambulatory care visit rates were higher among men compared with women, Whites compared with Blacks, and Hispanics compared with non-Hispanics.

Table 50 Appendicitis: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 52 | 108 | 55 | 113
Age (years) | 12 to 24 | 108 | 196 | 115 | 208
Age (years) | 25 to 44 | 112 | 129 | 123 | 141
Age (years) | 45 to 54 | 43 | 104 | 48 | 115
Age (years) | 55 to 64 | 35 | 83 | 41 | 96
Age (years) | 65 to 74 | 21 | 68 | 25 | 83
Age (years) | 75 plus | 10 | 47 | 14 | 66
Sex | Female | 177 | 111 | 198 | 123
Sex | Male | 205 | 131 | 223 | 142
Total | | 382 | 121 | 421 | 133

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Appendicitis contributed to 421,000 emergency department visits in 2018 (Table 50). Emergency department visit rates (all-listed diagnoses) peaked among persons 12–24 years and then decreased with age. Age-adjusted rates were higher among men compared with women.

Table 51 Appendicitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 22 | 46 | 24 | 50
Age (years) | 12 to 24 | 36 | 64 | 40 | 72
Age (years) | 25 to 44 | 41 | 47 | 49 | 56
Age (years) | 45 to 54 | 20 | 48 | 25 | 60
Age (years) | 55 to 64 | 19 | 45 | 25 | 58
Age (years) | 65 to 74 | 14 | 45 | 18 | 60
Age (years) | 75 plus | 8 | 38 | 12 | 56
Race | White | 131 | 53 | 159 | 63
Race | Black | 12 | 27 | 16 | 36
Race | Other | 16 | 63 | 19 | 74
Ethnicity | Hispanic | 41 | 66 | 48 | 79
Ethnicity | Not Hispanic | 119 | 45 | 147 | 54
Sex | Female | 73 | 44 | 91 | 54
Sex | Male | 86 | 54 | 103 | 64
Total | | 159 | 49 | 193 | 59

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Appendicitis contributed to 193,000 hospital discharges in 2018 (Table 51). Hospital discharge rates (all-listed diagnoses) peaked at 12–24 years and were similar for other age groups. Age-adjusted rates were higher among men compared with women, Whites compared with Blacks, and Hispanics compared with non-Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by 47% from 111 to 59. (4,6)

Table 52 Appendicitis: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 6 | 0.0 | 0.4 | 10 | 0.0 | 0.7
Age (years) | 12 to 24 | 7 | 0.0 | 0.4 | 14 | 0.0 | 0.9
Age (years) | 25 to 44 | 24 | 0.0 | 1.0 | 38 | 0.0 | 1.6
Age (years) | 45 to 54 | 22 | 0.1 | 0.7 | 54 | 0.1 | 1.7
Age (years) | 55 to 64 | 54 | 0.1 | 1.3 | 126 | 0.3 | 2.9
Age (years) | 65 to 74 | 77 | 0.2 | 1.2 | 153 | 0.5 | 2.4
Age (years) | 75 plus | 201 | 0.9 | 1.4 | 336 | 1.5 | 2.4
Race | White | 328 | 0.1 | 5.1 | 619 | 0.2 | 10.2
Race | Black | 42 | 0.1 | 1.0 | 73 | 0.2 | 1.7
Race | Other | 21 | 0.1 | 0.3 | 39 | 0.2 | 0.7
Ethnicity | Hispanic | 33 | 0.1 | 0.9 | 70 | 0.2 | 1.9
Ethnicity | Not Hispanic | 358 | 0.1 | 5.6 | 661 | 0.2 | 10.7
Sex | Female | 177 | 0.1 | 2.7 | 336 | 0.2 | 5.8
Sex | Male | 214 | 0.1 | 3.7 | 395 | 0.2 | 6.8
Total | | 391 | 0.1 | 6.4 | 731 | 0.2 | 12.6

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Appendicitis contributed to 1,000 deaths in 2019 (Table 52). Mortality was uncommon through young adulthood after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates did not differ by sex, race, or ethnicity. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with appendicitis as underlying or other cause decreased by a third from 0.3 to 0.2.(4)

Table 53 Appendicitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 847 | 0.1% | 892 | 0.1%
Age (years) | 12 to 24 | 1,451,892 | 2,688 | 0.2% | 2,879 | 0.2%
Age (years) | 25 to 44 | 2,656,672 | 4,184 | 0.2% | 4,672 | 0.2%
Age (years) | 45 to 54 | 1,452,320 | 1,873 | 0.1% | 2,144 | 0.1%
Age (years) | 55 to 64 | 1,640,216 | 1,842 | 0.1% | 2,236 | 0.1%
Age (years) | 65 to 74 | 2,840,615 | 2,387 | 0.1% | 3,119 | 0.1%
Age (years) | 75 plus | 2,576,241 | 1,510 | 0.1% | 2,173 | 0.1%
Race-ethnicity | White | 8,657,702 | 10,198 | 0.1% | 12,007 | 0.1%
Race-ethnicity | Black | 1,242,477 | 1,000 | 0.1% | 1,298 | 0.1%
Race-ethnicity | Hispanic | 1,493,457 | 1,941 | 0.1% | 2,280 | 0.2%
Race-ethnicity | Asian | 607,284 | 541 | 0.1% | 623 | 0.1%
Race-ethnicity | Unknown | 1,719,014 | 1,651 | 0.1% | 1,907 | 0.1%
Sex | Female | 7,199,363 | 7,551 | 0.1% | 9,171 | 0.1%
Sex | Male | 6,520,571 | 7,780 | 0.1% | 8,944 | 0.1%
Region | Northeast | 1,526,275 | 1,556 | 0.1% | 1,908 | 0.1%
Region | Midwest | 3,322,846 | 4,273 | 0.1% | 4,873 | 0.1%
Region | South | 5,619,435 | 6,246 | 0.1% | 7,488 | 0.1%
Region | West | 3,251,378 | 3,256 | 0.1% | 3,846 | 0.1%
Total | | 13,719,934 | 15,331 | 0.1% | 18,115 | 0.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of appendicitis (based on all-listed diagnoses) was 0.1% (Table 53). Prevalence was highest among adolescents and younger adults and did not differ by sex. It was highest among Hispanics and similar among Whites, Blacks, and Asians. It did not differ by region.

Table 54 Appendicitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 1,105 | 100 | 1,191 | 108
Age (years) | 12 to 24 | 3,575 | 246 | 3,879 | 267
Age (years) | 25 to 44 | 5,492 | 207 | 6,210 | 234
Age (years) | 45 to 54 | 2,503 | 172 | 2,938 | 202
Age (years) | 55 to 64 | 2,313 | 141 | 2,821 | 172
Age (years) | 65 to 74 | 2,725 | 96 | 3,445 | 121
Age (years) | 75 plus | 1,750 | 68 | 2,517 | 98
Race-ethnicity | White | 12,963 | 150 | 15,250 | 176
Race-ethnicity | Black | 1,274 | 103 | 1,576 | 127
Race-ethnicity | Hispanic | 2,447 | 164 | 2,924 | 196
Race-ethnicity | Asian | 689 | 113 | 809 | 133
Race-ethnicity | Unknown | 2,090 | 122 | 2,442 | 142
Sex | Female | 9,717 | 135 | 11,752 | 163
Sex | Male | 9,746 | 149 | 11,249 | 173
Region | Northeast | 2,113 | 138 | 2,566 | 168
Region | Midwest | 5,385 | 162 | 6,135 | 185
Region | South | 7,960 | 142 | 9,527 | 170
Region | West | 4,005 | 123 | 4,773 | 147
Total | | 19,463 | 142 | 23,001 | 168

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with appendicitis (all-listed diagnoses) peaked among adolescents and the youngest adults and then decreased with age and were higher among men compared with women (Table 54). Among persons with known race-ethnicity, rates were highest among Hispanics, followed by Whites, then Asians, and lowest among Blacks. Rates were highest in the Midwest, followed by the South and Northeast, and lowest in the West.

Table 55 Appendicitis: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 36 | 3 | 39 | 4
Age (years) | 12 to 24 | 151 | 10 | 173 | 12
Age (years) | 25 to 44 | 257 | 10 | 306 | 12
Age (years) | 45 to 54 | 174 | 12 | 214 | 15
Age (years) | 55 to 64 | 302 | 18 | 388 | 24
Age (years) | 65 to 74 | 1,382 | 49 | 1,805 | 64
Age (years) | 75 plus | 896 | 35 | 1,209 | 47
Race-ethnicity | White | 2,196 | 25 | 2,822 | 33
Race-ethnicity | Black | 222 | 18 | 335 | 27
Race-ethnicity | Hispanic | 381 | 26 | 496 | 33
Race-ethnicity | Asian | 121 | 20 | 137 | 23
Race-ethnicity | Unknown | 278 | 16 | 344 | 20
Sex | Female | 1,737 | 24 | 2,267 | 31
Sex | Male | 1,461 | 22 | 1,867 | 29
Region | Northeast | 375 | 25 | 440 | 29
Region | Midwest | 917 | 28 | 1,087 | 33
Region | South | 1,109 | 20 | 1,549 | 28
Region | West | 797 | 25 | 1,058 | 33
Total | | 3,198 | 23 | 4,134 | 30

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with appendicitis (all-listed diagnoses) increased with age until 75 years and were higher among women compared with men (Table 55). Among persons with known race-ethnicity, rates were highest among Whites and Hispanics, followed by Blacks, and lowest among Asians. Rates were higher in the Midwest and West compared with the Northeast and South.

Table 56 Appendicitis: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 256 | 23 | 287 | 26
Age (years) | 12 to 24 | 409 | 28 | 504 | 35
Age (years) | 25 to 44 | 586 | 22 | 873 | 33
Age (years) | 45 to 54 | 394 | 27 | 609 | 42
Age (years) | 55 to 64 | 524 | 32 | 873 | 53
Age (years) | 65 to 74 | 899 | 32 | 1,572 | 55
Age (years) | 75 plus | 751 | 29 | 1,368 | 53
Race-ethnicity | White | 2,486 | 29 | 3,980 | 46
Race-ethnicity | Black | 289 | 23 | 552 | 44
Race-ethnicity | Hispanic | 506 | 34 | 766 | 51
Race-ethnicity | Asian | 155 | 26 | 207 | 34
Race-ethnicity | Unknown | 383 | 22 | 581 | 34
Sex | Female | 1,847 | 26 | 3,029 | 42
Sex | Male | 1,972 | 30 | 3,057 | 47
Region | Northeast | 493 | 32 | 769 | 50
Region | Midwest | 918 | 28 | 1,450 | 44
Region | South | 1,538 | 27 | 2,501 | 45
Region | West | 870 | 27 | 1,366 | 42
Total | | 3,819 | 28 | 6,086 | 44

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with appendicitis (all-listed diagnoses) generally increased with age and were higher among men compared with women (Table 56). Among persons with known race-ethnicity, rates were highest among Hispanics, followed by Whites and Blacks, and lowest among Asians. Rates were highest in the Northeast, followed by the South and Midwest, and lowest in the West.

Table 57 Appendicitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 8,880 | 0.1% | 10,440 | 0.1%
Age (years) | 70 to 74 | 6,936,940 | 6,960 | 0.1% | 8,720 | 0.1%
Age (years) | 75 to 79 | 4,894,060 | 4,160 | 0.1% | 5,560 | 0.1%
Age (years) | 80 to 84 | 3,335,340 | 2,220 | 0.1% | 2,900 | 0.1%
Age (years) | 85+ | 3,578,120 | 2,100 | 0.1% | 2,940 | 0.1%
Race | White | 22,023,800 | 20,360 | 0.1% | 25,260 | 0.1%
Race | Black | 1,861,660 | 1,060 | 0.1% | 1,500 | 0.1%
Race | Other | 2,925,320 | 2,900 | 0.1% | 3,800 | 0.1%
Sex | Female | 14,975,560 | 13,420 | 0.1% | 16,720 | 0.1%
Sex | Male | 11,835,220 | 10,900 | 0.1% | 13,840 | 0.1%
Region | Northeast | 4,748,700 | 4,060 | 0.1% | 5,040 | 0.1%
Region | Midwest | 6,069,800 | 5,280 | 0.1% | 6,560 | 0.1%
Region | South | 10,595,900 | 9,680 | 0.1% | 12,300 | 0.1%
Region | West | 5,396,380 | 5,300 | 0.1% | 6,660 | 0.1%
Total | | 26,810,780 | 24,320 | 0.1% | 30,560 | 0.1%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of appendicitis (based on all-listed diagnoses) was 0.1% (Table 57). Prevalence did not differ by age, sex, or race. It did not differ by region.

Table 58 Appendicitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 8,880 | 110 | 11,680 | 145
Age (years) | 70 to 74 | 7,320 | 106 | 10,020 | 144
Age (years) | 75 to 79 | 4,140 | 85 | 6,100 | 125
Age (years) | 80 to 84 | 1,980 | 59 | 3,500 | 105
Age (years) | 85+ | 2,380 | 67 | 3,660 | 102
Race | White | 21,080 | 96 | 29,600 | 134
Race | Black | 1,140 | 61 | 1,700 | 91
Race | Other | 2,480 | 85 | 3,660 | 125
Sex | Female | 13,720 | 92 | 19,500 | 130
Sex | Male | 10,980 | 93 | 15,460 | 131
Region | Northeast | 4,380 | 92 | 6,000 | 126
Region | Midwest | 5,240 | 86 | 7,780 | 128
Region | South | 10,100 | 95 | 13,780 | 130
Region | West | 4,980 | 92 | 7,400 | 137
Total | | 24,700 | 92 | 34,960 | 130

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with appendicitis (all-listed diagnoses) decreased with age, differed little by sex, and were higher among Whites compared with Blacks (Table 58). Rates were highest in the West, followed by the South, then the Midwest, and lowest in the Northeast.

Table 59 Appendicitis: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 8,040 | 100 | 9,080 | 113
Age (years) | 70 to 74 | 6,020 | 87 | 7,500 | 108
Age (years) | 75 to 79 | 3,640 | 74 | 4,600 | 94
Age (years) | 80 to 84 | 1,760 | 53 | 2,220 | 67
Age (years) | 85+ | 1,940 | 54 | 2,600 | 73
Race | White | 17,780 | 81 | 21,300 | 97
Race | Black | 1,000 | 54 | 1,360 | 73
Race | Other | 2,620 | 90 | 3,340 | 114
Sex | Female | 11,680 | 78 | 13,980 | 93
Sex | Male | 9,720 | 82 | 12,020 | 102
Region | Northeast | 3,760 | 79 | 4,640 | 98
Region | Midwest | 4,280 | 71 | 5,220 | 86
Region | South | 8,640 | 82 | 10,500 | 99
Region | West | 4,720 | 87 | 5,640 | 105
Total | | 21,400 | 80 | 26,000 | 97

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with appendicitis (all-listed diagnoses) decreased with age until 85 years and were higher among men compared with women and Whites compared with Blacks (Table 59). Rates were highest in the West, followed by the South and Northeast, and lowest in the Midwest.

Table 60 Appendicitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 4,240 | 53 | 5,360 | 66
Age (years) | 70 to 74 | 3,460 | 50 | 4,940 | 71
Age (years) | 75 to 79 | 2,020 | 41 | 3,280 | 67
Age (years) | 80 to 84 | 1,360 | 41 | 1,820 | 55
Age (years) | 85+ | 1,040 | 29 | 1,920 | 54
Race | White | 9,820 | 45 | 13,920 | 63
Race | Black | 760 | 41 | 1,100 | 59
Race | Other | 1,540 | 53 | 2,300 | 79
Sex | Female | 6,600 | 44 | 9,180 | 61
Sex | Male | 5,520 | 47 | 8,140 | 69
Region | Northeast | 2,160 | 45 | 3,000 | 63
Region | Midwest | 2,540 | 42 | 3,560 | 59
Region | South | 4,840 | 46 | 6,960 | 66
Region | West | 2,580 | 48 | 3,800 | 70
Total | | 12,120 | 45 | 17,320 | 65

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with appendicitis (all-listed diagnoses) peaked among persons 70 to 74 years and were higher among men compared with women and Whites compared with Blacks (Table 60). Rates were highest in the West, followed by the South, then the Northeast, and lowest in the Midwest.