# Chapter 4 Functional Disorders

Table 37 Functional Disorders: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 871 | 1,790 | 1,815 | 3,732
Age (years) | 12 to 24 | 444 | 791 | 991 | 1,765
Age (years) | 25 to 44 | 577 | 683 | 2,304 | 2,727
Age (years) | 45 to 54 | 444 | 1,030 | 1,921 | 4,459
Age (years) | 55 to 64 | 299 | 732 | 1,770 | 4,336
Age (years) | 65 to 74 | 612 | 2,224 | 1,571 | 5,707
Age (years) | 75 plus | 664 | 3,287 | 1,862 | 9,215
Race | White | 2,837 | 1,128 | 9,633 | 3,626
Race | Black | 772 | 1,882 | 1,833 | 4,388
Race | Other | 301 | 1,488 | 768 | 3,504
Ethnicity | Hispanic | 874 | 1,923 | 2,434 | 5,097
Ethnicity | Not Hispanic | 3,036 | 1,125 | 9,800 | 3,498
Sex | Female | 2,298 | 1,407 | 8,394 | 4,921
Sex | Male | 1,613 | 1,069 | 3,841 | 2,479
Total | | 3,910 | 1,230 | 12,234 | 3,707

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Functional disorders contributed to 12.2 million ambulatory visits (2015) (Table 37). Ambulatory care visit rates (all-listed diagnoses) were higher among children compared with adolescents and younger adults and then generally increased with age. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 38 Functional Disorders: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 356 | 736 | 588 | 1,214
Age (years) | 12 to 24 | 174 | 313 | 416 | 750
Age (years) | 25 to 44 | 205 | 236 | 791 | 909
Age (years) | 45 to 54 | 108 | 258 | 494 | 1,186
Age (years) | 55 to 64 | 124 | 292 | 612 | 1,448
Age (years) | 65 to 74 | 126 | 414 | 614 | 2,014
Age (years) | 75 plus | 190 | 864 | 952 | 4,341
Sex | Female | 727 | 440 | 2,713 | 1,522
Sex | Male | 554 | 348 | 1,753 | 1,062
Total | | 1,282 | 393 | 4,467 | 1,294

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Functional disorders contributed to 4.5 million emergency department visits in 2018 (Table 38). Emergency department visit rates (all-listed diagnoses) were higher among children compared with adolescents and younger adults and then generally increased with age. Age-adjusted rates were higher among women compared with men.

Table 39 Functional Disorders: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 10 | 22 | 82 | 170
Age (years) | 12 to 24 | 9 | 16 | 114 | 205
Age (years) | 25 to 44 | 21 | 24 | 356 | 409
Age (years) | 45 to 54 | 17 | 40 | 298 | 716
Age (years) | 55 to 64 | 23 | 54 | 466 | 1,103
Age (years) | 65 to 74 | 24 | 77 | 520 | 1,704
Age (years) | 75 plus | 27 | 125 | 736 | 3,354
Race | White | 103 | 36 | 2,023 | 668
Race | Black | 20 | 46 | 419 | 957
Race | Other | 8 | 31 | 150 | 604
Ethnicity | Hispanic | 15 | 31 | 263 | 571
Ethnicity | Not Hispanic | 116 | 38 | 2,329 | 725
Sex | Female | 76 | 41 | 1,509 | 771
Sex | Male | 54 | 32 | 1,062 | 614
Total | | 130 | 37 | 2,571 | 695

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Functional disorders contributed to 2.6 million hospital discharges in 2018 (Table 39). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by 64% from 423 to 695.(4)

Table 40 Functional Disorders: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 13 | 0.0 | 1.0 | 39 | 0.1 | 2.9
Age (years) | 12 to 24 | 11 | 0.0 | 0.6 | 41 | 0.1 | 2.5
Age (years) | 25 to 44 | 43 | 0.0 | 1.9 | 179 | 0.2 | 8.0
Age (years) | 45 to 54 | 59 | 0.1 | 1.8 | 252 | 0.6 | 7.9
Age (years) | 55 to 64 | 127 | 0.3 | 2.9 | 598 | 1.4 | 13.8
Age (years) | 65 to 74 | 207 | 0.7 | 3.3 | 924 | 2.9 | 14.6
Age (years) | 75 plus | 493 | 2.2 | 3.3 | 2,259 | 10.0 | 15.3
Race | White | 835 | 0.2 | 12.5 | 3,717 | 1.1 | 54.3
Race | Black | 99 | 0.2 | 2.1 | 436 | 1.0 | 8.3
Race | Other | 19 | 0.1 | 0.3 | 139 | 0.6 | 2.3
Ethnicity | Hispanic | 48 | 0.1 | 1.2 | 254 | 0.6 | 6.0
Ethnicity | Not Hispanic | 905 | 0.3 | 13.7 | 4,038 | 1.1 | 59.0
Sex | Female | 589 | 0.3 | 8.6 | 2,536 | 1.1 | 36.8
Sex | Male | 364 | 0.2 | 6.3 | 1,756 | 1.0 | 28.2
Total | | 953 | 0.2 | 14.9 | 4,292 | 1.1 | 64.9

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Functional disorders contributed to 4,000 deaths in 2019 (Table 40). Mortality rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among women, Whites, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with functional disorders as underlying or other cause increased by 57% from 0.7 to 1.1.(4)

Table 41 Functional Disorders: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 17,221 | 1.6% | 41,010 | 3.7%
Age (years) | 12 to 24 | 1,451,892 | 12,495 | 0.9% | 31,145 | 2.1%
Age (years) | 25 to 44 | 2,656,672 | 24,790 | 0.9% | 71,710 | 2.7%
Age (years) | 45 to 54 | 1,452,320 | 18,234 | 1.3% | 59,554 | 4.1%
Age (years) | 55 to 64 | 1,640,216 | 26,001 | 1.6% | 89,930 | 5.5%
Age (years) | 65 to 74 | 2,840,615 | 53,853 | 1.9% | 179,930 | 6.3%
Age (years) | 75 plus | 2,576,241 | 65,723 | 2.6% | 227,352 | 8.8%
Race-ethnicity | White | 8,657,702 | 135,735 | 1.6% | 444,685 | 5.1%
Race-ethnicity | Black | 1,242,477 | 25,978 | 2.1% | 84,337 | 6.8%
Race-ethnicity | Hispanic | 1,493,457 | 23,554 | 1.6% | 74,925 | 5.0%
Race-ethnicity | Asian | 607,284 | 6,968 | 1.1% | 21,398 | 3.5%
Race-ethnicity | Unknown | 1,719,014 | 26,082 | 1.5% | 75,286 | 4.4%
Sex | Female | 7,199,363 | 142,418 | 2.0% | 458,945 | 6.4%
Sex | Male | 6,520,571 | 75,899 | 1.2% | 241,686 | 3.7%
Region | Northeast | 1,526,275 | 30,308 | 2.0% | 90,664 | 5.9%
Region | Midwest | 3,322,846 | 43,513 | 1.3% | 146,587 | 4.4%
Region | South | 5,619,435 | 102,125 | 1.8% | 325,473 | 5.8%
Region | West | 3,251,378 | 42,371 | 1.3% | 137,907 | 4.2%
Total | | 13,719,934 | 218,317 | 1.6% | 700,631 | 5.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of functional disorders (based on all-listed diagnoses) was 5.1% (Table 41). Prevalence was higher among children compared with adolescents and younger adults and then increased with age. It was higher among women. It was highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. It was higher in the Northeast and South compared with the Midwest and West.

Table 42 Functional Disorders: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 22,308 | 2,024 | 57,585 | 5,226
Age (years) | 12 to 24 | 16,865 | 1,162 | 45,951 | 3,165
Age (years) | 25 to 44 | 33,288 | 1,253 | 112,940 | 4,251
Age (years) | 45 to 54 | 24,548 | 1,690 | 98,347 | 6,772
Age (years) | 55 to 64 | 34,877 | 2,126 | 148,806 | 9,072
Age (years) | 65 to 74 | 71,228 | 2,507 | 288,154 | 10,144
Age (years) | 75 plus | 89,635 | 3,479 | 393,339 | 15,268
Race-ethnicity | White | 182,846 | 2,112 | 726,991 | 8,397
Race-ethnicity | Black | 35,038 | 2,820 | 141,648 | 11,400
Race-ethnicity | Hispanic | 31,103 | 2,083 | 122,070 | 8,174
Race-ethnicity | Asian | 8,907 | 1,467 | 33,771 | 5,561
Race-ethnicity | Unknown | 34,855 | 2,028 | 120,642 | 7,018
Sex | Female | 193,110 | 2,682 | 775,604 | 10,773
Sex | Male | 99,639 | 1,528 | 369,518 | 5,667
Region | Northeast | 42,798 | 2,804 | 155,976 | 10,219
Region | Midwest | 56,744 | 1,708 | 225,756 | 6,794
Region | South | 136,425 | 2,428 | 537,446 | 9,564
Region | West | 56,782 | 1,746 | 225,944 | 6,949
Total | | 292,749 | 2,134 | 1,145,122 | 8,346

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with functional disorders (all-listed diagnoses) were higher among children compared with adolescents and younger adults and then increased with age and were higher among women compared with men (Table 42). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, and lowest in the West and Midwest.

Table 43 Functional Disorders: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 114 | 10 | 206 | 19
Age (years) | 12 to 24 | 131 | 9 | 393 | 27
Age (years) | 25 to 44 | 815 | 31 | 2,277 | 86
Age (years) | 45 to 54 | 1,028 | 71 | 2,428 | 167
Age (years) | 55 to 64 | 2,300 | 140 | 4,773 | 291
Age (years) | 65 to 74 | 6,666 | 235 | 13,039 | 459
Age (years) | 75 plus | 10,824 | 420 | 21,223 | 824
Race-ethnicity | White | 13,484 | 156 | 27,644 | 319
Race-ethnicity | Black | 4,044 | 325 | 7,784 | 626
Race-ethnicity | Hispanic | 2,057 | 138 | 4,333 | 290
Race-ethnicity | Asian | 425 | 70 | 831 | 137
Race-ethnicity | Unknown | 1,868 | 109 | 3,747 | 218
Sex | Female | 12,091 | 168 | 25,602 | 356
Sex | Male | 9,787 | 150 | 18,737 | 287
Region | Northeast | 3,077 | 202 | 5,609 | 367
Region | Midwest | 4,506 | 136 | 8,761 | 264
Region | South | 10,174 | 181 | 21,045 | 375
Region | West | 4,121 | 127 | 8,924 | 274
Total | | 21,878 | 159 | 44,339 | 323

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with functional disorders (all-listed diagnoses) increased with age and were higher among women compared with men (Table 43). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 44 Functional Disorders: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 81 | 7 | 1,222 | 111
Age (years) | 12 to 24 | 120 | 8 | 2,601 | 179
Age (years) | 25 to 44 | 318 | 12 | 6,990 | 263
Age (years) | 45 to 54 | 387 | 27 | 8,714 | 600
Age (years) | 55 to 64 | 684 | 42 | 19,259 | 1,174
Age (years) | 65 to 74 | 1,219 | 43 | 40,825 | 1,437
Age (years) | 75 plus | 1,517 | 59 | 60,455 | 2,347
Race-ethnicity | White | 2,894 | 33 | 92,269 | 1,066
Race-ethnicity | Black | 553 | 45 | 20,808 | 1,675
Race-ethnicity | Hispanic | 405 | 27 | 12,692 | 850
Race-ethnicity | Asian | 93 | 15 | 2,846 | 469
Race-ethnicity | Unknown | 381 | 22 | 11,451 | 666
Sex | Female | 2,521 | 35 | 81,522 | 1,132
Sex | Male | 1,805 | 28 | 58,544 | 898
Region | Northeast | 611 | 40 | 18,619 | 1,220
Region | Midwest | 919 | 28 | 30,462 | 917
Region | South | 1,985 | 35 | 66,446 | 1,182
Region | West | 811 | 25 | 24,539 | 755
Total | | 4,326 | 32 | 140,066 | 1,021

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with functional disorders (all-listed diagnoses) increased with age and were higher among women compared with men (Table 44). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 45 Functional Disorders: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 200,600 | 2.5% | 651,060 | 8.1%
Age (years) | 70 to 74 | 6,936,940 | 211,120 | 3.0% | 672,680 | 9.7%
Age (years) | 75 to 79 | 4,894,060 | 185,700 | 3.8% | 584,700 | 11.9%
Age (years) | 80 to 84 | 3,335,340 | 149,220 | 4.5% | 487,200 | 14.6%
Age (years) | 85+ | 3,578,120 | 192,180 | 5.4% | 644,840 | 18.0%
Race | White | 22,023,800 | 760,060 | 3.5% | 2,477,760 | 11.3%
Race | Black | 1,861,660 | 78,480 | 4.2% | 242,680 | 13.0%
Race | Other | 2,925,320 | 100,280 | 3.4% | 320,040 | 10.9%
Sex | Female | 14,975,560 | 609,300 | 4.1% | 1,981,680 | 13.2%
Sex | Male | 11,835,220 | 329,520 | 2.8% | 1,058,800 | 8.9%
Region | Northeast | 4,748,700 | 183,080 | 3.9% | 565,260 | 11.9%
Region | Midwest | 6,069,800 | 185,320 | 3.1% | 648,220 | 10.7%
Region | South | 10,595,900 | 399,780 | 3.8% | 1,286,480 | 12.1%
Region | West | 5,396,380 | 170,640 | 3.2% | 540,520 | 10.0%
Total | | 26,810,780 | 938,820 | 3.5% | 3,040,480 | 11.3%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of functional disorders (based on all-listed diagnoses) was 11.3% (Table 45). Prevalence increased with age and was higher among women and Blacks. It was highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 46 Functional Disorders: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 246,240 | 3,053 | 1,048,200 | 12,995
Age (years) | 70 to 74 | 263,460 | 3,798 | 1,102,520 | 15,893
Age (years) | 75 to 79 | 233,340 | 4,768 | 979,480 | 20,014
Age (years) | 80 to 84 | 190,220 | 5,703 | 834,440 | 25,018
Age (years) | 85+ | 250,060 | 6,989 | 1,238,160 | 34,604
Race | White | 962,360 | 4,370 | 4,196,640 | 19,055
Race | Black | 94,800 | 5,092 | 431,000 | 23,151
Race | Other | 126,160 | 4,313 | 575,160 | 19,661
Sex | Female | 801,320 | 5,351 | 3,560,620 | 23,776
Sex | Male | 382,000 | 3,228 | 1,642,180 | 13,875
Region | Northeast | 245,840 | 5,177 | 1,012,540 | 21,322
Region | Midwest | 221,640 | 3,652 | 1,048,280 | 17,270
Region | South | 506,440 | 4,780 | 2,235,620 | 21,099
Region | West | 209,400 | 3,880 | 906,360 | 16,796
Total | | 1,183,320 | 4,414 | 5,202,800 | 19,406

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with functional disorders (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 46). Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 47 Functional Disorders: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 43,220 | 536 | 181,220 | 2,247
Age (years) | 70 to 74 | 44,820 | 646 | 191,960 | 2,767
Age (years) | 75 to 79 | 44,900 | 917 | 184,600 | 3,772
Age (years) | 80 to 84 | 38,840 | 1,164 | 169,820 | 5,092
Age (years) | 85+ | 54,680 | 1,528 | 261,520 | 7,309
Race | White | 173,280 | 787 | 789,220 | 3,583
Race | Black | 28,860 | 1,550 | 106,400 | 5,715
Race | Other | 24,320 | 831 | 93,500 | 3,196
Sex | Female | 123,240 | 823 | 599,640 | 4,004
Sex | Male | 103,220 | 872 | 389,480 | 3,291
Region | Northeast | 38,840 | 818 | 185,980 | 3,916
Region | Midwest | 49,440 | 815 | 219,240 | 3,612
Region | South | 94,520 | 892 | 414,480 | 3,912
Region | West | 43,660 | 809 | 169,420 | 3,140
Total | | 226,460 | 845 | 989,120 | 3,689

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with functional disorders (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 47). Rates were highest in the Northeast and South, followed by the Midwest, and lowest in the West.

Table 48 Functional Disorders: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 7,560 | 94 | 159,320 | 1,975
Age (years) | 70 to 74 | 6,840 | 99 | 168,820 | 2,434
Age (years) | 75 to 79 | 6,080 | 124 | 153,340 | 3,133
Age (years) | 80 to 84 | 4,220 | 127 | 137,960 | 4,136
Age (years) | 85+ | 5,900 | 165 | 201,980 | 5,645
Race | White | 23,540 | 107 | 669,340 | 3,039
Race | Black | 3,660 | 197 | 77,220 | 4,148
Race | Other | 3,400 | 116 | 74,860 | 2,559
Sex | Female | 16,700 | 112 | 489,400 | 3,268
Sex | Male | 13,900 | 117 | 332,020 | 2,805
Region | Northeast | 5,960 | 126 | 154,940 | 3,263
Region | Midwest | 6,540 | 108 | 187,240 | 3,085
Region | South | 12,400 | 117 | 348,160 | 3,286
Region | West | 5,700 | 106 | 131,080 | 2,429
Total | | 30,600 | 114 | 821,420 | 3,064

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with functional disorders (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 48). Rates were lower in the West compared with the South, Northeast, and Midwest.