# Chapter 3 Gastric and Small Intestinal Disease

## Peptic Ulcer Disease

Table 25 Peptic Ulcer Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 5 | 8 | 32 | 56
Age (years) | 25 to 44 | 85 | 101 | 128 | 152
Age (years) | 45 to 54 | 43 | 100 | 230 | 533
Age (years) | 55 to 64 | 105 | 257 | 236 | 577
Age (years) | 65 to 74 | 155 | 563 | 499 | 1,812
Age (years) | 75 plus | 38 | 189 | 241 | 1,191
Race | White | 235 | 92 | 965 | 329
Race | Black | 154 | 319 | 263 | 588
Race | Other | 42 | 188 | 137 | 548
Ethnicity | Hispanic | 60 | 157 | 333 | 871
Ethnicity | Not Hispanic | 371 | 113 | 1,032 | 331
Sex | Female | 288 | 148 | 779 | 404
Sex | Male | 144 | 83 | 586 | 339
Total | | 431 | 117 | 1,365 | 372

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Peptic ulcer disease contributed to 1.4 million ambulatory visits (2015) (Table 25). Ambulatory care visits were uncommon during childhood and then rates (all-listed diagnoses) increased with age until the oldest age group. Age-adjusted ambulatory care visit rates were higher among women compared with men, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 26 Peptic Ulcer Disease: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 1 | 1 | 2
Age (years) | 12 to 24 | 6 | 10 | 12 | 22
Age (years) | 25 to 44 | 26 | 30 | 65 | 75
Age (years) | 45 to 54 | 22 | 53 | 63 | 152
Age (years) | 55 to 64 | 33 | 77 | 94 | 222
Age (years) | 65 to 74 | 34 | 113 | 100 | 328
Age (years) | 75 plus | 47 | 213 | 135 | 615
Sex | Female | 83 | 42 | 240 | 121
Sex | Male | 84 | 48 | 231 | 132
Total | | 168 | 45 | 471 | 126

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Peptic ulcer disease contributed to 471,000 emergency department visits in 2018 (Table 26). Emergency department visit rates increased with age. Age-adjusted emergency department visit rates were higher among men compared with women.

Table 27 Peptic Ulcer Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 1 | 2
Age (years) | 12 to 24 | 2 | 4 | 6 | 10
Age (years) | 25 to 44 | 15 | 17 | 43 | 49
Age (years) | 45 to 54 | 18 | 44 | 52 | 124
Age (years) | 55 to 64 | 31 | 74 | 90 | 214
Age (years) | 65 to 74 | 36 | 117 | 105 | 346
Age (years) | 75 plus | 49 | 225 | 142 | 645
Race | White | 122 | 39 | 349 | 110
Race | Black | 20 | 46 | 63 | 145
Race | Other | 11 | 46 | 31 | 127
Ethnicity | Hispanic | 13 | 31 | 44 | 105
Ethnicity | Not Hispanic | 140 | 41 | 399 | 118
Sex | Female | 74 | 36 | 217 | 105
Sex | Male | 78 | 44 | 222 | 126
Total | | 152 | 40 | 439 | 114

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Peptic ulcer disease contributed to 439,000 hospital discharges in 2018 (Table 27). Hospital discharge rates increased with age. Hospital discharge rates were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by 31% from 166 to 114.(4)

Table 28 Peptic Ulcer Disease: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 1 | 0.0 | 0.1 | 2 | 0.0 | 0.1
Age (years) | 12 to 24 | 5 | 0.0 | 0.3 | 12 | 0.0 | 0.7
Age (years) | 25 to 44 | 122 | 0.1 | 5.1 | 202 | 0.2 | 8.5
Age (years) | 45 to 54 | 237 | 0.6 | 7.2 | 437 | 1.1 | 13.4
Age (years) | 55 to 64 | 584 | 1.4 | 13.4 | 1,136 | 2.7 | 26.0
Age (years) | 65 to 74 | 758 | 2.4 | 12.0 | 1,607 | 5.1 | 25.3
Age (years) | 75 plus | 1,848 | 8.2 | 12.9 | 3,662 | 16.2 | 25.7
Race | White | 3,022 | 0.9 | 42.4 | 6,009 | 1.8 | 83.1
Race | Black | 353 | 0.8 | 5.9 | 677 | 1.6 | 11.1
Race | Other | 180 | 0.8 | 2.7 | 372 | 1.5 | 5.6
Ethnicity | Hispanic | 227 | 0.6 | 3.8 | 482 | 1.3 | 8.2
Ethnicity | Not Hispanic | 3,328 | 0.9 | 47.2 | 6,576 | 1.8 | 91.6
Sex | Female | 1,751 | 0.8 | 23.8 | 3,336 | 1.5 | 45.5
Sex | Male | 1,804 | 1.0 | 27.2 | 3,722 | 2.1 | 54.3
Total | | 3,555 | 0.9 | 51.0 | 7,058 | 1.7 | 99.8

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Peptic ulcer disease contributed to 7,000 deaths in 2019 (Table 28). Mortality was uncommon among the youngest age groups and then rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Whites, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with peptic ulcer disease as underlying or other cause decreased by 39% from 2.8 to 1.7.(4)

Table 29 Peptic Ulcer Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 39 | 0.0% | 105 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 355 | 0.0% | 895 | 0.1%
Age (years) | 25 to 44 | 2,656,672 | 1,652 | 0.1% | 4,242 | 0.2%
Age (years) | 45 to 54 | 1,452,320 | 1,735 | 0.1% | 5,241 | 0.4%
Age (years) | 55 to 64 | 1,640,216 | 3,369 | 0.2% | 10,402 | 0.6%
Age (years) | 65 to 74 | 2,840,615 | 7,852 | 0.3% | 23,619 | 0.8%
Age (years) | 75 plus | 2,576,241 | 9,206 | 0.4% | 27,042 | 1.0%
Race-ethnicity | White | 8,657,702 | 16,044 | 0.2% | 47,287 | 0.5%
Race-ethnicity | Black | 1,242,477 | 2,988 | 0.2% | 8,857 | 0.7%
Race-ethnicity | Hispanic | 1,493,457 | 2,460 | 0.2% | 7,378 | 0.5%
Race-ethnicity | Asian | 607,284 | 894 | 0.1% | 2,554 | 0.4%
Race-ethnicity | Unknown | 1,719,014 | 1,822 | 0.1% | 5,470 | 0.3%
Sex | Female | 7,199,363 | 13,993 | 0.2% | 40,459 | 0.6%
Sex | Male | 6,520,571 | 10,215 | 0.2% | 31,087 | 0.5%
Region | Northeast | 1,526,275 | 3,075 | 0.2% | 9,058 | 0.6%
Region | Midwest | 3,322,846 | 5,054 | 0.2% | 15,022 | 0.5%
Region | South | 5,619,435 | 11,073 | 0.2% | 33,199 | 0.6%
Region | West | 3,251,378 | 5,006 | 0.2% | 14,267 | 0.4%
Total | | 13,719,934 | 24,208 | 0.2% | 71,546 | 0.5%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of peptic ulcer disease (based on all-listed diagnoses) was 0.5% (Table 29). Prevalence increased with age and was higher among women. It was highest among Blacks, similar among Whites and Hispanics, and lowest among Asians. It was highest in the Northeast and South, and lowest in the West.

Table 30 Peptic Ulcer Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 46 | 4 | 130 | 12
Age (years) | 12 to 24 | 444 | 31 | 1,210 | 83
Age (years) | 25 to 44 | 1,962 | 74 | 5,714 | 215
Age (years) | 45 to 54 | 2,090 | 144 | 7,129 | 491
Age (years) | 55 to 64 | 3,817 | 233 | 13,880 | 846
Age (years) | 65 to 74 | 8,754 | 308 | 31,724 | 1,117
Age (years) | 75 plus | 9,500 | 369 | 37,610 | 1,460
Race-ethnicity | White | 17,436 | 201 | 64,734 | 748
Race-ethnicity | Black | 3,433 | 276 | 11,898 | 958
Race-ethnicity | Hispanic | 2,804 | 188 | 10,039 | 672
Race-ethnicity | Asian | 1,038 | 171 | 3,648 | 601
Race-ethnicity | Unknown | 1,902 | 111 | 7,078 | 412
Sex | Female | 16,007 | 222 | 57,474 | 798
Sex | Male | 10,606 | 163 | 39,923 | 612
Region | Northeast | 3,337 | 219 | 12,003 | 786
Region | Midwest | 5,311 | 160 | 19,397 | 584
Region | South | 12,513 | 223 | 45,431 | 808
Region | West | 5,452 | 168 | 20,566 | 633
Total | | 26,613 | 194 | 97,397 | 710

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with peptic ulcer disease (all-listed diagnoses) increased with age and were higher among women compared with men (Table 30). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 31 Peptic Ulcer Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 1 | 0 | 3 | 0
Age (years) | 12 to 24 | 4 | 0 | 22 | 2
Age (years) | 25 to 44 | 50 | 2 | 130 | 5
Age (years) | 45 to 54 | 51 | 4 | 157 | 11
Age (years) | 55 to 64 | 153 | 9 | 366 | 22
Age (years) | 65 to 74 | 381 | 13 | 787 | 28
Age (years) | 75 plus | 439 | 17 | 939 | 36
Race-ethnicity | White | 768 | 9 | 1,629 | 19
Race-ethnicity | Black | 132 | 11 | 314 | 25
Race-ethnicity | Hispanic | 79 | 5 | 208 | 14
Race-ethnicity | Asian | 21 | 3 | 57 | 9
Race-ethnicity | Unknown | 79 | 5 | 196 | 11
Sex | Female | 601 | 8 | 1,326 | 18
Sex | Male | 478 | 7 | 1,078 | 17
Region | Northeast | 158 | 10 | 334 | 22
Region | Midwest | 283 | 9 | 539 | 16
Region | South | 433 | 8 | 1,039 | 18
Region | West | 205 | 6 | 492 | 15
Total | | 1,079 | 8 | 2,404 | 18

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with peptic ulcer disease (all-listed diagnoses) increased with age and differed little by sex (Table 31). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, and lowest in the Midwest and West.

Table 32 Peptic Ulcer Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 3 | 0 | 18 | 2
Age (years) | 12 to 24 | 24 | 2 | 100 | 7
Age (years) | 25 to 44 | 192 | 7 | 694 | 26
Age (years) | 45 to 54 | 337 | 23 | 1,230 | 85
Age (years) | 55 to 64 | 919 | 56 | 3,360 | 205
Age (years) | 65 to 74 | 2,523 | 89 | 8,812 | 310
Age (years) | 75 plus | 4,211 | 163 | 13,342 | 518
Race-ethnicity | White | 5,725 | 66 | 18,415 | 213
Race-ethnicity | Black | 941 | 76 | 3,651 | 294
Race-ethnicity | Hispanic | 710 | 48 | 2,621 | 175
Race-ethnicity | Asian | 240 | 40 | 722 | 119
Race-ethnicity | Unknown | 593 | 34 | 2,147 | 125
Sex | Female | 4,213 | 59 | 14,152 | 197
Sex | Male | 3,996 | 61 | 13,404 | 206
Region | Northeast | 978 | 64 | 3,431 | 225
Region | Midwest | 1,866 | 56 | 5,958 | 179
Region | South | 3,516 | 63 | 12,581 | 224
Region | West | 1,849 | 57 | 5,586 | 172
Total | | 8,209 | 60 | 27,556 | 201

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with peptic ulcer disease (all-listed diagnoses) increased with age and were higher among men compared with women (Table 32). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were higher in the Northeast and South compared with the Midwest and West.

Table 33 Peptic Ulcer Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 26,060 | 0.3% | 77,660 | 1.0%
Age (years) | 70 to 74 | 6,936,940 | 27,640 | 0.4% | 79,920 | 1.2%
Age (years) | 75 to 79 | 4,894,060 | 23,420 | 0.5% | 68,360 | 1.4%
Age (years) | 80 to 84 | 3,335,340 | 18,240 | 0.5% | 50,660 | 1.5%
Age (years) | 85+ | 3,578,120 | 18,260 | 0.5% | 53,480 | 1.5%
Race | White | 22,023,800 | 90,720 | 0.4% | 264,140 | 1.2%
Race | Black | 1,861,660 | 8,340 | 0.4% | 25,460 | 1.4%
Race | Other | 2,925,320 | 14,560 | 0.5% | 40,480 | 1.4%
Sex | Female | 14,975,560 | 65,180 | 0.4% | 188,600 | 1.3%
Sex | Male | 11,835,220 | 48,440 | 0.4% | 141,480 | 1.2%
Region | Northeast | 4,748,700 | 19,620 | 0.4% | 56,500 | 1.2%
Region | Midwest | 6,069,800 | 24,540 | 0.4% | 72,540 | 1.2%
Region | South | 10,595,900 | 45,840 | 0.4% | 135,980 | 1.3%
Region | West | 5,396,380 | 23,620 | 0.4% | 65,060 | 1.2%
Total | | 26,810,780 | 113,620 | 0.4% | 330,080 | 1.2%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of peptic ulcer disease (based on all-listed diagnoses) was 1.2% (Table 33). Prevalence increased with age until the oldest age group and was higher among women and Blacks. It differed little by region.

Table 34 Peptic Ulcer Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 28,320 | 351 | 108,400 | 1,344
Age (years) | 70 to 74 | 30,300 | 437 | 116,640 | 1,681
Age (years) | 75 to 79 | 24,660 | 504 | 96,200 | 1,966
Age (years) | 80 to 84 | 18,900 | 567 | 75,600 | 2,267
Age (years) | 85+ | 17,480 | 489 | 74,560 | 2,084
Race | White | 94,780 | 430 | 374,340 | 1,700
Race | Black | 8,280 | 445 | 33,320 | 1,790
Race | Other | 16,600 | 567 | 63,740 | 2,179
Sex | Female | 72,060 | 481 | 281,780 | 1,882
Sex | Male | 47,600 | 402 | 189,620 | 1,602
Region | Northeast | 21,620 | 455 | 81,420 | 1,715
Region | Midwest | 24,320 | 401 | 96,520 | 1,590
Region | South | 48,400 | 457 | 194,020 | 1,831
Region | West | 25,320 | 469 | 99,440 | 1,843
Total | | 119,660 | 446 | 471,400 | 1,758

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with peptic ulcer disease (all-listed diagnoses) increased with age until 85 years and were higher among women compared with men but differed little by race (Table 34). Rates were highest in the West and South, followed by the Northeast, and lowest in the Midwest.

Table 35 Peptic Ulcer Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 9,420 | 117 | 25,540 | 317
Age (years) | 70 to 74 | 10,260 | 148 | 27,980 | 403
Age (years) | 75 to 79 | 9,420 | 192 | 27,380 | 559
Age (years) | 80 to 84 | 8,500 | 255 | 22,740 | 682
Age (years) | 85+ | 10,520 | 294 | 29,060 | 812
Race | White | 38,440 | 175 | 104,440 | 474
Race | Black | 4,320 | 232 | 12,980 | 697
Race | Other | 5,360 | 183 | 15,280 | 522
Sex | Female | 25,880 | 173 | 71,940 | 480
Sex | Male | 22,240 | 188 | 60,760 | 513
Region | Northeast | 8,160 | 172 | 22,860 | 481
Region | Midwest | 10,560 | 174 | 29,140 | 480
Region | South | 19,260 | 182 | 55,060 | 520
Region | West | 10,140 | 188 | 25,640 | 475
Total | | 48,120 | 179 | 132,700 | 495

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with peptic ulcer disease (all-listed diagnoses) increased with age and were higher among men compared with women and Blacks compared with Whites (Table 35). Rates were higher in the South compared with the Northeast and Midwest and lowest in the West.

Table 36 Peptic Ulcer Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 9,360 | 116 | 26,920 | 334
Age (years) | 70 to 74 | 10,200 | 147 | 29,580 | 426
Age (years) | 75 to 79 | 9,440 | 193 | 29,580 | 604
Age (years) | 80 to 84 | 8,700 | 261 | 24,140 | 724
Age (years) | 85+ | 10,760 | 301 | 30,000 | 838
Race | White | 39,420 | 179 | 111,460 | 506
Race | Black | 3,900 | 209 | 12,700 | 682
Race | Other | 5,140 | 176 | 16,060 | 549
Sex | Female | 25,600 | 171 | 74,320 | 496
Sex | Male | 22,860 | 193 | 65,900 | 557
Region | Northeast | 8,020 | 169 | 23,420 | 493
Region | Midwest | 10,980 | 181 | 31,920 | 526
Region | South | 19,380 | 183 | 57,940 | 547
Region | West | 10,080 | 187 | 26,940 | 499
Total | | 48,460 | 181 | 140,220 | 523

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with peptic ulcer disease (all-listed diagnoses) increased with age and were higher among men compared with women and Blacks compared with Whites (Table 36). Rates were highest in the South, followed by the Midwest, then the West, and lowest in the Northeast.

## Gastric Cancer

Table 244 Gastric Cancer: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | . | .
Age (years) | 12 to 24 | . | 0.2
Age (years) | 25 to 44 | 1,346 | 1.5
Age (years) | 45 to 54 | 2,262 | 5.4
Age (years) | 55 to 64 | 5,412 | 12.8
Age (years) | 65 to 74 | 7,184 | 23.6
Age (years) | 75 plus | 8,093 | 36.9
Race | White | 17,077 | 5.4
Race | Black | 3,483 | 8.5
Race | Other | 2,422 | 9.1
Ethnicity | Hispanic | 3,486 | 8.6
Ethnicity | Not Hispanic | 19,874 | 5.9
Sex | Female | 9,182 | 4.5
Sex | Male | 14,343 | 8.2
Total | | 23,539 | 6.2

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastric cancer accounted for 24,000 incident cases in 2016 (Table 244). Gastric cancer was rare among children and adolescents and incidence rates increased with age throughout adulthood. Age-adjusted incidence rates were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 245 Gastric Cancer: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 0 | 0
Age (years) | 12 to 24 | 0 | 0 | 0 | 0
Age (years) | 25 to 44 | 1 | 2 | 3 | 4
Age (years) | 45 to 54 | 2 | 5 | 5 | 12
Age (years) | 55 to 64 | 5 | 11 | 10 | 24
Age (years) | 65 to 74 | 5 | 16 | 11 | 37
Age (years) | 75 plus | 5 | 24 | 12 | 53
Race | White | 13 | 4 | 29 | 9
Race | Black | 3 | 7 | 7 | 16
Race | Other | 3 | 11 | 5 | 22
Ethnicity | Hispanic | 4 | 8 | 7 | 17
Ethnicity | Not Hispanic | 15 | 4 | 34 | 10
Sex | Female | 7 | 3 | 15 | 7
Sex | Male | 12 | 7 | 26 | 14
Total | | 19 | 5 | 41 | 11

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastric cancer contributed to 41,000 hospital discharges in 2018 (Table 245). Gastric cancer hospitalization was rare among children and adolescents and hospital discharge rates increased with age throughout adulthood. Age-adjusted hospital discharges rates (all-listed diagnoses) were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 246 Gastric Cancer: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 21 | 0.0 | 1.2 | 23 | 0.0 | 1.3
Age (years) | 25 to 44 | 559 | 0.6 | 24.0 | 583 | 0.7 | 25.1
Age (years) | 45 to 54 | 1,021 | 2.5 | 32.1 | 1,055 | 2.6 | 33.2
Age (years) | 55 to 64 | 2,074 | 4.9 | 47.2 | 2,208 | 5.2 | 50.2
Age (years) | 65 to 74 | 2,925 | 9.3 | 45.7 | 3,149 | 10.0 | 49.1
Age (years) | 75 plus | 4,513 | 20.0 | 34.3 | 5,039 | 22.3 | 38.2
Race | White | 8,137 | 2.5 | 136.3 | 8,829 | 2.7 | 145.4
Race | Black | 1,941 | 4.6 | 30.5 | 2,114 | 5.0 | 32.9
Race | Other | 1,035 | 4.1 | 17.9 | 1,114 | 4.5 | 18.8
Ethnicity | Hispanic | 1,709 | 4.1 | 38.4 | 1,828 | 4.4 | 40.5
Ethnicity | Not Hispanic | 9,404 | 2.6 | 146.3 | 10,229 | 2.8 | 156.7
Sex | Female | 4,478 | 2.1 | 79.1 | 4,827 | 2.2 | 84.1
Sex | Male | 6,635 | 3.7 | 105.6 | 7,230 | 4.0 | 113.1
Total | | 11,113 | 2.8 | 184.7 | 12,057 | 3.0 | 197.2

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Gastric cancer contributed to 12,000 deaths in 2019 (Table 246). Gastric cancer mortality was rare among children and adolescents and mortality rates increased with age throughout adulthood. Age-adjusted mortality rates (underlying or other cause) were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

## Cancer of Small Intestine

Table 247 Cancer of Small Intestine: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | . | .
Age (years) | 12 to 24 | . | 0.0
Age (years) | 25 to 44 | 577 | 0.7
Age (years) | 45 to 54 | 1,168 | 2.8
Age (years) | 55 to 64 | 2,081 | 4.9
Age (years) | 65 to 74 | 2,873 | 9.4
Age (years) | 75 plus | 2,630 | 12.0
Race | White | 7,256 | 2.3
Race | Black | 1,607 | 3.8
Race | Other | 455 | 1.7
Ethnicity | Hispanic | 674 | 1.6
Ethnicity | Not Hispanic | 8,157 | 2.5
Sex | Female | 4,247 | 2.1
Sex | Male | 4,795 | 2.7
Total | | 9,044 | 2.4

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Cancer of the small intestine accounted for 9,000 incident cases in 2016 (Table 247). Small intestinal cancer was rare among children and adolescents and incidence rates increased with age throughout adulthood. Age-adjusted incidence rates were higher among men compared with women, Blacks compared with Whites, and among non-Hispanics compared with Hispanics. Between 2004 and 2016, age-adjusted incidence rates (per 100,000) increased by a third from 1.8 to 2.4.(4)

Table 248 Cancer of Small Intestine: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 0 | 0 | 0 | 0
Age (years) | 25 to 44 | 0 | 0 | 0 | 1
Age (years) | 45 to 54 | 0 | 1 | 1 | 3
Age (years) | 55 to 64 | 1 | 2 | 2 | 5
Age (years) | 65 to 74 | 1 | 4 | 3 | 9
Age (years) | 75 plus | 1 | 6 | 3 | 13
Race | White | 3 | 1 | 7 | 2
Race | Black | 1 | 2 | 2 | 4
Race | Other | 0 | 1 | 1 | 3
Ethnicity | Hispanic | 0 | 1 | 1 | 2
Ethnicity | Not Hispanic | 4 | 1 | 9 | 2
Sex | Female | 2 | 1 | 4 | 2
Sex | Male | 2 | 1 | 5 | 3
Total | | 4 | 1 | 9 | 2

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Cancer of the small intestine contributed to 9,000 hospital discharges in 2018 (Table 248). Small intestinal cancer hospitalization was rare among children and adolescents and hospital discharge rates increased with age throughout adulthood. Age-adjusted hospital discharge rates (all-listed diagnoses) were higher among men compared with women and Blacks compared with Whites but did not differ by ethnicity. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by a third from 3 to 2.(4)

Table 249 Cancer of Small Intestine: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 3 | 0.0 | 0.2 | 3 | 0.0 | 0.2
Age (years) | 25 to 44 | 51 | 0.1 | 2.1 | 54 | 0.1 | 2.3
Age (years) | 45 to 54 | 107 | 0.3 | 3.3 | 119 | 0.3 | 3.6
Age (years) | 55 to 64 | 286 | 0.7 | 6.5 | 315 | 0.7 | 7.1
Age (years) | 65 to 74 | 490 | 1.6 | 7.7 | 542 | 1.7 | 8.5
Age (years) | 75 plus | 771 | 3.4 | 5.9 | 883 | 3.9 | 6.8
Race | White | 1,362 | 0.4 | 20.1 | 1,528 | 0.4 | 22.3
Race | Black | 277 | 0.6 | 4.6 | 308 | 0.7 | 5.2
Race | Other | 69 | 0.3 | 1.0 | 80 | 0.3 | 1.1
Ethnicity | Hispanic | 100 | 0.3 | 1.8 | 120 | 0.3 | 2.2
Ethnicity | Not Hispanic | 1,608 | 0.4 | 23.9 | 1,796 | 0.5 | 26.3
Sex | Female | 782 | 0.3 | 12.4 | 867 | 0.4 | 13.6
Sex | Male | 926 | 0.5 | 13.3 | 1,049 | 0.6 | 14.9
Total | | 1,708 | 0.4 | 25.7 | 1,916 | 0.5 | 28.5

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Cancer of the small intestine contributed to 2,000 deaths in 2019 (Table 249). Small intestinal cancer mortality was rare among children and adolescents and mortality rates increased with age throughout adulthood. Age-adjusted mortality rates (underlying or other cause) were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by a fourth from 0.4 to 0.5.(4)