# Chapter 2 Esophageal Disease

## Gastroesophageal Reflux Disease

Table 13 Gastroesophageal Reflux Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 362 | 745 | 1,195 | 2,457
Age (years) | 12 to 24 | 541 | 964 | 1,146 | 2,042
Age (years) | 25 to 44 | 1,065 | 1,260 | 3,463 | 4,098
Age (years) | 45 to 54 | 952 | 2,210 | 4,592 | 10,657
Age (years) | 55 to 64 | 985 | 2,414 | 5,635 | 13,810
Age (years) | 65 to 74 | 974 | 3,539 | 5,945 | 21,597
Age (years) | 75 plus | 562 | 2,780 | 4,735 | 23,432
Race | White | 4,387 | 1,638 | 21,392 | 7,488
Race | Black | 797 | 1,835 | 3,561 | 8,328
Race | Other | 257 | 1,087 | 1,759 | 7,906
Ethnicity | Hispanic | 912 | 2,232 | 4,242 | 10,206
Ethnicity | Not Hispanic | 4,529 | 1,568 | 22,469 | 7,340
Sex | Female | 3,572 | 2,009 | 16,082 | 8,673
Sex | Male | 1,869 | 1,175 | 10,629 | 6,421
Total | | 5,441 | 1,609 | 26,711 | 7,578

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastroesophageal reflux disease contributed to 26.7 million ambulatory visits (2015) (Table 13). Ambulatory care visit rates (all-listed diagnoses) were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 14 Gastroesophageal Reflux Disease: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 44 | 91 | 226 | 466
Age (years) | 12 to 24 | 60 | 109 | 326 | 589
Age (years) | 25 to 44 | 123 | 141 | 1,447 | 1,663
Age (years) | 45 to 54 | 61 | 147 | 1,335 | 3,208
Age (years) | 55 to 64 | 58 | 138 | 1,791 | 4,236
Age (years) | 65 to 74 | 45 | 147 | 1,841 | 6,037
Age (years) | 75 plus | 46 | 211 | 2,518 | 11,478
Sex | Female | 245 | 144 | 5,657 | 2,913
Sex | Male | 192 | 118 | 3,826 | 2,228
Total | | 438 | 131 | 9,484 | 2,582

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastroesophageal reflux disease contributed to 9.5 million emergency department visits in 2018 (Table 14). Emergency department visit rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men.

Table 15 Gastroesophageal Reflux Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 6 | 12 | 78 | 162
Age (years) | 12 to 24 | 2 | 4 | 104 | 188
Age (years) | 25 to 44 | 10 | 12 | 628 | 722
Age (years) | 45 to 54 | 11 | 27 | 704 | 1,691
Age (years) | 55 to 64 | 17 | 40 | 1,233 | 2,917
Age (years) | 65 to 74 | 16 | 52 | 1,510 | 4,953
Age (years) | 75 plus | 20 | 90 | 1,967 | 8,967
Race | White | 65 | 22 | 5,207 | 1,653
Race | Black | 13 | 30 | 800 | 1,841
Race | Other | 5 | 20 | 274 | 1,112
Ethnicity | Hispanic | 10 | 21 | 476 | 1,103
Ethnicity | Not Hispanic | 73 | 23 | 5,806 | 1,726
Sex | Female | 41 | 21 | 3,599 | 1,759
Sex | Male | 41 | 24 | 2,626 | 1,489
Total | | 82 | 22 | 6,225 | 1,628

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastroesophageal reflux disease contributed to 6.2 million hospital discharges in 2018 (Table 15). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by 50% from 1,086 to 1628.(4,5)

Table 16 Gastroesophageal Reflux Disease: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 10 | 0.0 | 0.8 | 43 | 0.1 | 3.2
Age (years) | 12 to 24 | 2 | 0.0 | 0.1 | 27 | 0.0 | 1.6
Age (years) | 25 to 44 | 33 | 0.0 | 1.4 | 194 | 0.2 | 8.2
Age (years) | 45 to 54 | 45 | 0.1 | 1.4 | 449 | 1.1 | 13.8
Age (years) | 55 to 64 | 117 | 0.3 | 2.7 | 1,269 | 3.0 | 28.8
Age (years) | 65 to 74 | 194 | 0.6 | 3.0 | 2,216 | 7.0 | 34.4
Age (years) | 75 plus | 824 | 3.7 | 4.8 | 7,515 | 33.3 | 47.8
Race | White | 1,107 | 0.3 | 12.3 | 10,412 | 3.0 | 118.8
Race | Black | 81 | 0.2 | 1.3 | 1,008 | 2.5 | 14.9
Race | Other | 37 | 0.2 | 0.6 | 293 | 1.2 | 4.1
Ethnicity | Hispanic | 64 | 0.2 | 1.2 | 524 | 1.4 | 8.5
Ethnicity | Not Hispanic | 1,161 | 0.3 | 13.0 | 11,189 | 3.0 | 129.3
Sex | Female | 603 | 0.3 | 6.7 | 6,312 | 2.7 | 70.0
Sex | Male | 622 | 0.4 | 7.5 | 5,401 | 3.1 | 67.9
Total | | 1,225 | 0.3 | 14.2 | 11,713 | 2.9 | 137.9

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Gastroesophageal reflux disease contributed to 12,000 deaths in 2019 (Table 16). Mortality rates (underlying or other cause) were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted mortality rates were higher among men, Whites, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with gastroesophageal reflux disease as underlying or other cause increased by 7% from 2.7 to 2.9.(4)

Table 17 Gastroesophageal Reflux Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 9,567 | 0.9% | 20,842 | 1.9%
Age (years) | 12 to 24 | 1,451,892 | 10,511 | 0.7% | 25,914 | 1.8%
Age (years) | 25 to 44 | 2,656,672 | 43,031 | 1.6% | 132,690 | 5.0%
Age (years) | 45 to 54 | 1,452,320 | 36,937 | 2.5% | 145,474 | 10.0%
Age (years) | 55 to 64 | 1,640,216 | 52,413 | 3.2% | 241,952 | 14.8%
Age (years) | 65 to 74 | 2,840,615 | 103,549 | 3.6% | 492,699 | 17.3%
Age (years) | 75 plus | 2,576,241 | 80,437 | 3.1% | 470,137 | 18.2%
Race-ethnicity | White | 8,657,702 | 219,262 | 2.5% | 1,039,266 | 12.0%
Race-ethnicity | Black | 1,242,477 | 37,054 | 3.0% | 177,232 | 14.3%
Race-ethnicity | Hispanic | 1,493,457 | 37,219 | 2.5% | 150,528 | 10.1%
Race-ethnicity | Asian | 607,284 | 10,905 | 1.8% | 40,131 | 6.6%
Race-ethnicity | Unknown | 1,719,014 | 32,005 | 1.9% | 122,551 | 7.1%
Sex | Female | 7,199,363 | 204,551 | 2.8% | 912,394 | 12.7%
Sex | Male | 6,520,571 | 131,894 | 2.0% | 617,314 | 9.5%
Region | Northeast | 1,526,275 | 44,716 | 2.9% | 181,214 | 11.9%
Region | Midwest | 3,322,846 | 65,408 | 2.0% | 339,807 | 10.2%
Region | South | 5,619,435 | 165,939 | 3.0% | 738,811 | 13.1%
Region | West | 3,251,378 | 60,382 | 1.9% | 269,876 | 8.3%
Total | | 13,719,934 | 336,445 | 2.5% | 1,529,708 | 11.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of gastroesophageal reflux disease (based on all-listed diagnoses) was 11.1% (Table 17). Prevalence was similar among children compared with adolescents and the youngest adults and then increased with age. It was higher among women. It was highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. It was highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 18 Gastroesophageal Reflux Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 14,041 | 1,274 | 39,452 | 3,580
Age (years) | 12 to 24 | 14,641 | 1,008 | 40,683 | 2,802
Age (years) | 25 to 44 | 60,273 | 2,269 | 228,478 | 8,600
Age (years) | 45 to 54 | 50,487 | 3,476 | 268,369 | 18,479
Age (years) | 55 to 64 | 71,490 | 4,359 | 460,324 | 28,065
Age (years) | 65 to 74 | 141,710 | 4,989 | 928,025 | 32,670
Age (years) | 75 plus | 110,129 | 4,275 | 932,876 | 36,211
Race-ethnicity | White | 299,725 | 3,462 | 1,928,520 | 22,275
Race-ethnicity | Black | 51,036 | 4,108 | 365,372 | 29,407
Race-ethnicity | Hispanic | 51,726 | 3,464 | 293,130 | 19,628
Race-ethnicity | Asian | 15,100 | 2,486 | 73,076 | 12,033
Race-ethnicity | Unknown | 45,184 | 2,628 | 238,109 | 13,851
Sex | Female | 282,690 | 3,927 | 1,783,786 | 24,777
Sex | Male | 180,081 | 2,762 | 1,114,421 | 17,091
Region | Northeast | 63,293 | 4,147 | 345,225 | 22,619
Region | Midwest | 86,607 | 2,606 | 598,397 | 18,009
Region | South | 230,753 | 4,106 | 1,467,869 | 26,121
Region | West | 82,118 | 2,526 | 486,716 | 14,970
Total | | 462,771 | 3,373 | 2,898,207 | 21,124

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with gastroesophageal reflux disease (all-listed diagnoses) were higher among children compared with adolescents and the youngest adults and then increased with age and were higher among women compared with men (Table 18). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 19 Gastroesophageal Reflux Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 32 | 3 | 73 | 7
Age (years) | 12 to 24 | 139 | 10 | 371 | 26
Age (years) | 25 to 44 | 688 | 26 | 2,394 | 90
Age (years) | 45 to 54 | 536 | 37 | 2,071 | 143
Age (years) | 55 to 64 | 907 | 55 | 3,921 | 239
Age (years) | 65 to 74 | 1,776 | 63 | 7,832 | 276
Age (years) | 75 plus | 1,882 | 73 | 8,846 | 343
Race-ethnicity | White | 3,595 | 42 | 16,654 | 192
Race-ethnicity | Black | 1,051 | 85 | 4,064 | 327
Race-ethnicity | Hispanic | 662 | 44 | 2,141 | 143
Race-ethnicity | Asian | 105 | 17 | 467 | 77
Race-ethnicity | Unknown | 547 | 32 | 2,182 | 127
Sex | Female | 3,576 | 50 | 15,940 | 221
Sex | Male | 2,384 | 37 | 9,568 | 147
Region | Northeast | 743 | 49 | 3,910 | 256
Region | Midwest | 1,249 | 38 | 6,771 | 204
Region | South | 3,055 | 54 | 11,272 | 201
Region | West | 913 | 28 | 3,555 | 109
Total | | 5,960 | 43 | 25,508 | 186

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with gastroesophageal reflux disease (all-listed diagnoses) increased with age and were higher among women compared with men (Table 19). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the Midwest and South, and lowest in the West.

Table 20 Gastroesophageal Reflux Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 55 | 5 | 933 | 85
Age (years) | 12 to 24 | 25 | 2 | 1,570 | 108
Age (years) | 25 to 44 | 108 | 4 | 11,259 | 424
Age (years) | 45 to 54 | 143 | 10 | 17,165 | 1,182
Age (years) | 55 to 64 | 405 | 25 | 44,429 | 2,709
Age (years) | 65 to 74 | 750 | 26 | 99,583 | 3,506
Age (years) | 75 plus | 1,130 | 44 | 143,001 | 5,551
Race-ethnicity | White | 1,709 | 20 | 221,785 | 2,562
Race-ethnicity | Black | 385 | 31 | 43,846 | 3,529
Race-ethnicity | Hispanic | 247 | 17 | 24,559 | 1,644
Race-ethnicity | Asian | 42 | 7 | 4,729 | 779
Race-ethnicity | Unknown | 233 | 14 | 23,021 | 1,339
Sex | Female | 1,390 | 19 | 185,026 | 2,570
Sex | Male | 1,226 | 19 | 132,914 | 2,038
Region | Northeast | 312 | 20 | 39,742 | 2,604
Region | Midwest | 554 | 17 | 75,875 | 2,283
Region | South | 1,185 | 21 | 152,116 | 2,707
Region | West | 565 | 17 | 50,207 | 1,544
Total | | 2,616 | 19 | 317,940 | 2,317

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with gastroesophageal reflux disease (all-listed diagnoses) increased with age and were higher among women compared with men (Table 20). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 21 Gastroesophageal Reflux Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 392,040 | 4.9% | 1,659,120 | 20.6%
Age (years) | 70 to 74 | 6,936,940 | 368,140 | 5.3% | 1,629,540 | 23.5%
Age (years) | 75 to 79 | 4,894,060 | 268,220 | 5.5% | 1,273,780 | 26.0%
Age (years) | 80 to 84 | 3,335,340 | 174,080 | 5.2% | 893,240 | 26.8%
Age (years) | 85+ | 3,578,120 | 155,280 | 4.3% | 940,280 | 26.3%
Race | White | 22,023,800 | 1,127,640 | 5.1% | 5,374,440 | 24.4%
Race | Black | 1,861,660 | 86,000 | 4.6% | 424,540 | 22.8%
Race | Other | 2,925,320 | 144,120 | 4.9% | 596,980 | 20.4%
Sex | Female | 14,975,560 | 862,780 | 5.8% | 3,926,880 | 26.2%
Sex | Male | 11,835,220 | 494,980 | 4.2% | 2,469,080 | 20.9%
Region | Northeast | 4,748,700 | 253,520 | 5.3% | 1,099,980 | 23.2%
Region | Midwest | 6,069,800 | 256,180 | 4.2% | 1,429,680 | 23.6%
Region | South | 10,595,900 | 614,400 | 5.8% | 2,851,060 | 26.9%
Region | West | 5,396,380 | 233,660 | 4.3% | 1,015,240 | 18.8%
Total | | 26,810,780 | 1,357,760 | 5.1% | 6,395,960 | 23.9%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of gastroesophageal reflux disease (based on all-listed diagnoses) was 23.9% (Table 21). Prevalence increased with age until the oldest age group and was higher among women and Whites. It was highest in the South, followed by the Midwest and Northeast, and lowest in the West.

Table 22 Gastroesophageal Reflux Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 557,060 | 6,906 | 3,213,040 | 39,833
Age (years) | 70 to 74 | 532,500 | 7,676 | 3,213,460 | 46,324
Age (years) | 75 to 79 | 378,820 | 7,740 | 2,518,320 | 51,457
Age (years) | 80 to 84 | 247,340 | 7,416 | 1,801,280 | 54,006
Age (years) | 85+ | 234,320 | 6,549 | 1,979,600 | 55,325
Race | White | 1,606,080 | 7,292 | 10,517,200 | 47,754
Race | Black | 130,000 | 6,983 | 930,960 | 50,007
Race | Other | 213,960 | 7,314 | 1,277,540 | 43,672
Sex | Female | 1,259,740 | 8,412 | 8,152,640 | 54,440
Sex | Male | 690,300 | 5,833 | 4,573,060 | 38,639
Region | Northeast | 371,400 | 7,821 | 2,241,740 | 47,207
Region | Midwest | 348,820 | 5,747 | 2,533,080 | 41,733
Region | South | 894,920 | 8,446 | 6,014,200 | 56,760
Region | West | 334,900 | 6,206 | 1,936,680 | 35,889
Total | | 1,950,040 | 7,273 | 12,725,700 | 47,465

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with gastroesophageal reflux disease (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 22). Rates were highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 23 Gastroesophageal Reflux Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 13,720 | 170 | 515,880 | 6,395
Age (years) | 70 to 74 | 12,660 | 183 | 562,800 | 8,113
Age (years) | 75 to 79 | 11,500 | 235 | 537,080 | 10,974
Age (years) | 80 to 84 | 9,880 | 296 | 462,380 | 13,863
Age (years) | 85+ | 11,580 | 324 | 623,620 | 17,429
Race | White | 45,860 | 208 | 2,251,100 | 10,221
Race | Black | 7,660 | 411 | 247,140 | 13,275
Race | Other | 5,820 | 199 | 203,520 | 6,957
Sex | Female | 35,000 | 234 | 1,657,340 | 11,067
Sex | Male | 24,340 | 206 | 1,044,420 | 8,825
Region | Northeast | 9,040 | 190 | 475,160 | 10,006
Region | Midwest | 14,360 | 237 | 653,820 | 10,772
Region | South | 26,040 | 246 | 1,200,480 | 11,330
Region | West | 9,900 | 183 | 372,300 | 6,899
Total | | 59,340 | 221 | 2,701,760 | 10,077

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with gastroesophageal reflux disease (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 23). Rates were lower in the West compared with the South, Midwest, and Northeast.

Table 24 Gastroesophageal Reflux Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 3,560 | 44 | 431,460 | 5,349
Age (years) | 70 to 74 | 3,940 | 57 | 484,000 | 6,977
Age (years) | 75 to 79 | 3,580 | 73 | 444,260 | 9,078
Age (years) | 80 to 84 | 3,120 | 94 | 362,980 | 10,883
Age (years) | 85+ | 4,240 | 118 | 468,520 | 13,094
Race | White | 14,700 | 67 | 1,859,960 | 8,445
Race | Black | 2,020 | 109 | 167,660 | 9,006
Race | Other | 1,720 | 59 | 163,600 | 5,593
Sex | Female | 10,220 | 68 | 1,293,460 | 8,637
Sex | Male | 8,220 | 69 | 897,760 | 7,585
Region | Northeast | 3,440 | 72 | 391,460 | 8,244
Region | Midwest | 4,400 | 72 | 539,980 | 8,896
Region | South | 7,200 | 68 | 951,340 | 8,978
Region | West | 3,400 | 63 | 308,440 | 5,716
Total | | 18,440 | 69 | 2,191,220 | 8,173

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with gastroesophageal reflux disease (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 24). Rates were lower in the West compared with the South, Midwest, and Northeast.

## Esophageal Cancer

Table 241 Esophageal Cancer: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | . | .
Age (years) | 12 to 24 | . | .
Age (years) | 25 to 44 | 324 | 0.4
Age (years) | 45 to 54 | 1,347 | 3.2
Age (years) | 55 to 64 | 4,323 | 10.2
Age (years) | 65 to 74 | 5,692 | 18.7
Age (years) | 75 plus | 5,350 | 24.4
Race | White | 14,984 | 4.6
Race | Black | 1,395 | 3.3
Race | Other | 686 | 2.5
Ethnicity | Hispanic | 842 | 2.0
Ethnicity | Not Hispanic | 15,065 | 4.3
Sex | Female | 3,791 | 1.8
Sex | Male | 12,562 | 7.0
Total | | 16,376 | 4.2

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Esophageal cancer accounted for 16,000 incident cases in 2016 (Table 241). Esophageal cancer was rare among children and adolescents and incidence rates increased with age throughout adulthood. Age-adjusted incidence rates were much higher among men compared with women, and higher among Whites compared with Blacks, and non-Hispanics compared with Hispanics.

Table 242 Esophageal Cancer: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | . | . | 0 | 0
Age (years) | 25 to 44 | 0 | 0 | 1 | 1
Age (years) | 45 to 54 | 2 | 4 | 4 | 10
Age (years) | 55 to 64 | 4 | 10 | 11 | 27
Age (years) | 65 to 74 | 4 | 14 | 13 | 43
Age (years) | 75 plus | 3 | 15 | 10 | 48
Race | White | 12 | 4 | 34 | 10
Race | Black | 1 | 3 | 4 | 8
Race | Other | 1 | 3 | 2 | 8
Ethnicity | Hispanic | 1 | 2 | 3 | 6
Ethnicity | Not Hispanic | 13 | 4 | 38 | 10
Sex | Female | 3 | 1 | 8 | 4
Sex | Male | 11 | 6 | 32 | 17
Total | | 14 | 3 | 40 | 10

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Esophageal cancer accounted contributed to 40,000 hospital discharges in 2018 (Table 242). Esophageal cancer hospitalization was rare among children and adolescents and hospital discharge rates increased with age throughout adulthood. Age-adjusted hospital discharge rates (all-listed diagnoses) were much higher among men compared with women, and higher among Whites compared with Blacks, and non-Hispanics compared with Hispanics.

Table 243 Esophageal Cancer: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 6 | 0.0 | 0.3 | 6 | 0.0 | 0.3
Age (years) | 25 to 44 | 283 | 0.3 | 11.4 | 298 | 0.3 | 12.0
Age (years) | 45 to 54 | 1,122 | 2.7 | 33.1 | 1,197 | 2.9 | 35.3
Age (years) | 55 to 64 | 3,817 | 9.0 | 83.9 | 4,081 | 9.6 | 89.7
Age (years) | 65 to 74 | 5,200 | 16.5 | 79.4 | 5,702 | 18.1 | 87.0
Age (years) | 75 plus | 5,557 | 24.6 | 43.8 | 6,221 | 27.6 | 49.0
Race | White | 14,295 | 4.1 | 223.7 | 15,631 | 4.5 | 242.3
Race | Black | 1,264 | 2.8 | 21.2 | 1,410 | 3.1 | 23.4
Race | Other | 426 | 1.7 | 7.1 | 464 | 1.8 | 7.7
Ethnicity | Hispanic | 681 | 1.7 | 12.9 | 753 | 1.8 | 14.2
Ethnicity | Not Hispanic | 15,304 | 4.1 | 239.1 | 16,752 | 4.5 | 259.2
Sex | Female | 3,145 | 1.4 | 50.8 | 3,466 | 1.5 | 55.5
Sex | Male | 12,840 | 6.8 | 201.2 | 14,039 | 7.4 | 217.9
Total | | 15,985 | 3.8 | 252.0 | 17,505 | 4.2 | 273.4

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Esophageal cancer contributed to 18,000 deaths in 2019 (Table 243). Esophageal cancer mortality was rare among children and adolescents and mortality rates increased with age throughout adulthood. Age-adjusted mortality rates (underlying or other cause) were much higher among men compared with women, and higher among Whites compared with Blacks, and non-Hispanics compared with Hispanics.