# Chapter 14 Gastrointestinal Infections

## Gastrointestinal Infections (exc. C. difficile)

Table 217 Gastrointestinal Infections (exc. C. difficile): Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 339 | 696 | 468 | 962
Age (years) | 12 to 24 | 323 | 576 | 377 | 671
Age (years) | 25 to 44 | 270 | 320 | 318 | 377
Age (years) | 45 to 54 | 84 | 196 | 123 | 286
Age (years) | 55 to 64 | 119 | 291 | 167 | 410
Age (years) | 65 to 74 | 37 | 135 | 108 | 393
Age (years) | 75 plus | 77 | 382 | 81 | 400
Race | White | 940 | 394 | 1,257 | 519
Race | Black | 286 | 627 | 354 | 786
Race | Other | 24 | 104 | 31 | 136
Ethnicity | Hispanic | 217 | 394 | 316 | 551
Ethnicity | Not Hispanic | 1,033 | 422 | 1,327 | 528
Sex | Female | 692 | 455 | 952 | 608
Sex | Male | 557 | 368 | 690 | 454
Total | | 1,250 | 408 | 1,642 | 527

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastrointestinal infections (excluding C. difficile) contributed to 1.6 million ambulatory visits (2015) (Table 217). Ambulatory care visit rates (all-listed diagnoses) were highest among children and adolescents. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 218 Gastrointestinal Infections (exc. C. difficile): Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 174 | 360 | 208 | 429
Age (years) | 12 to 24 | 83 | 149 | 101 | 182
Age (years) | 25 to 44 | 108 | 124 | 143 | 164
Age (years) | 45 to 54 | 40 | 97 | 60 | 144
Age (years) | 55 to 64 | 38 | 90 | 63 | 149
Age (years) | 65 to 74 | 32 | 106 | 57 | 185
Age (years) | 75 plus | 35 | 161 | 67 | 304
Sex | Female | 287 | 179 | 394 | 239
Sex | Male | 224 | 144 | 304 | 193
Total | | 510 | 162 | 698 | 217

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastrointestinal infections (excluding C. difficile) contributed to 698,000 emergency department visits in 2018 (Table 218). Emergency department visit rates (all-listed diagnoses) were highest among children and second highest among persons 75 years and over. Age-adjusted rates were higher among women compared with men.

Table 219 Gastrointestinal Infections (exc. C. difficile): Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 16 | 32 | 31 | 64
Age (years) | 12 to 24 | 7 | 12 | 14 | 25
Age (years) | 25 to 44 | 16 | 18 | 36 | 42
Age (years) | 45 to 54 | 13 | 30 | 28 | 68
Age (years) | 55 to 64 | 16 | 39 | 39 | 92
Age (years) | 65 to 74 | 17 | 55 | 40 | 133
Age (years) | 75 plus | 21 | 97 | 51 | 231
Race | White | 85 | 30 | 190 | 67
Race | Black | 14 | 32 | 35 | 78
Race | Other | 7 | 29 | 17 | 66
Ethnicity | Hispanic | 16 | 30 | 34 | 65
Ethnicity | Not Hispanic | 91 | 31 | 208 | 69
Sex | Female | 63 | 34 | 137 | 74
Sex | Male | 43 | 26 | 102 | 61
Total | | 106 | 30 | 240 | 68

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gastrointestinal infections (excluding C. difficile) contributed to 240,000 hospital discharges in 2018 (Table 219). Hospital discharge rates (all-listed diagnoses) were higher among children compared with adolescents and younger adults and then increased with age. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and non-Hispanics compared with Hispanics.

Table 220 Gastrointestinal Infections (exc. C. difficile): Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 215 | 0.4 | 16.5 | 279 | 0.6 | 21.4
Age (years) | 12 to 24 | 9 | 0.0 | 0.6 | 19 | 0.0 | 1.2
Age (years) | 25 to 44 | 70 | 0.1 | 3.1 | 146 | 0.2 | 6.4
Age (years) | 45 to 54 | 112 | 0.3 | 3.5 | 235 | 0.6 | 7.3
Age (years) | 55 to 64 | 313 | 0.7 | 7.2 | 632 | 1.5 | 14.6
Age (years) | 65 to 74 | 537 | 1.7 | 8.5 | 1,060 | 3.4 | 16.8
Age (years) | 75 plus | 1,580 | 7.0 | 10.3 | 2,905 | 12.9 | 19.4
Race | White | 2,398 | 0.7 | 36.9 | 4,519 | 1.3 | 66.9
Race | Black | 332 | 0.8 | 10.5 | 566 | 1.3 | 16.1
Race | Other | 106 | 0.4 | 2.2 | 191 | 0.8 | 4.0
Ethnicity | Hispanic | 237 | 0.6 | 6.3 | 402 | 1.0 | 9.7
Ethnicity | Not Hispanic | 2,599 | 0.7 | 43.3 | 4,874 | 1.4 | 77.2
Sex | Female | 1,701 | 0.8 | 27.5 | 3,103 | 1.4 | 48.1
Sex | Male | 1,135 | 0.7 | 22.1 | 2,173 | 1.3 | 38.9
Total | | 2,836 | 0.7 | 49.6 | 5,276 | 1.3 | 87.0

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Gastrointestinal infections (excluding C. difficile) contributed to 5,000 deaths in 2019 (Table 220). Mortality rates (underlying or other cause) were higher among children compared with adolescents and younger adults and then increased with age. Age-adjusted mortality rates were higher among women and non-Hispanics and did not differ by race.

Table 221 Gastrointestinal Infections (exc. C. difficile): Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 6,863 | 0.6% | 9,069 | 0.8%
Age (years) | 12 to 24 | 1,451,892 | 4,595 | 0.3% | 6,335 | 0.4%
Age (years) | 25 to 44 | 2,656,672 | 7,506 | 0.3% | 11,473 | 0.4%
Age (years) | 45 to 54 | 1,452,320 | 3,713 | 0.3% | 6,703 | 0.5%
Age (years) | 55 to 64 | 1,640,216 | 4,038 | 0.2% | 7,891 | 0.5%
Age (years) | 65 to 74 | 2,840,615 | 6,251 | 0.2% | 13,250 | 0.5%
Age (years) | 75 plus | 2,576,241 | 5,661 | 0.2% | 12,428 | 0.5%
Race-ethnicity | White | 8,657,702 | 21,074 | 0.2% | 37,052 | 0.4%
Race-ethnicity | Black | 1,242,477 | 3,801 | 0.3% | 7,231 | 0.6%
Race-ethnicity | Hispanic | 1,493,457 | 5,039 | 0.3% | 9,396 | 0.6%
Race-ethnicity | Asian | 607,284 | 1,370 | 0.2% | 2,421 | 0.4%
Race-ethnicity | Unknown | 1,719,014 | 7,343 | 0.4% | 11,049 | 0.6%
Sex | Female | 7,199,363 | 21,975 | 0.3% | 38,875 | 0.5%
Sex | Male | 6,520,571 | 16,652 | 0.3% | 28,274 | 0.4%
Region | Northeast | 1,526,275 | 4,349 | 0.3% | 7,660 | 0.5%
Region | Midwest | 3,322,846 | 8,389 | 0.3% | 13,719 | 0.4%
Region | South | 5,619,435 | 19,018 | 0.3% | 33,725 | 0.6%
Region | West | 3,251,378 | 6,871 | 0.2% | 12,045 | 0.4%
Total | | 13,719,934 | 38,627 | 0.3% | 67,149 | 0.5%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of gastrointestinal infections (excluding C. difficile) (based on all-listed diagnoses) was 0.5% (Table 221). Prevalence was highest among children and higher among women. It was higher among Blacks and Hispanics compared with Whites and Asians. It was highest in the South, and lowest in the Midwest and West.

Table 222 Gastrointestinal Infections (exc. C. difficile): Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 7,126 | 647 | 9,592 | 870
Age (years) | 12 to 24 | 4,791 | 330 | 6,796 | 468
Age (years) | 25 to 44 | 8,008 | 301 | 12,919 | 486
Age (years) | 45 to 54 | 3,852 | 265 | 7,267 | 500
Age (years) | 55 to 64 | 4,017 | 245 | 8,065 | 492
Age (years) | 65 to 74 | 6,298 | 222 | 13,223 | 465
Age (years) | 75 plus | 5,716 | 222 | 11,860 | 460
Race-ethnicity | White | 21,410 | 247 | 37,151 | 429
Race-ethnicity | Black | 3,880 | 312 | 7,281 | 586
Race-ethnicity | Hispanic | 5,365 | 359 | 10,559 | 707
Race-ethnicity | Asian | 1,466 | 241 | 2,765 | 455
Race-ethnicity | Unknown | 7,687 | 447 | 11,966 | 696
Sex | Female | 22,588 | 314 | 40,674 | 565
Sex | Male | 17,220 | 264 | 29,048 | 445
Region | Northeast | 4,512 | 296 | 8,008 | 525
Region | Midwest | 8,538 | 257 | 13,571 | 408
Region | South | 19,559 | 348 | 34,967 | 622
Region | West | 7,199 | 221 | 13,176 | 405
Total | | 39,808 | 290 | 69,722 | 508

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with gastrointestinal infections (excluding C. difficile) (all-listed diagnoses) were highest among children and were higher among women compared with men (Table 222). Among persons with known race-ethnicity, rates were highest among Hispanics, followed by Blacks, then Asians, and lowest among Whites. Rates were highest in the South, followed by the Northeast, and lowest in the Midwest and West.

Table 223 Gastrointestinal Infections (exc. C. difficile): Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 23 | 2 | 33 | 3
Age (years) | 12 to 24 | 16 | 1 | 35 | 2
Age (years) | 25 to 44 | 117 | 4 | 205 | 8
Age (years) | 45 to 54 | 135 | 9 | 225 | 15
Age (years) | 55 to 64 | 265 | 16 | 458 | 28
Age (years) | 65 to 74 | 553 | 19 | 1,042 | 37
Age (years) | 75 plus | 550 | 21 | 1,085 | 42
Race-ethnicity | White | 1,027 | 12 | 1,888 | 22
Race-ethnicity | Black | 243 | 20 | 445 | 36
Race-ethnicity | Hispanic | 200 | 13 | 412 | 28
Race-ethnicity | Asian | 31 | 5 | 55 | 9
Race-ethnicity | Unknown | 158 | 9 | 283 | 16
Sex | Female | 1,104 | 15 | 2,067 | 29
Sex | Male | 555 | 9 | 1,016 | 16
Region | Northeast | 190 | 12 | 306 | 20
Region | Midwest | 444 | 13 | 720 | 22
Region | South | 804 | 14 | 1,593 | 28
Region | West | 221 | 7 | 464 | 14
Total | | 1,659 | 12 | 3,083 | 22

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with gastrointestinal infections (excluding C. difficile) (all-listed diagnoses) increased with age and were higher among women compared with men (Table 223). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics, then Whites, and lowest among Asians. Rates were highest in the South, followed by the Midwest, then the Northeast, and lowest in the West.

Table 224 Gastrointestinal Infections (exc. C. difficile): Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 105 | 10 | 222 | 20
Age (years) | 12 to 24 | 69 | 5 | 194 | 13
Age (years) | 25 to 44 | 151 | 6 | 550 | 21
Age (years) | 45 to 54 | 213 | 15 | 741 | 51
Age (years) | 55 to 64 | 366 | 22 | 1,511 | 92
Age (years) | 65 to 74 | 744 | 26 | 3,331 | 117
Age (years) | 75 plus | 1,132 | 44 | 4,530 | 176
Race-ethnicity | White | 1,839 | 21 | 7,104 | 82
Race-ethnicity | Black | 347 | 28 | 1,535 | 124
Race-ethnicity | Hispanic | 263 | 18 | 1,216 | 81
Race-ethnicity | Asian | 51 | 8 | 231 | 38
Race-ethnicity | Unknown | 280 | 16 | 993 | 58
Sex | Female | 1,818 | 25 | 6,754 | 94
Sex | Male | 962 | 15 | 4,325 | 66
Region | Northeast | 366 | 24 | 1,571 | 103
Region | Midwest | 603 | 18 | 2,423 | 73
Region | South | 1,352 | 24 | 5,246 | 93
Region | West | 459 | 14 | 1,839 | 57
Total | | 2,780 | 20 | 11,079 | 81

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with gastrointestinal infections (excluding C. difficile) (all-listed diagnoses) were higher among children compared with adolescents and the youngest adults and then increased with age and were higher among women compared with men (Table 224). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 225 Gastrointestinal Infections (exc. C. difficile): Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 30,860 | 0.4% | 56,600 | 0.7%
Age (years) | 70 to 74 | 6,936,940 | 30,000 | 0.4% | 54,300 | 0.8%
Age (years) | 75 to 79 | 4,894,060 | 22,540 | 0.5% | 41,700 | 0.9%
Age (years) | 80 to 84 | 3,335,340 | 17,660 | 0.5% | 30,960 | 0.9%
Age (years) | 85+ | 3,578,120 | 18,360 | 0.5% | 33,000 | 0.9%
Race | White | 22,023,800 | 96,880 | 0.4% | 174,260 | 0.8%
Race | Black | 1,861,660 | 7,740 | 0.4% | 14,300 | 0.8%
Race | Other | 2,925,320 | 14,800 | 0.5% | 28,000 | 1.0%
Sex | Female | 14,975,560 | 77,640 | 0.5% | 139,240 | 0.9%
Sex | Male | 11,835,220 | 41,780 | 0.4% | 77,320 | 0.7%
Region | Northeast | 4,748,700 | 22,820 | 0.5% | 41,000 | 0.9%
Region | Midwest | 6,069,800 | 24,620 | 0.4% | 43,700 | 0.7%
Region | South | 10,595,900 | 50,380 | 0.5% | 90,780 | 0.9%
Region | West | 5,396,380 | 21,600 | 0.4% | 41,080 | 0.8%
Total | | 26,810,780 | 119,420 | 0.4% | 216,560 | 0.8%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of gastrointestinal infections (excluding C. difficile) (based on all-listed diagnoses) was 0.8% (Table 225). Prevalence was highest among persons 75 years and over, higher among women, and did not differ by race. It was highest in the Northeast and South, and lowest in the Midwest.

Table 226 Gastrointestinal Infections (exc. C. difficile): Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 24,660 | 306 | 52,760 | 654
Age (years) | 70 to 74 | 23,740 | 342 | 49,320 | 711
Age (years) | 75 to 79 | 18,760 | 383 | 38,600 | 789
Age (years) | 80 to 84 | 13,260 | 398 | 26,480 | 794
Age (years) | 85+ | 14,620 | 409 | 28,760 | 804
Race | White | 76,520 | 347 | 154,820 | 703
Race | Black | 5,620 | 302 | 12,840 | 690
Race | Other | 12,900 | 441 | 28,260 | 966
Sex | Female | 61,700 | 412 | 126,620 | 846
Sex | Male | 33,340 | 282 | 69,300 | 586
Region | Northeast | 18,980 | 400 | 37,820 | 796
Region | Midwest | 17,460 | 288 | 34,960 | 576
Region | South | 40,720 | 384 | 84,140 | 794
Region | West | 17,880 | 331 | 39,000 | 723
Total | | 95,040 | 354 | 195,920 | 731

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with gastrointestinal infections (excluding C. difficile) (all-listed diagnoses) increased with age and were higher among women compared with men and Whites compared with Blacks (Table 226). Rates were highest in the Northeast and South, followed by the West, and lowest in the Midwest.

Table 227 Gastrointestinal Infections (exc. C. difficile): Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 9,920 | 123 | 17,340 | 215
Age (years) | 70 to 74 | 10,220 | 147 | 17,520 | 253
Age (years) | 75 to 79 | 7,380 | 151 | 13,760 | 281
Age (years) | 80 to 84 | 7,100 | 213 | 12,960 | 389
Age (years) | 85+ | 8,380 | 234 | 16,180 | 452
Race | White | 35,460 | 161 | 63,880 | 290
Race | Black | 3,060 | 164 | 5,680 | 305
Race | Other | 4,480 | 153 | 8,200 | 280
Sex | Female | 28,900 | 193 | 49,900 | 333
Sex | Male | 14,100 | 119 | 27,860 | 235
Region | Northeast | 8,280 | 174 | 15,520 | 327
Region | Midwest | 10,420 | 172 | 18,340 | 302
Region | South | 17,240 | 163 | 30,540 | 288
Region | West | 7,060 | 131 | 13,360 | 248
Total | | 43,000 | 160 | 77,760 | 290

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with gastrointestinal infections (excluding C. difficile) (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 227). Rates were highest in the Northeast, followed by the Midwest, then the South, and lowest in the West.

Table 228 Gastrointestinal Infections (exc. C. difficile): Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 4,660 | 58 | 11,600 | 144
Age (years) | 70 to 74 | 5,380 | 78 | 12,060 | 174
Age (years) | 75 to 79 | 3,920 | 80 | 10,040 | 205
Age (years) | 80 to 84 | 4,080 | 122 | 9,520 | 285
Age (years) | 85+ | 4,880 | 136 | 12,040 | 336
Race | White | 18,920 | 86 | 45,520 | 207
Race | Black | 1,680 | 90 | 3,940 | 212
Race | Other | 2,320 | 79 | 5,800 | 198
Sex | Female | 15,200 | 101 | 34,760 | 232
Sex | Male | 7,720 | 65 | 20,500 | 173
Region | Northeast | 5,020 | 106 | 12,000 | 253
Region | Midwest | 5,500 | 91 | 13,160 | 217
Region | South | 8,720 | 82 | 20,580 | 194
Region | West | 3,680 | 68 | 9,520 | 176
Total | | 22,920 | 85 | 55,260 | 206

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with gastrointestinal infections (excluding C. difficile) (all-listed diagnoses) increased with age and were higher among women compared with men but differed little by race (Table 228). Rates were highest in the Northeast, followed by the Midwest, then the South, and lowest in the West.

## Clostridium difficile

Table 229 Clostridium difficile: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 16 | 34 | 18 | 38
Age (years) | 12 to 24 | 3 | 5 | 3 | 5
Age (years) | 25 to 44 | 15 | 17 | 20 | 24
Age (years) | 45 to 54 | 21 | 48 | 27 | 62
Age (years) | 55 to 64 | 49 | 119 | 56 | 136
Age (years) | 65 to 74 | 28 | 100 | 67 | 245
Age (years) | 75 plus | 39 | 195 | 59 | 291
Race | White | 140 | 47 | 211 | 71
Race | Black | 7 | 18 | 14 | 42
Race | Other | 23 | 80 | 24 | 83
Ethnicity | Hispanic | 23 | 49 | 26 | 56
Ethnicity | Not Hispanic | 147 | 48 | 223 | 70
Sex | Female | 104 | 50 | 166 | 80
Sex | Male | 66 | 39 | 83 | 50
Total | | 170 | 45 | 249 | 67

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Clostridium difficile contributed to 249,000 ambulatory visits (2015) (Table 229). Ambulatory care visit rates (all-listed diagnoses) were higher among children compared with adolescents and younger adults and then increased with age. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and non-Hispanics compared with Hispanics.

Table 230 Clostridium difficile: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 3 | 6 | 5 | 11
Age (years) | 12 to 24 | 4 | 8 | 9 | 16
Age (years) | 25 to 44 | 14 | 16 | 32 | 37
Age (years) | 45 to 54 | 12 | 29 | 31 | 75
Age (years) | 55 to 64 | 18 | 43 | 52 | 123
Age (years) | 65 to 74 | 21 | 68 | 63 | 208
Age (years) | 75 plus | 36 | 162 | 100 | 454
Sex | Female | 70 | 35 | 173 | 85
Sex | Male | 39 | 23 | 120 | 69
Total | | 108 | 29 | 293 | 78

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Clostridium difficile contributed to 293,000 emergency department visits in 2018 (Table 230). Emergency department visit rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men.

Table 231 Clostridium difficile: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 2 | 4 | 5 | 10
Age (years) | 12 to 24 | 3 | 5 | 8 | 15
Age (years) | 25 to 44 | 9 | 10 | 29 | 33
Age (years) | 45 to 54 | 9 | 21 | 30 | 73
Age (years) | 55 to 64 | 15 | 35 | 57 | 135
Age (years) | 65 to 74 | 19 | 63 | 71 | 233
Age (years) | 75 plus | 33 | 149 | 106 | 485
Race | White | 77 | 25 | 254 | 81
Race | Black | 10 | 23 | 40 | 93
Race | Other | 3 | 15 | 15 | 63
Ethnicity | Hispanic | 7 | 18 | 27 | 63
Ethnicity | Not Hispanic | 82 | 25 | 282 | 84
Sex | Female | 57 | 28 | 175 | 85
Sex | Male | 32 | 19 | 132 | 75
Total | | 89 | 23 | 307 | 80

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Clostridium difficile contributed to 307,000 hospital discharges in 2018 (Table 231). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites, and non-Hispanics compared with Hispanics.

Table 232 Clostridium difficile: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 5 | 0.0 | 0.4 | 9 | 0.0 | 0.7
Age (years) | 12 to 24 | 2 | 0.0 | 0.1 | 13 | 0.0 | 0.7
Age (years) | 25 to 44 | 66 | 0.1 | 2.8 | 144 | 0.2 | 6.1
Age (years) | 45 to 54 | 135 | 0.3 | 4.2 | 287 | 0.7 | 8.9
Age (years) | 55 to 64 | 444 | 1.0 | 10.2 | 916 | 2.2 | 21.0
Age (years) | 65 to 74 | 949 | 3.0 | 15.0 | 1,814 | 5.8 | 28.4
Age (years) | 75 plus | 2,940 | 13.0 | 20.0 | 4,956 | 22.0 | 34.6
Race | White | 3,956 | 1.2 | 44.2 | 7,095 | 2.1 | 84.6
Race | Black | 441 | 1.1 | 6.7 | 803 | 1.9 | 12.6
Race | Other | 144 | 0.6 | 1.8 | 241 | 1.0 | 3.3
Ethnicity | Hispanic | 308 | 0.9 | 4.5 | 509 | 1.4 | 8.0
Ethnicity | Not Hispanic | 4,233 | 1.1 | 48.1 | 7,630 | 2.1 | 92.4
Sex | Female | 2,644 | 1.1 | 30.8 | 4,571 | 2.0 | 56.7
Sex | Male | 1,897 | 1.1 | 21.8 | 3,568 | 2.1 | 43.8
Total | | 4,541 | 1.1 | 52.6 | 8,139 | 2.0 | 100.5

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Clostridium difficile contributed to 8,000 deaths in 2019 (Table 232). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Whites, and non-Hispanics.

Table 233 Clostridium difficile: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 56 | 0.0% | 121 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 161 | 0.0% | 308 | 0.0%
Age (years) | 25 to 44 | 2,656,672 | 507 | 0.0% | 965 | 0.0%
Age (years) | 45 to 54 | 1,452,320 | 526 | 0.0% | 1,083 | 0.1%
Age (years) | 55 to 64 | 1,640,216 | 1,128 | 0.1% | 2,503 | 0.2%
Age (years) | 65 to 74 | 2,840,615 | 2,483 | 0.1% | 5,627 | 0.2%
Age (years) | 75 plus | 2,576,241 | 4,530 | 0.2% | 9,292 | 0.4%
Race-ethnicity | White | 8,657,702 | 6,991 | 0.1% | 14,293 | 0.2%
Race-ethnicity | Black | 1,242,477 | 866 | 0.1% | 2,182 | 0.2%
Race-ethnicity | Hispanic | 1,493,457 | 728 | 0.0% | 1,656 | 0.1%
Race-ethnicity | Asian | 607,284 | 147 | 0.0% | 353 | 0.1%
Race-ethnicity | Unknown | 1,719,014 | 659 | 0.0% | 1,415 | 0.1%
Sex | Female | 7,199,363 | 6,141 | 0.1% | 12,325 | 0.2%
Sex | Male | 6,520,571 | 3,250 | 0.0% | 7,574 | 0.1%
Region | Northeast | 1,526,275 | 1,251 | 0.1% | 2,631 | 0.2%
Region | Midwest | 3,322,846 | 2,262 | 0.1% | 4,806 | 0.1%
Region | South | 5,619,435 | 3,892 | 0.1% | 8,361 | 0.1%
Region | West | 3,251,378 | 1,986 | 0.1% | 4,101 | 0.1%
Total | | 13,719,934 | 9,391 | 0.1% | 19,899 | 0.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of Clostridium difficile (based on all-listed diagnoses) was 0.1% (Table 233). C. difficile was uncommon among children and adolescents and the youngest adults and then prevalence increased with age. Prevalence was higher among women and higher among Whites and Blacks compared with Hispanics and Asians. It differed little by region.

Table 234 Clostridium difficile: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 63 | 6 | 147 | 13
Age (years) | 12 to 24 | 222 | 15 | 454 | 31
Age (years) | 25 to 44 | 744 | 28 | 1,533 | 58
Age (years) | 45 to 54 | 765 | 53 | 1,670 | 115
Age (years) | 55 to 64 | 1,771 | 108 | 4,123 | 251
Age (years) | 65 to 74 | 4,218 | 148 | 10,143 | 357
Age (years) | 75 plus | 9,474 | 368 | 21,614 | 839
Race-ethnicity | White | 13,316 | 154 | 29,790 | 344
Race-ethnicity | Black | 1,376 | 111 | 3,631 | 292
Race-ethnicity | Hispanic | 1,206 | 81 | 3,107 | 208
Race-ethnicity | Asian | 221 | 36 | 573 | 94
Race-ethnicity | Unknown | 1,138 | 66 | 2,583 | 150
Sex | Female | 11,239 | 156 | 25,525 | 355
Sex | Male | 6,018 | 92 | 14,159 | 217
Region | Northeast | 2,588 | 170 | 5,918 | 388
Region | Midwest | 3,967 | 119 | 9,593 | 289
Region | South | 6,684 | 119 | 14,887 | 265
Region | West | 4,018 | 124 | 9,286 | 286
Total | | 17,257 | 126 | 39,684 | 289

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with Clostridium difficile (all-listed diagnoses) increased with age and were higher among women compared with men (Table 234). Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the Midwest and West, and lowest in the South.

Table 235 Clostridium difficile: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 1 | 0 | 1 | 0
Age (years) | 12 to 24 | 4 | 0 | 6 | 0
Age (years) | 25 to 44 | 24 | 1 | 39 | 1
Age (years) | 45 to 54 | 28 | 2 | 70 | 5
Age (years) | 55 to 64 | 105 | 6 | 226 | 14
Age (years) | 65 to 74 | 290 | 10 | 612 | 22
Age (years) | 75 plus | 527 | 20 | 1,117 | 43
Race-ethnicity | White | 763 | 9 | 1,586 | 18
Race-ethnicity | Black | 73 | 6 | 174 | 14
Race-ethnicity | Hispanic | 69 | 5 | 149 | 10
Race-ethnicity | Asian | 13 | 2 | 24 | 4
Race-ethnicity | Unknown | 61 | 4 | 138 | 8
Sex | Female | 640 | 9 | 1,324 | 18
Sex | Male | 339 | 5 | 747 | 11
Region | Northeast | 151 | 10 | 290 | 19
Region | Midwest | 298 | 9 | 594 | 18
Region | South | 334 | 6 | 752 | 13
Region | West | 196 | 6 | 435 | 13
Total | | 979 | 7 | 2,071 | 15

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with Clostridium difficile (all-listed diagnoses) increased with age and were higher among women compared with men (Table 235). Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were higher in the Northeast and Midwest compared with the South and West.

Table 236 Clostridium difficile: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 14 | 1 | 65 | 6
Age (years) | 12 to 24 | 33 | 2 | 133 | 9
Age (years) | 25 to 44 | 90 | 3 | 393 | 15
Age (years) | 45 to 54 | 156 | 11 | 662 | 46
Age (years) | 55 to 64 | 371 | 23 | 1,904 | 116
Age (years) | 65 to 74 | 841 | 30 | 4,305 | 152
Age (years) | 75 plus | 1,595 | 62 | 6,788 | 263
Race-ethnicity | White | 2,240 | 26 | 9,845 | 114
Race-ethnicity | Black | 336 | 27 | 1,869 | 150
Race-ethnicity | Hispanic | 269 | 18 | 1,297 | 87
Race-ethnicity | Asian | 37 | 6 | 227 | 37
Race-ethnicity | Unknown | 218 | 13 | 1,012 | 59
Sex | Female | 2,053 | 29 | 8,320 | 116
Sex | Male | 1,047 | 16 | 5,930 | 91
Region | Northeast | 403 | 26 | 1,895 | 124
Region | Midwest | 683 | 21 | 3,449 | 104
Region | South | 1,446 | 26 | 6,209 | 110
Region | West | 568 | 17 | 2,697 | 83
Total | | 3,100 | 23 | 14,250 | 104

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with Clostridium difficile (all-listed diagnoses) increased with age and were higher among women compared with men (Table 236). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the Midwest, and lowest in the West.

Table 237 Clostridium difficile: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 10,820 | 0.1% | 23,040 | 0.3%
Age (years) | 70 to 74 | 6,936,940 | 13,600 | 0.2% | 26,500 | 0.4%
Age (years) | 75 to 79 | 4,894,060 | 14,440 | 0.3% | 25,760 | 0.5%
Age (years) | 80 to 84 | 3,335,340 | 10,100 | 0.3% | 20,060 | 0.6%
Age (years) | 85+ | 3,578,120 | 16,520 | 0.5% | 29,880 | 0.8%
Race | White | 22,023,800 | 57,120 | 0.3% | 106,640 | 0.5%
Race | Black | 1,861,660 | 4,020 | 0.2% | 8,940 | 0.5%
Race | Other | 2,925,320 | 4,340 | 0.1% | 9,660 | 0.3%
Sex | Female | 14,975,560 | 42,500 | 0.3% | 78,120 | 0.5%
Sex | Male | 11,835,220 | 22,980 | 0.2% | 47,120 | 0.4%
Region | Northeast | 4,748,700 | 12,040 | 0.3% | 23,480 | 0.5%
Region | Midwest | 6,069,800 | 16,480 | 0.3% | 30,080 | 0.5%
Region | South | 10,595,900 | 26,420 | 0.2% | 50,320 | 0.5%
Region | West | 5,396,380 | 10,540 | 0.2% | 21,360 | 0.4%
Total | | 26,810,780 | 65,480 | 0.2% | 125,240 | 0.5%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of Clostridium difficile (based on all-listed diagnoses) was 0.5% (Table 237). Prevalence increased with age, was higher among women, and did not differ by race. It differed little by region.

Table 238 Clostridium difficile: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 16,700 | 207 | 41,420 | 513
Age (years) | 70 to 74 | 19,480 | 281 | 49,680 | 716
Age (years) | 75 to 79 | 23,980 | 490 | 52,540 | 1,074
Age (years) | 80 to 84 | 18,820 | 564 | 42,920 | 1,287
Age (years) | 85+ | 31,020 | 867 | 70,900 | 1,981
Race | White | 96,780 | 439 | 225,020 | 1,022
Race | Black | 6,340 | 341 | 15,880 | 853
Race | Other | 6,880 | 235 | 16,560 | 566
Sex | Female | 74,480 | 497 | 169,100 | 1,129
Sex | Male | 35,520 | 300 | 88,360 | 747
Region | Northeast | 22,440 | 473 | 55,240 | 1,163
Region | Midwest | 25,820 | 425 | 59,400 | 979
Region | South | 43,440 | 410 | 98,420 | 929
Region | West | 18,300 | 339 | 44,400 | 823
Total | | 110,000 | 410 | 257,460 | 960

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with Clostridium difficile (all-listed diagnoses) increased with age and were higher among women compared with men and Whites compared with Blacks (Table 238). Rates were highest in the Northeast, followed by the Midwest, then the South, and lowest in the West.

Table 239 Clostridium difficile: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 5,200 | 64 | 15,920 | 197
Age (years) | 70 to 74 | 6,680 | 96 | 18,140 | 261
Age (years) | 75 to 79 | 7,000 | 143 | 18,040 | 369
Age (years) | 80 to 84 | 5,140 | 154 | 14,560 | 437
Age (years) | 85+ | 8,800 | 246 | 22,140 | 619
Race | White | 28,300 | 128 | 73,460 | 334
Race | Black | 2,180 | 117 | 7,980 | 429
Race | Other | 2,340 | 80 | 7,360 | 252
Sex | Female | 21,560 | 144 | 54,480 | 364
Sex | Male | 11,260 | 95 | 34,320 | 290
Region | Northeast | 6,260 | 132 | 17,020 | 358
Region | Midwest | 8,080 | 133 | 21,580 | 356
Region | South | 13,400 | 126 | 34,560 | 326
Region | West | 5,080 | 94 | 15,640 | 290
Total | | 32,820 | 122 | 88,800 | 331

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with Clostridium difficile (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 239). Rates were highest in the Northeast and Midwest, followed by the South, and lowest in the West.

Table 240 Clostridium difficile: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 4,420 | 55 | 18,420 | 228
Age (years) | 70 to 74 | 5,400 | 78 | 19,940 | 287
Age (years) | 75 to 79 | 5,900 | 121 | 19,660 | 402
Age (years) | 80 to 84 | 4,240 | 127 | 15,420 | 462
Age (years) | 85+ | 7,740 | 216 | 22,320 | 624
Race | White | 24,140 | 110 | 78,640 | 357
Race | Black | 1,860 | 100 | 8,900 | 478
Race | Other | 1,700 | 58 | 8,220 | 281
Sex | Female | 18,220 | 122 | 57,100 | 381
Sex | Male | 9,480 | 80 | 38,660 | 327
Region | Northeast | 4,880 | 103 | 17,520 | 369
Region | Midwest | 7,220 | 119 | 23,820 | 392
Region | South | 11,840 | 112 | 38,560 | 364
Region | West | 3,760 | 70 | 15,860 | 294
Total | | 27,700 | 103 | 95,760 | 357

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with Clostridium difficile (all-listed diagnoses) increased with age and were higher among women compared with men and Blacks compared with Whites (Table 240). Rates were highest in the Midwest, followed by the Northeast and South, and lowest in the West.