# Chapter 13 Celiac Disease

Table 205 Celiac Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 5 | 9 | 122 | 251
Age (years) | 12 to 24 | 11 | 19 | 37 | 65
Age (years) | 25 to 44 | 2 | 2 | 138 | 164
Age (years) | 45 to 54 | 18 | 42 | 80 | 186
Age (years) | 55 to 64 | 13 | 31 | 192 | 470
Age (years) | 65 to 74 | 8 | 30 | 19 | 70
Age (years) | 75 plus | 7 | 35 | 22 | 109
Race | White | 63 | 23 | 507 | 199
Race | Black | . | . | 44 | 80
Race | Other | . | . | 59 | 257
Ethnicity | Hispanic | 3 | 6 | 118 | 195
Ethnicity | Not Hispanic | 60 | 21 | 493 | 180
Sex | Female | 47 | 27 | 390 | 247
Sex | Male | 16 | 10 | 220 | 126
Total | | 63 | 18 | 611 | 187

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Celiac disease contributed to 611,000 ambulatory visits (2015) (Table 205). Ambulatory care visit rates (all-listed diagnoses) were highest among persons 55–64 years and second highest among children. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and Hispanics compared with non-Hispanics.

Table 206 Celiac Disease: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 3 | 5
Age (years) | 12 to 24 | 0 | 1 | 10 | 18
Age (years) | 25 to 44 | 0 | 0 | 18 | 21
Age (years) | 45 to 54 | 0 | 0 | 9 | 21
Age (years) | 55 to 64 | 0 | 0 | 9 | 22
Age (years) | 65 to 74 | 0 | 0 | 8 | 26
Age (years) | 75 plus | 0 | 1 | 11 | 51
Sex | Female | 1 | 1 | 50 | 29
Sex | Male | 0 | 0 | 18 | 11
Total | | 1 | 0 | 68 | 20

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Celiac disease contributed to 68,000 emergency department visits in 2018 (Table 206). Emergency department visit rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men.

Table 207 Celiac Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 1 | 2
Age (years) | 12 to 24 | 0 | 0 | 4 | 8
Age (years) | 25 to 44 | 0 | 0 | 10 | 11
Age (years) | 45 to 54 | 0 | 0 | 5 | 12
Age (years) | 55 to 64 | 0 | 0 | 6 | 15
Age (years) | 65 to 74 | 0 | 0 | 7 | 23
Age (years) | 75 plus | 0 | 0 | 9 | 41
Race | White | 1 | 0 | 40 | 14
Race | Black | 0 | 0 | 2 | 3
Race | Other | 0 | 0 | 1 | 4
Ethnicity | Hispanic | 0 | 0 | 2 | 4
Ethnicity | Not Hispanic | 1 | 0 | 40 | 13
Sex | Female | 0 | 0 | 30 | 16
Sex | Male | 0 | 0 | 13 | 7
Total | | 1 | 0 | 42 | 12

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Celiac disease contributed to 42,000 hospital discharges in 2018 (Table 207). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and non-Hispanics compared with Hispanics.

Table 208 Celiac Disease: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | 1 | 0.0 | 0.1
Age (years) | 12 to 24 | . | . | . | . | . | .
Age (years) | 25 to 44 | 2 | 0.0 | 0.1 | 4 | 0.0 | 0.2
Age (years) | 45 to 54 | 1 | 0.0 | 0.0 | 5 | 0.0 | 0.2
Age (years) | 55 to 64 | 3 | 0.0 | 0.1 | 26 | 0.1 | 0.6
Age (years) | 65 to 74 | 10 | 0.0 | 0.2 | 44 | 0.1 | 0.7
Age (years) | 75 plus | 28 | 0.1 | 0.2 | 128 | 0.6 | 0.8
Race | White | 42 | 0.0 | 0.5 | 202 | 0.1 | 2.4
Race | Black | 1 | 0.0 | 0.0 | 2 | 0.0 | 0.0
Race | Other | 1 | 0.0 | 0.0 | 4 | 0.0 | 0.1
Ethnicity | Hispanic | 2 | 0.0 | 0.1 | 6 | 0.0 | 0.1
Ethnicity | Not Hispanic | 42 | 0.0 | 0.5 | 202 | 0.1 | 2.4
Sex | Female | 25 | 0.0 | 0.3 | 130 | 0.1 | 1.5
Sex | Male | 19 | 0.0 | 0.3 | 78 | 0.0 | 1.1
Total | | 44 | 0.0 | 0.6 | 208 | 0.1 | 2.6

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Celiac disease contributed to <1,000 deaths in 2019 (Table 208). Mortality was uncommon with the highest rate (underlying or other cause) among persons 75 years and over. Age-adjusted mortality rates were higher among women, Whites, and non-Hispanics.

Table 209 Celiac Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 492 | 0.0% | 904 | 0.1%
Age (years) | 12 to 24 | 1,451,892 | 1,012 | 0.1% | 2,476 | 0.2%
Age (years) | 25 to 44 | 2,656,672 | 1,072 | 0.0% | 3,555 | 0.1%
Age (years) | 45 to 54 | 1,452,320 | 554 | 0.0% | 2,163 | 0.1%
Age (years) | 55 to 64 | 1,640,216 | 564 | 0.0% | 2,299 | 0.1%
Age (years) | 65 to 74 | 2,840,615 | 954 | 0.0% | 3,555 | 0.1%
Age (years) | 75 plus | 2,576,241 | 587 | 0.0% | 2,909 | 0.1%
Race-ethnicity | White | 8,657,702 | 4,083 | 0.0% | 14,136 | 0.2%
Race-ethnicity | Black | 1,242,477 | 203 | 0.0% | 710 | 0.1%
Race-ethnicity | Hispanic | 1,493,457 | 351 | 0.0% | 1,178 | 0.1%
Race-ethnicity | Asian | 607,284 | 89 | 0.0% | 298 | 0.0%
Race-ethnicity | Unknown | 1,719,014 | 509 | 0.0% | 1,539 | 0.1%
Sex | Female | 7,199,363 | 3,588 | 0.0% | 12,546 | 0.2%
Sex | Male | 6,520,571 | 1,647 | 0.0% | 5,315 | 0.1%
Region | Northeast | 1,526,275 | 976 | 0.1% | 2,948 | 0.2%
Region | Midwest | 3,322,846 | 1,353 | 0.0% | 4,605 | 0.1%
Region | South | 5,619,435 | 1,710 | 0.0% | 5,957 | 0.1%
Region | West | 3,251,378 | 1,196 | 0.0% | 4,351 | 0.1%
Total | | 13,719,934 | 5,235 | 0.0% | 17,861 | 0.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of celiac disease (based on all-listed diagnoses) was 0.1% (Table 209). Prevalence was highest among adolescents and the youngest adults and among women. It was highest among Whites, similar among Blacks and Hispanics, and lowest among Asians. It differed little by region.

Table 210 Celiac Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 710 | 64 | 1,666 | 151
Age (years) | 12 to 24 | 1,405 | 97 | 4,473 | 308
Age (years) | 25 to 44 | 1,448 | 55 | 5,917 | 223
Age (years) | 45 to 54 | 713 | 49 | 3,727 | 257
Age (years) | 55 to 64 | 743 | 45 | 3,947 | 241
Age (years) | 65 to 74 | 1,296 | 46 | 6,340 | 223
Age (years) | 75 plus | 786 | 31 | 5,350 | 208
Race-ethnicity | White | 5,516 | 64 | 24,758 | 286
Race-ethnicity | Black | 280 | 23 | 1,268 | 102
Race-ethnicity | Hispanic | 488 | 33 | 2,251 | 151
Race-ethnicity | Asian | 128 | 21 | 460 | 76
Race-ethnicity | Unknown | 689 | 40 | 2,683 | 156
Sex | Female | 4,857 | 67 | 22,158 | 308
Sex | Male | 2,244 | 34 | 9,262 | 142
Region | Northeast | 1,328 | 87 | 5,253 | 344
Region | Midwest | 1,798 | 54 | 7,704 | 232
Region | South | 2,338 | 42 | 10,788 | 192
Region | West | 1,637 | 50 | 7,675 | 236
Total | | 7,101 | 52 | 31,420 | 229

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with celiac disease (all-listed diagnoses) were higher among adolescents and the youngest adults compared with other age groups and were over twice as high among women compared with men (Table 210). Among persons with known race-ethnicity, rates were highest among Whites, followed by Hispanics, then Blacks, and lowest among Asians. Rates were highest in the Northeast, followed by the West and Midwest, and lowest in the South.

Table 211 Celiac Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 2 | 0 | 3 | 0
Age (years) | 12 to 24 | 5 | 0 | 25 | 2
Age (years) | 25 to 44 | 12 | 0 | 81 | 3
Age (years) | 45 to 54 | 2 | 0 | 9 | 1
Age (years) | 55 to 64 | 5 | 0 | 15 | 1
Age (years) | 65 to 74 | 5 | 0 | 43 | 2
Age (years) | 75 plus | 4 | 0 | 27 | 1
Race-ethnicity | White | 29 | 0 | 171 | 2
Race-ethnicity | Black | 3 | 0 | 6 | 0
Race-ethnicity | Hispanic | 2 | 0 | 6 | 0
Race-ethnicity | Asian | . | . | 3 | 0
Race-ethnicity | Unknown | 1 | 0 | 17 | 1
Sex | Female | 28 | 0 | 163 | 2
Sex | Male | 7 | 0 | 40 | 1
Region | Northeast | 8 | 1 | 42 | 3
Region | Midwest | 8 | 0 | 50 | 2
Region | South | 9 | 0 | 55 | 1
Region | West | 10 | 0 | 56 | 2
Total | | 35 | 0 | 203 | 1

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with celiac disease (all-listed diagnoses) were highest among persons 25 to 44 years and differed little by sex (Table 211). Among persons with known race-ethnicity, rates were higher among Whites compared with other race-ethnicities. Rates were highest in the Northeast, followed by the Midwest and West, and lowest in the South.

Table 212 Celiac Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 2 | 0 | 12 | 1
Age (years) | 12 to 24 | 3 | 0 | 157 | 11
Age (years) | 25 to 44 | . | . | 302 | 11
Age (years) | 45 to 54 | 2 | 0 | 139 | 10
Age (years) | 55 to 64 | 4 | 0 | 276 | 17
Age (years) | 65 to 74 | 7 | 0 | 459 | 16
Age (years) | 75 plus | 3 | 0 | 769 | 30
Race-ethnicity | White | 14 | 0 | 1,691 | 20
Race-ethnicity | Black | . | . | 122 | 10
Race-ethnicity | Hispanic | 2 | 0 | 113 | 8
Race-ethnicity | Asian | . | . | 29 | 5
Race-ethnicity | Unknown | 5 | 0 | 159 | 9
Sex | Female | 11 | 0 | 1,480 | 21
Sex | Male | 10 | 0 | 634 | 10
Region | Northeast | 3 | 0 | 310 | 20
Region | Midwest | 7 | 0 | 609 | 18
Region | South | 6 | 0 | 674 | 12
Region | West | 5 | 0 | 521 | 16
Total | | 21 | 0 | 2,114 | 15

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with celiac disease (all-listed diagnoses) were highest among persons 75 years and over and were twice as high among women compared with men (Table 212). Among persons with known race-ethnicity, rates were highest among Whites, followed by Blacks, then Hispanics, and lowest among Asians. Rates were highest in the Northeast, followed by the Midwest, then the West, and lowest in the South.

Table 213 Celiac Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 3,400 | 0.0% | 13,660 | 0.2%
Age (years) | 70 to 74 | 6,936,940 | 3,200 | 0.0% | 12,720 | 0.2%
Age (years) | 75 to 79 | 4,894,060 | 2,720 | 0.1% | 9,500 | 0.2%
Age (years) | 80 to 84 | 3,335,340 | 1,840 | 0.1% | 7,220 | 0.2%
Age (years) | 85+ | 3,578,120 | 940 | 0.0% | 4,880 | 0.1%
Race | White | 22,023,800 | 11,320 | 0.1% | 44,340 | 0.2%
Race | Black | 1,861,660 | . | . | 680 | 0.0%
Race | Other | 2,925,320 | . | . | 2,960 | 0.1%
Sex | Female | 14,975,560 | 8,560 | 0.1% | 32,980 | 0.2%
Sex | Male | 11,835,220 | 3,540 | 0.0% | 15,000 | 0.1%
Region | Northeast | 4,748,700 | 3,380 | 0.1% | 12,320 | 0.3%
Region | Midwest | 6,069,800 | 2,540 | 0.0% | 11,100 | 0.2%
Region | South | 10,595,900 | 4,100 | 0.0% | 15,760 | 0.1%
Region | West | 5,396,380 | 2,080 | 0.0% | 8,800 | 0.2%
Total | | 26,810,780 | 12,100 | 0.0% | 47,980 | 0.2%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of celiac disease (based on all-listed diagnoses) was 0.2% (Table 213). Prevalence was lowest in the oldest age group and higher among women and Whites. It was highest in the Northeast, and lowest in the South.

Table 214 Celiac Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 4,720 | 59 | 25,400 | 315
Age (years) | 70 to 74 | 4,900 | 71 | 23,900 | 345
Age (years) | 75 to 79 | 3,620 | 74 | 17,200 | 351
Age (years) | 80 to 84 | 2,680 | 80 | 12,480 | 374
Age (years) | 85+ | 1,300 | 36 | 10,320 | 288
Race | White | 16,060 | 73 | 82,580 | 375
Race | Black | . | . | 1,420 | 76
Race | Other | . | . | 5,300 | 181
Sex | Female | 12,440 | 83 | 62,380 | 417
Sex | Male | 4,780 | 40 | 26,920 | 227
Region | Northeast | 4,800 | 101 | 23,200 | 489
Region | Midwest | 3,380 | 56 | 18,980 | 313
Region | South | 5,960 | 56 | 31,380 | 296
Region | West | 3,080 | 57 | 15,740 | 292
Total | | 17,220 | 64 | 89,300 | 333

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with celiac disease (all-listed diagnoses) increased with age until 85 years and were higher among women compared with men and almost five times higher among Whites compared with Blacks (Table 214). Rates were highest in the Northeast, followed by the Midwest, and lowest in the South and West.

Table 215 Celiac Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | . | . | 2,580 | 32
Age (years) | 70 to 74 | . | . | 3,140 | 45
Age (years) | 75 to 79 | . | . | 3,300 | 67
Age (years) | 80 to 84 | . | . | 2,780 | 83
Age (years) | 85+ | . | . | 2,400 | 67
Race | White | . | . | 13,260 | 60
Race | Black | . | . | . | .
Race | Other | . | . | . | .
Sex | Female | . | . | 10,240 | 68
Sex | Male | . | . | 3,960 | 33
Region | Northeast | . | . | 3,540 | 75
Region | Midwest | . | . | 2,940 | 48
Region | South | . | . | 5,100 | 48
Region | West | . | . | 2,620 | 49
Total | | . | . | 14,200 | 53

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visits with celiac disease were uncommon among Blacks (Table 215). Rates (all-listed diagnoses) increased with age until 85 years and were twice as high among women compared with men. Rates were higher in the Northeast compared with the Midwest, South, and West.

Table 216 Celiac Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | . | . | 2,160 | 27
Age (years) | 70 to 74 | . | . | 2,560 | 37
Age (years) | 75 to 79 | . | . | 2,560 | 52
Age (years) | 80 to 84 | . | . | 1,940 | 58
Age (years) | 85+ | . | . | 2,140 | 60
Race | White | . | . | 10,580 | 48
Race | Black | . | . | . | .
Race | Other | . | . | . | .
Sex | Female | . | . | 7,880 | 53
Sex | Male | . | . | 3,480 | 29
Region | Northeast | . | . | 2,960 | 62
Region | Midwest | . | . | 2,420 | 40
Region | South | . | . | 3,820 | 36
Region | West | . | . | 2,160 | 40
Total | | . | . | 11,360 | 42

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharges with celiac disease were uncommon among Blacks (Table 216). Rates (all-listed diagnoses) increased with age and were higher among women compared with men. Rates were higher in the Northeast compared with the South, Midwest, and West.