# Chapter 12 Pancreatic Disease

## Acute Pancreatitis

Table 181 Acute Pancreatitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 2 | 5 | 2 | 5
Age (years) | 12 to 24 | 25 | 45 | 32 | 57
Age (years) | 25 to 44 | 113 | 133 | 202 | 239
Age (years) | 45 to 54 | 165 | 383 | 234 | 543
Age (years) | 55 to 64 | 86 | 212 | 236 | 578
Age (years) | 65 to 74 | 32 | 117 | 125 | 453
Age (years) | 75 plus | 21 | 103 | 66 | 325
Race | White | 391 | 158 | 720 | 275
Race | Black | 47 | 111 | 161 | 333
Race | Other | 7 | 31 | 16 | 78
Ethnicity | Hispanic | 73 | 140 | 125 | 265
Ethnicity | Not Hispanic | 371 | 144 | 772 | 269
Sex | Female | 239 | 155 | 484 | 282
Sex | Male | 206 | 125 | 413 | 250
Total | | 445 | 140 | 897 | 264

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Acute pancreatitis contributed to 897,000 ambulatory visits (2015) (Table 181). Ambulatory care visit rates (all-listed diagnoses) peaked among persons 55–64 years. Age-adjusted ambulatory care visit rates were higher among women compared with men, Blacks compared with Whites and among non-Hispanics compared with Hispanics.

Table 182 Acute Pancreatitis: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 2 | 4 | 3 | 6
Age (years) | 12 to 24 | 20 | 36 | 31 | 55
Age (years) | 25 to 44 | 123 | 141 | 177 | 203
Age (years) | 45 to 54 | 82 | 197 | 122 | 294
Age (years) | 55 to 64 | 73 | 173 | 115 | 273
Age (years) | 65 to 74 | 44 | 144 | 74 | 243
Age (years) | 75 plus | 33 | 152 | 62 | 284
Sex | Female | 172 | 98 | 274 | 154
Sex | Male | 206 | 125 | 310 | 187
Total | | 377 | 111 | 585 | 170

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Acute pancreatitis contributed to 585,000 emergency department visits in 2018 (Table 182). Emergency department visit rates (all-listed diagnoses) were similar among middle-aged and older adults. Age-adjusted emergency department visit rates were higher among men.

Table 183 Acute Pancreatitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 2 | 3 | 3 | 6
Age (years) | 12 to 24 | 14 | 25 | 22 | 40
Age (years) | 25 to 44 | 88 | 101 | 126 | 145
Age (years) | 45 to 54 | 60 | 144 | 88 | 212
Age (years) | 55 to 64 | 56 | 133 | 89 | 211
Age (years) | 65 to 74 | 35 | 116 | 63 | 207
Age (years) | 75 plus | 29 | 131 | 56 | 256
Race | White | 221 | 82 | 351 | 127
Race | Black | 48 | 108 | 71 | 159
Race | Other | 17 | 65 | 29 | 112
Ethnicity | Hispanic | 40 | 76 | 66 | 130
Ethnicity | Not Hispanic | 247 | 86 | 386 | 131
Sex | Female | 131 | 74 | 213 | 118
Sex | Male | 153 | 92 | 235 | 140
Total | | 283 | 83 | 448 | 129

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Acute pancreatitis contributed to 448,000 hospital discharges in 2018 (Table 183). Hospital discharge rates (all-listed diagnoses) were highest among persons 75 years and over. Age-adjusted rates were higher among women compared with men, Blacks compared with Whites and among non-Hispanics compared with Hispanics.

Table 184 Acute Pancreatitis: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 2 | 0.0 | 0.1 | 4 | 0.0 | 0.3
Age (years) | 12 to 24 | 39 | 0.1 | 2.3 | 67 | 0.1 | 3.9
Age (years) | 25 to 44 | 398 | 0.5 | 17.2 | 721 | 0.8 | 31.1
Age (years) | 45 to 54 | 335 | 0.8 | 10.3 | 698 | 1.7 | 21.5
Age (years) | 55 to 64 | 586 | 1.4 | 13.4 | 1,186 | 2.8 | 27.1
Age (years) | 65 to 74 | 599 | 1.9 | 9.4 | 1,216 | 3.9 | 19.2
Age (years) | 75 plus | 861 | 3.8 | 6.4 | 1,802 | 8.0 | 13.2
Race | White | 2,368 | 0.8 | 48.2 | 4,724 | 1.5 | 94.0
Race | Black | 342 | 0.8 | 8.0 | 720 | 1.6 | 16.4
Race | Other | 110 | 0.4 | 2.8 | 250 | 1.0 | 5.8
Ethnicity | Hispanic | 178 | 0.4 | 4.7 | 409 | 0.9 | 10.4
Ethnicity | Not Hispanic | 2,642 | 0.8 | 54.3 | 5,285 | 1.6 | 105.9
Sex | Female | 1,120 | 0.5 | 21.3 | 2,314 | 1.1 | 44.0
Sex | Male | 1,700 | 1.0 | 37.7 | 3,380 | 1.9 | 72.3
Total | | 2,820 | 0.7 | 59.0 | 5,694 | 1.5 | 116.3

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Acute pancreatitis contributed to 6,000 deaths in 2019 (Table 184). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Blacks, and non-Hispanics.

Table 185 Acute Pancreatitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 38 | 0.0% | 60 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 319 | 0.0% | 452 | 0.0%
Age (years) | 25 to 44 | 2,656,672 | 2,242 | 0.1% | 3,163 | 0.1%
Age (years) | 45 to 54 | 1,452,320 | 2,140 | 0.1% | 3,168 | 0.2%
Age (years) | 55 to 64 | 1,640,216 | 3,022 | 0.2% | 4,874 | 0.3%
Age (years) | 65 to 74 | 2,840,615 | 4,546 | 0.2% | 7,676 | 0.3%
Age (years) | 75 plus | 2,576,241 | 3,895 | 0.2% | 7,019 | 0.3%
Race-ethnicity | White | 8,657,702 | 10,530 | 0.1% | 17,037 | 0.2%
Race-ethnicity | Black | 1,242,477 | 2,157 | 0.2% | 3,495 | 0.3%
Race-ethnicity | Hispanic | 1,493,457 | 1,891 | 0.1% | 3,202 | 0.2%
Race-ethnicity | Asian | 607,284 | 384 | 0.1% | 613 | 0.1%
Race-ethnicity | Unknown | 1,719,014 | 1,240 | 0.1% | 2,065 | 0.1%
Sex | Female | 7,199,363 | 8,071 | 0.1% | 13,427 | 0.2%
Sex | Male | 6,520,571 | 8,131 | 0.1% | 12,985 | 0.2%
Region | Northeast | 1,526,275 | 1,682 | 0.1% | 2,835 | 0.2%
Region | Midwest | 3,322,846 | 3,583 | 0.1% | 5,519 | 0.2%
Region | South | 5,619,435 | 7,728 | 0.1% | 12,685 | 0.2%
Region | West | 3,251,378 | 3,209 | 0.1% | 5,373 | 0.2%
Total | | 13,719,934 | 16,202 | 0.1% | 26,412 | 0.2%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of acute pancreatitis (based on all-listed diagnoses) was 0.2% (Table 185). Prevalence was uncommon among children and adolescents and the youngest adults and was highest among persons 55 years and over. It did not differ by sex and was highest among Blacks, similar among Whites and Hispanics, and lowest among Asians. It did not differ by region.

Table 186 Acute Pancreatitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 57 | 5 | 103 | 9
Age (years) | 12 to 24 | 500 | 34 | 747 | 51
Age (years) | 25 to 44 | 3,239 | 122 | 5,445 | 205
Age (years) | 45 to 54 | 2,949 | 203 | 5,122 | 353
Age (years) | 55 to 64 | 3,706 | 226 | 7,100 | 433
Age (years) | 65 to 74 | 4,545 | 160 | 9,265 | 326
Age (years) | 75 plus | 3,875 | 150 | 8,178 | 317
Race-ethnicity | White | 12,681 | 146 | 24,018 | 277
Race-ethnicity | Black | 2,193 | 177 | 4,229 | 340
Race-ethnicity | Hispanic | 2,106 | 141 | 4,104 | 275
Race-ethnicity | Asian | 458 | 75 | 847 | 139
Race-ethnicity | Unknown | 1,433 | 83 | 2,762 | 161
Sex | Female | 9,178 | 127 | 17,955 | 249
Sex | Male | 9,693 | 149 | 18,005 | 276
Region | Northeast | 1,800 | 118 | 3,619 | 237
Region | Midwest | 4,655 | 140 | 8,089 | 243
Region | South | 8,586 | 153 | 16,873 | 300
Region | West | 3,830 | 118 | 7,379 | 227
Total | | 18,871 | 138 | 35,960 | 262

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with acute pancreatitis (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among men compared with women (Table 186). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Rates were higher in the South compared with the West, Northeast, and Midwest.

Table 187 Acute Pancreatitis: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 3 | 0 | 3 | 0
Age (years) | 12 to 24 | 13 | 1 | 16 | 1
Age (years) | 25 to 44 | 290 | 11 | 410 | 15
Age (years) | 45 to 54 | 537 | 37 | 848 | 58
Age (years) | 55 to 64 | 1,177 | 72 | 1,799 | 110
Age (years) | 65 to 74 | 2,678 | 94 | 4,235 | 149
Age (years) | 75 plus | 2,302 | 89 | 3,788 | 147
Race-ethnicity | White | 4,478 | 52 | 7,023 | 81
Race-ethnicity | Black | 1,051 | 85 | 1,684 | 136
Race-ethnicity | Hispanic | 764 | 51 | 1,257 | 84
Race-ethnicity | Asian | 135 | 22 | 199 | 33
Race-ethnicity | Unknown | 572 | 33 | 936 | 54
Sex | Female | 3,632 | 50 | 5,779 | 80
Sex | Male | 3,368 | 52 | 5,320 | 82
Region | Northeast | 869 | 57 | 1,222 | 80
Region | Midwest | 1,420 | 43 | 2,083 | 63
Region | South | 3,372 | 60 | 5,478 | 97
Region | West | 1,339 | 41 | 2,316 | 71
Total | | 7,000 | 51 | 11,099 | 81

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with acute pancreatitis (all-listed diagnoses) increased with age until 75 years and differed little by sex (Table 187). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics and Whites, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 188 Acute Pancreatitis: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 24 | 2 | 47 | 4
Age (years) | 12 to 24 | 160 | 11 | 275 | 19
Age (years) | 25 to 44 | 1,408 | 53 | 2,214 | 83
Age (years) | 45 to 54 | 1,351 | 93 | 2,183 | 150
Age (years) | 55 to 64 | 1,774 | 108 | 3,260 | 199
Age (years) | 65 to 74 | 2,562 | 90 | 5,308 | 187
Age (years) | 75 plus | 2,139 | 83 | 5,008 | 194
Race-ethnicity | White | 6,064 | 70 | 11,760 | 136
Race-ethnicity | Black | 1,338 | 108 | 2,444 | 197
Race-ethnicity | Hispanic | 1,061 | 71 | 2,222 | 149
Race-ethnicity | Asian | 207 | 34 | 407 | 67
Race-ethnicity | Unknown | 748 | 44 | 1,462 | 85
Sex | Female | 4,548 | 63 | 9,065 | 126
Sex | Male | 4,870 | 75 | 9,230 | 142
Region | Northeast | 948 | 62 | 2,008 | 132
Region | Midwest | 2,218 | 67 | 4,034 | 121
Region | South | 4,494 | 80 | 8,618 | 153
Region | West | 1,758 | 54 | 3,635 | 112
Total | | 9,418 | 69 | 18,295 | 133

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with acute pancreatitis (all-listed diagnoses) increased with age until 65 years and were higher among men compared with women (Table 188). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics, then Whites, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 189 Acute Pancreatitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 16,500 | 0.2% | 26,020 | 0.3%
Age (years) | 70 to 74 | 6,936,940 | 15,740 | 0.2% | 25,420 | 0.4%
Age (years) | 75 to 79 | 4,894,060 | 9,940 | 0.2% | 16,660 | 0.3%
Age (years) | 80 to 84 | 3,335,340 | 7,680 | 0.2% | 13,300 | 0.4%
Age (years) | 85+ | 3,578,120 | 8,300 | 0.2% | 13,740 | 0.4%
Race | White | 22,023,800 | 47,040 | 0.2% | 75,520 | 0.3%
Race | Black | 1,861,660 | 4,440 | 0.2% | 7,920 | 0.4%
Race | Other | 2,925,320 | 6,680 | 0.2% | 11,700 | 0.4%
Sex | Female | 14,975,560 | 30,500 | 0.2% | 50,440 | 0.3%
Sex | Male | 11,835,220 | 27,660 | 0.2% | 44,700 | 0.4%
Region | Northeast | 4,748,700 | 8,820 | 0.2% | 14,740 | 0.3%
Region | Midwest | 6,069,800 | 13,340 | 0.2% | 21,160 | 0.3%
Region | South | 10,595,900 | 24,840 | 0.2% | 40,080 | 0.4%
Region | West | 5,396,380 | 11,160 | 0.2% | 19,160 | 0.4%
Total | | 26,810,780 | 58,160 | 0.2% | 95,140 | 0.4%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of acute pancreatitis (based on all-listed diagnoses) was 0.4% (Table 189). Prevalence differed little with age and was higher among men and Blacks. It differed little by region.

Table 190 Acute Pancreatitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 14,000 | 174 | 30,100 | 373
Age (years) | 70 to 74 | 14,300 | 206 | 29,240 | 422
Age (years) | 75 to 79 | 9,320 | 190 | 18,500 | 378
Age (years) | 80 to 84 | 6,620 | 198 | 14,180 | 425
Age (years) | 85+ | 7,920 | 221 | 14,780 | 413
Race | White | 44,560 | 202 | 88,520 | 402
Race | Black | 2,500 | 134 | 6,360 | 342
Race | Other | 5,100 | 174 | 11,920 | 407
Sex | Female | 25,920 | 173 | 53,540 | 358
Sex | Male | 26,240 | 222 | 53,260 | 450
Region | Northeast | 9,060 | 191 | 18,140 | 382
Region | Midwest | 12,320 | 203 | 25,220 | 415
Region | South | 21,280 | 201 | 43,080 | 407
Region | West | 9,500 | 176 | 20,360 | 377
Total | | 52,160 | 195 | 106,800 | 398

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with acute pancreatitis (all-listed diagnoses) were relatively stable with age and were higher among men compared with women and Whites compared with Blacks (Table 190). Rates were higher in the Midwest and South compared with the Northeast and West.

Table 191 Acute Pancreatitis: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 15,480 | 192 | 23,280 | 289
Age (years) | 70 to 74 | 13,920 | 201 | 21,100 | 304
Age (years) | 75 to 79 | 8,920 | 182 | 14,560 | 298
Age (years) | 80 to 84 | 6,900 | 207 | 11,640 | 349
Age (years) | 85+ | 7,700 | 215 | 12,660 | 354
Race | White | 42,480 | 193 | 65,660 | 298
Race | Black | 4,480 | 241 | 7,440 | 400
Race | Other | 5,960 | 204 | 10,140 | 347
Sex | Female | 27,700 | 185 | 43,820 | 293
Sex | Male | 25,220 | 213 | 39,420 | 333
Region | Northeast | 8,060 | 170 | 12,620 | 266
Region | Midwest | 11,940 | 197 | 17,860 | 294
Region | South | 22,640 | 214 | 36,080 | 341
Region | West | 10,280 | 190 | 16,680 | 309
Total | | 52,920 | 197 | 83,240 | 310

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with acute pancreatitis (all-listed diagnoses) generally increased with age and were higher among men compared with women and Blacks compared with Whites (Table 191). Rates were highest in the South, followed by the West, then the Midwest, and lowest in the Northeast.

Table 192 Acute Pancreatitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 9,840 | 122 | 17,340 | 215
Age (years) | 70 to 74 | 9,160 | 132 | 16,200 | 234
Age (years) | 75 to 79 | 5,600 | 114 | 10,920 | 223
Age (years) | 80 to 84 | 4,480 | 134 | 8,860 | 266
Age (years) | 85+ | 5,360 | 150 | 10,420 | 291
Race | White | 28,480 | 129 | 51,340 | 233
Race | Black | 2,460 | 132 | 4,900 | 263
Race | Other | 3,500 | 120 | 7,500 | 256
Sex | Female | 17,760 | 119 | 33,120 | 221
Sex | Male | 16,680 | 141 | 30,620 | 259
Region | Northeast | 5,100 | 107 | 9,820 | 207
Region | Midwest | 8,660 | 143 | 15,020 | 247
Region | South | 14,700 | 139 | 26,540 | 250
Region | West | 5,980 | 111 | 12,360 | 229
Total | | 34,440 | 128 | 63,740 | 238

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with acute pancreatitis (all-listed diagnoses) generally increased with age and were higher among men compared with women and Blacks compared with Whites (Table 192). Rates were highest in the South and Midwest, followed by the West, and lowest in the Northeast.

## Chronic Pancreatitis

Table 193 Chronic Pancreatitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | . | . | 3 | 5
Age (years) | 25 to 44 | 16 | 19 | 54 | 64
Age (years) | 45 to 54 | 40 | 92 | 86 | 199
Age (years) | 55 to 64 | 9 | 22 | 49 | 119
Age (years) | 65 to 74 | 31 | 114 | 36 | 129
Age (years) | 75 plus | 1 | 7 | 19 | 93
Race | White | 86 | 30 | 228 | 81
Race | Black | 11 | 27 | 16 | 37
Race | Other | . | . | 2 | 7
Ethnicity | Hispanic | 74 | 168 | 91 | 206
Ethnicity | Not Hispanic | 23 | 9 | 154 | 52
Sex | Female | 40 | 28 | 107 | 67
Sex | Male | 57 | 30 | 138 | 80
Total | | 97 | 28 | 245 | 71

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Chronic pancreatitis contributed to 245,000 ambulatory visits (2015) (Table 193). Ambulatory care visit rates (all-listed diagnoses) peaked in middle age. Age-adjusted rates were higher among men compared with women, Whites compared with Blacks, and Hispanics compared with non-Hispanics.

Table 194 Chronic Pancreatitis: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 1 | 2
Age (years) | 12 to 24 | 1 | 2 | 6 | 10
Age (years) | 25 to 44 | 15 | 17 | 78 | 90
Age (years) | 45 to 54 | 10 | 25 | 69 | 165
Age (years) | 55 to 64 | 8 | 19 | 62 | 147
Age (years) | 65 to 74 | 2 | 8 | 29 | 94
Age (years) | 75 plus | 1 | 4 | 19 | 85
Sex | Female | 16 | 10 | 114 | 65
Sex | Male | 22 | 13 | 149 | 89
Total | | 38 | 12 | 263 | 77

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Chronic pancreatitis contributed to 263,000 emergency department visits in 2018 (Table 194). Emergency department visit rates (all-listed diagnoses) peaked in middle age. Age-adjusted rates were higher among men compared with women.

Table 195 Chronic Pancreatitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 1 | 2
Age (years) | 12 to 24 | 1 | 1 | 5 | 8
Age (years) | 25 to 44 | 3 | 4 | 51 | 58
Age (years) | 45 to 54 | 3 | 7 | 47 | 112
Age (years) | 55 to 64 | 2 | 5 | 47 | 112
Age (years) | 65 to 74 | 1 | 4 | 25 | 83
Age (years) | 75 plus | 1 | 3 | 17 | 76
Race | White | 8 | 3 | 143 | 52
Race | Black | 2 | 5 | 42 | 93
Race | Other | 1 | 2 | 9 | 34
Ethnicity | Hispanic | 1 | 2 | 18 | 35
Ethnicity | Not Hispanic | 10 | 4 | 176 | 60
Sex | Female | 5 | 3 | 84 | 47
Sex | Male | 6 | 3 | 109 | 64
Total | | 11 | 3 | 192 | 55

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Chronic pancreatitis contributed to 192,000 hospital discharges in 2018 (Table 195). Hospital discharge rates (all-listed diagnoses) peaked in middle age. Age-adjusted rates were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics.

Table 196 Chronic Pancreatitis: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | 4 | 0.0 | 0.3
Age (years) | 12 to 24 | 4 | 0.0 | 0.2 | 10 | 0.0 | 0.6
Age (years) | 25 to 44 | 44 | 0.1 | 1.9 | 193 | 0.2 | 8.2
Age (years) | 45 to 54 | 66 | 0.2 | 2.0 | 274 | 0.7 | 8.4
Age (years) | 55 to 64 | 118 | 0.3 | 2.7 | 458 | 1.1 | 10.5
Age (years) | 65 to 74 | 75 | 0.2 | 1.2 | 317 | 1.0 | 5.0
Age (years) | 75 plus | 112 | 0.5 | 0.8 | 337 | 1.5 | 2.5
Race | White | 324 | 0.1 | 6.7 | 1,259 | 0.4 | 28.0
Race | Black | 86 | 0.2 | 1.8 | 291 | 0.6 | 6.3
Race | Other | 9 | 0.0 | 0.2 | 43 | 0.2 | 1.2
Ethnicity | Hispanic | 23 | 0.0 | 0.6 | 64 | 0.1 | 1.7
Ethnicity | Not Hispanic | 396 | 0.1 | 8.2 | 1,529 | 0.5 | 33.9
Sex | Female | 156 | 0.1 | 3.3 | 640 | 0.3 | 14.8
Sex | Male | 263 | 0.1 | 5.5 | 953 | 0.5 | 20.7
Total | | 419 | 0.1 | 8.8 | 1,593 | 0.4 | 35.5

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Chronic pancreatitis contributed to 2,000 deaths in 2019 (Table 196). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Blacks, and non-Hispanics.

Table 197 Chronic Pancreatitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 9 | 0.0% | 15 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 54 | 0.0% | 110 | 0.0%
Age (years) | 25 to 44 | 2,656,672 | 484 | 0.0% | 1,168 | 0.0%
Age (years) | 45 to 54 | 1,452,320 | 669 | 0.0% | 1,704 | 0.1%
Age (years) | 55 to 64 | 1,640,216 | 1,157 | 0.1% | 3,288 | 0.2%
Age (years) | 65 to 74 | 2,840,615 | 1,530 | 0.1% | 4,823 | 0.2%
Age (years) | 75 plus | 2,576,241 | 963 | 0.0% | 4,092 | 0.2%
Race-ethnicity | White | 8,657,702 | 3,269 | 0.0% | 9,973 | 0.1%
Race-ethnicity | Black | 1,242,477 | 705 | 0.1% | 2,201 | 0.2%
Race-ethnicity | Hispanic | 1,493,457 | 404 | 0.0% | 1,520 | 0.1%
Race-ethnicity | Asian | 607,284 | 131 | 0.0% | 368 | 0.1%
Race-ethnicity | Unknown | 1,719,014 | 357 | 0.0% | 1,138 | 0.1%
Sex | Female | 7,199,363 | 2,364 | 0.0% | 7,456 | 0.1%
Sex | Male | 6,520,571 | 2,502 | 0.0% | 7,744 | 0.1%
Region | Northeast | 1,526,275 | 532 | 0.0% | 1,579 | 0.1%
Region | Midwest | 3,322,846 | 1,101 | 0.0% | 3,151 | 0.1%
Region | South | 5,619,435 | 2,312 | 0.0% | 7,271 | 0.1%
Region | West | 3,251,378 | 921 | 0.0% | 3,199 | 0.1%
Total | | 13,719,934 | 4,866 | 0.0% | 15,200 | 0.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of chronic pancreatitis (based on all-listed diagnoses) was 0.1% (Table 197). Chronic pancreatitis was uncommon among children and adolescents and the youngest adults and prevalence was highest among persons 55 years and over. Prevalence did not differ by sex and was highest among Blacks and similar among Whites, Hispanics, and Asians. It did not differ by region.

Table 198 Chronic Pancreatitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 9 | 1 | 25 | 2
Age (years) | 12 to 24 | 84 | 6 | 211 | 15
Age (years) | 25 to 44 | 1,006 | 38 | 2,884 | 109
Age (years) | 45 to 54 | 1,429 | 98 | 4,514 | 311
Age (years) | 55 to 64 | 2,269 | 138 | 7,853 | 479
Age (years) | 65 to 74 | 2,453 | 86 | 9,100 | 320
Age (years) | 75 plus | 1,468 | 57 | 6,576 | 255
Race-ethnicity | White | 5,832 | 67 | 20,509 | 237
Race-ethnicity | Black | 1,253 | 101 | 4,667 | 376
Race-ethnicity | Hispanic | 711 | 48 | 2,906 | 195
Race-ethnicity | Asian | 242 | 40 | 703 | 116
Race-ethnicity | Unknown | 680 | 40 | 2,378 | 138
Sex | Female | 4,342 | 60 | 15,938 | 221
Sex | Male | 4,376 | 67 | 15,225 | 233
Region | Northeast | 866 | 57 | 2,994 | 196
Region | Midwest | 2,044 | 62 | 6,668 | 201
Region | South | 4,187 | 75 | 14,983 | 267
Region | West | 1,621 | 50 | 6,518 | 200
Total | | 8,718 | 64 | 31,163 | 227

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with chronic pancreatitis (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among men compared with women (Table 198). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were higher in the South compared with the Northeast, West, and Midwest.

Table 199 Chronic Pancreatitis: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 1 | 0 | 1 | 0
Age (years) | 12 to 24 | . | . | 1 | 0
Age (years) | 25 to 44 | 58 | 2 | 119 | 4
Age (years) | 45 to 54 | 114 | 8 | 264 | 18
Age (years) | 55 to 64 | 202 | 12 | 455 | 28
Age (years) | 65 to 74 | 155 | 5 | 395 | 14
Age (years) | 75 plus | 50 | 2 | 177 | 7
Race-ethnicity | White | 330 | 4 | 862 | 10
Race-ethnicity | Black | 146 | 12 | 294 | 24
Race-ethnicity | Hispanic | 41 | 3 | 116 | 8
Race-ethnicity | Asian | 5 | 1 | 14 | 2
Race-ethnicity | Unknown | 58 | 3 | 126 | 7
Sex | Female | 249 | 3 | 631 | 9
Sex | Male | 331 | 5 | 781 | 12
Region | Northeast | 52 | 3 | 157 | 10
Region | Midwest | 121 | 4 | 270 | 8
Region | South | 335 | 6 | 760 | 14
Region | West | 72 | 2 | 225 | 7
Total | | 580 | 4 | 1,412 | 10

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with chronic pancreatitis (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among men compared with women (Table 199). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the South, followed by the Northeast, and lowest in the Midwest and West.

Table 200 Chronic Pancreatitis: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 1 | 0 | 9 | 1
Age (years) | 12 to 24 | 4 | 0 | 58 | 4
Age (years) | 25 to 44 | 34 | 1 | 746 | 28
Age (years) | 45 to 54 | 51 | 4 | 1,046 | 72
Age (years) | 55 to 64 | 78 | 5 | 1,893 | 115
Age (years) | 65 to 74 | 75 | 3 | 2,211 | 78
Age (years) | 75 plus | 22 | 1 | 1,611 | 63
Race-ethnicity | White | 169 | 2 | 4,784 | 55
Race-ethnicity | Black | 54 | 4 | 1,369 | 110
Race-ethnicity | Hispanic | 23 | 2 | 700 | 47
Race-ethnicity | Asian | 3 | 0 | 117 | 19
Race-ethnicity | Unknown | 16 | 1 | 604 | 35
Sex | Female | 140 | 2 | 3,521 | 49
Sex | Male | 125 | 2 | 4,053 | 62
Region | Northeast | 28 | 2 | 819 | 54
Region | Midwest | 62 | 2 | 1,726 | 52
Region | South | 125 | 2 | 3,708 | 66
Region | West | 50 | 2 | 1,321 | 41
Total | | 265 | 2 | 7,574 | 55

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with chronic pancreatitis (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among men compared with women (Table 200). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites, then Hispanics, and lowest among Asians. Rates were highest in the South, followed by the Northeast and Midwest, and lowest in the West.

Table 201 Chronic Pancreatitis: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 5,540 | 0.1% | 16,180 | 0.2%
Age (years) | 70 to 74 | 6,936,940 | 4,700 | 0.1% | 13,000 | 0.2%
Age (years) | 75 to 79 | 4,894,060 | 2,940 | 0.1% | 9,740 | 0.2%
Age (years) | 80 to 84 | 3,335,340 | 1,780 | 0.1% | 6,740 | 0.2%
Age (years) | 85+ | 3,578,120 | 1,640 | 0.0% | 6,260 | 0.2%
Race | White | 22,023,800 | 13,880 | 0.1% | 41,980 | 0.2%
Race | Black | 1,861,660 | 1,380 | 0.1% | 5,160 | 0.3%
Race | Other | 2,925,320 | 1,340 | 0.0% | 4,780 | 0.2%
Sex | Female | 14,975,560 | 7,920 | 0.1% | 26,220 | 0.2%
Sex | Male | 11,835,220 | 8,680 | 0.1% | 25,700 | 0.2%
Region | Northeast | 4,748,700 | 2,600 | 0.1% | 9,020 | 0.2%
Region | Midwest | 6,069,800 | 3,240 | 0.1% | 11,400 | 0.2%
Region | South | 10,595,900 | 7,660 | 0.1% | 22,200 | 0.2%
Region | West | 5,396,380 | 3,100 | 0.1% | 9,300 | 0.2%
Total | | 26,810,780 | 16,600 | 0.1% | 51,920 | 0.2%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of chronic pancreatitis (based on all-listed diagnoses) was 0.2% (Table 201). Prevalence did not differ by age or sex and was higher among Blacks. It did not differ by region.

Table 202 Chronic Pancreatitis: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 9,360 | 116 | 30,540 | 379
Age (years) | 70 to 74 | 7,120 | 103 | 23,280 | 336
Age (years) | 75 to 79 | 5,100 | 104 | 18,880 | 386
Age (years) | 80 to 84 | 2,380 | 71 | 11,140 | 334
Age (years) | 85+ | 1,840 | 51 | 7,660 | 214
Race | White | 21,900 | 99 | 74,580 | 339
Race | Black | 1,760 | 95 | 8,920 | 479
Race | Other | 2,140 | 73 | 8,000 | 273
Sex | Female | 12,360 | 83 | 47,000 | 314
Sex | Male | 13,440 | 114 | 44,500 | 376
Region | Northeast | 3,600 | 76 | 14,200 | 299
Region | Midwest | 6,040 | 100 | 21,100 | 348
Region | South | 11,420 | 108 | 40,020 | 378
Region | West | 4,740 | 88 | 16,180 | 300
Total | | 25,800 | 96 | 91,500 | 341

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with chronic pancreatitis (all-listed diagnoses) were generally stable before declining after 85 years and were higher among men compared with women and Blacks compared with Whites (Table 202). Rates were highest in the South, followed by the Midwest, and lowest in the West and Northeast.

Table 203 Chronic Pancreatitis: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 1,380 | 17 | 10,100 | 125
Age (years) | 70 to 74 | 680 | 10 | 6,300 | 91
Age (years) | 75 to 79 | . | . | 4,820 | 98
Age (years) | 80 to 84 | . | . | 3,100 | 93
Age (years) | 85+ | 260 | 7 | 3,760 | 105
Race | White | 1,840 | 8 | 21,300 | 97
Race | Black | . | . | 4,560 | 245
Race | Other | . | . | 2,220 | 76
Sex | Female | 1,380 | 9 | 13,960 | 93
Sex | Male | 1,400 | 12 | 14,120 | 119
Region | Northeast | 240 | 5 | 4,460 | 94
Region | Midwest | 580 | 10 | 7,040 | 116
Region | South | 1,340 | 13 | 11,360 | 107
Region | West | 620 | 11 | 5,220 | 97
Total | | 2,780 | 10 | 28,080 | 105

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with chronic pancreatitis (all-listed diagnoses) were highest among persons 65 to 69 years and were higher among men compared with women and over twice as high among Blacks compared with Whites (Table 203). Rates were highest in the Midwest, followed by the South, then the West, and lowest in the Northeast.

Table 204 Chronic Pancreatitis: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 360 | 4 | 8,280 | 103
Age (years) | 70 to 74 | 280 | 4 | 5,940 | 86
Age (years) | 75 to 79 | . | . | 4,800 | 98
Age (years) | 80 to 84 | . | . | 2,480 | 74
Age (years) | 85+ | . | . | 3,000 | 84
Race | White | 640 | 3 | 19,100 | 87
Race | Black | . | . | 3,520 | 189
Race | Other | . | . | 1,880 | 64
Sex | Female | 540 | 4 | 12,340 | 82
Sex | Male | 340 | 3 | 12,160 | 103
Region | Northeast | . | . | 3,880 | 82
Region | Midwest | . | . | 6,480 | 107
Region | South | 440 | 4 | 10,040 | 95
Region | West | . | . | 4,100 | 76
Total | | 880 | 3 | 24,500 | 91

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with chronic pancreatitis (all-listed diagnoses) were highest among persons 65 to 69 years and were higher among men compared with women and over twice as high among Blacks compared with Whites (Table 204). Rates were highest in the Midwest, followed by the South, then the Northeast, and lowest in the West.

## Pancreatic Cancer

Table 262 Pancreatic Cancer: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | . | 0.0
Age (years) | 12 to 24 | . | 0.1
Age (years) | 25 to 44 | 1,194 | 1.4
Age (years) | 45 to 54 | 3,851 | 9.3
Age (years) | 55 to 64 | 11,352 | 26.9
Age (years) | 65 to 74 | 17,152 | 56.3
Age (years) | 75 plus | 20,125 | 91.7
Race | White | 43,366 | 13.3
Race | Black | 6,430 | 15.6
Race | Other | 3,001 | 11.1
Ethnicity | Hispanic | 4,925 | 12.8
Ethnicity | Not Hispanic | 45,662 | 13.3
Sex | Female | 24,496 | 11.5
Sex | Male | 27,063 | 15.4
Total | | 51,567 | 13.3

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Pancreatic cancer accounted for 52,000 incident cases in 2016 (Table 262). Pancreatic cancer was rare among children and adolescents and incidence rates increased with age throughout adulthood. Age-adjusted incidence rates were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2016, age-adjusted incidence rates (per 100,000) increased by 18% from 11.3 to 13.3 (4)

Table 263 Pancreatic Cancer: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 0
Age (years) | 12 to 24 | 0 | 0 | 0 | 0
Age (years) | 25 to 44 | 1 | 1 | 3 | 3
Age (years) | 45 to 54 | 3 | 8 | 10 | 23
Age (years) | 55 to 64 | 9 | 22 | 27 | 65
Age (years) | 65 to 74 | 12 | 39 | 37 | 122
Age (years) | 75 plus | 12 | 53 | 33 | 152
Race | White | 30 | 9 | 89 | 26
Race | Black | 5 | 12 | 16 | 35
Race | Other | 3 | 12 | 7 | 30
Ethnicity | Hispanic | 3 | 8 | 10 | 24
Ethnicity | Not Hispanic | 34 | 9 | 102 | 28
Sex | Female | 19 | 9 | 54 | 24
Sex | Male | 18 | 10 | 57 | 30
Total | | 37 | 9 | 110 | 27

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Pancreatic cancer contributed to 110,000 hospital discharges in 2018 (Table 263). Pancreatic cancer hospitalization was rare among children and adolescents and hospital discharge rates increased with age throughout adulthood. Age-adjusted hospital discharge rates (all-listed diagnoses) were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by 17% from 23 to 27.(4)

Table 264 Pancreatic Cancer: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 1 | 0.0 | 0.1 | 1 | 0.0 | 0.1
Age (years) | 12 to 24 | 7 | 0.0 | 0.4 | 8 | 0.0 | 0.5
Age (years) | 25 to 44 | 534 | 0.6 | 21.5 | 565 | 0.6 | 22.7
Age (years) | 45 to 54 | 2,454 | 6.0 | 74.7 | 2,551 | 6.2 | 77.7
Age (years) | 55 to 64 | 9,068 | 21.4 | 205.6 | 9,456 | 22.3 | 214.4
Age (years) | 65 to 74 | 14,448 | 45.9 | 227.7 | 15,173 | 48.2 | 238.9
Age (years) | 75 plus | 19,444 | 86.1 | 155.9 | 20,570 | 91.1 | 164.7
Race | White | 38,345 | 11.0 | 566.0 | 40,315 | 11.6 | 593.2
Race | Black | 5,810 | 13.3 | 92.0 | 6,123 | 14.1 | 96.7
Race | Other | 1,801 | 7.3 | 27.8 | 1,886 | 7.6 | 29.0
Ethnicity | Hispanic | 2,941 | 7.4 | 53.4 | 3,087 | 7.8 | 56.0
Ethnicity | Not Hispanic | 43,015 | 11.4 | 632.4 | 45,237 | 12.0 | 662.8
Sex | Female | 22,176 | 9.6 | 333.4 | 23,224 | 10.1 | 348.3
Sex | Male | 23,780 | 12.7 | 352.4 | 25,100 | 13.4 | 370.5
Total | | 45,956 | 11.0 | 685.8 | 48,324 | 11.6 | 718.8

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Pancreatic cancer contributed to 48,000 deaths in 2019 (Table 264). Pancreatic cancer mortality was rare among children and adolescents and mortality rates increased with age throughout adulthood. Age-adjusted mortality rates (underlying or other cause) were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with pancreatic cancer as underlying or other cause increased by 3% from 11.3 to 11.6.(4)