# Chapter 11 Gallbladder and Biliary Tract Disease

## Gallstones

Table 169 Gallstones: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 2 | 4 | 2 | 4
Age (years) | 12 to 24 | 123 | 219 | 148 | 263
Age (years) | 25 to 44 | 383 | 453 | 565 | 669
Age (years) | 45 to 54 | 233 | 542 | 467 | 1,084
Age (years) | 55 to 64 | 328 | 804 | 414 | 1,015
Age (years) | 65 to 74 | 172 | 624 | 389 | 1,415
Age (years) | 75 plus | 113 | 558 | 218 | 1,080
Race | White | 1,139 | 426 | 1,901 | 691
Race | Black | 147 | 313 | 172 | 380
Race | Other | 67 | 235 | 131 | 519
Ethnicity | Hispanic | 491 | 1,029 | 600 | 1,254
Ethnicity | Not Hispanic | 863 | 305 | 1,604 | 554
Sex | Female | 899 | 546 | 1,466 | 870
Sex | Male | 454 | 255 | 738 | 418
Total | | 1,354 | 397 | 2,204 | 642

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gallstones contributed to an estimated 2.2 million ambulatory visits (2015) (Table 169). Ambulatory care visits rates (all-listed diagnoses) were highest among persons 65–74 years. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and Hispanics compared with non-Hispanics.

Table 170 Gallstones: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 2 | 2 | 5
Age (years) | 12 to 24 | 71 | 128 | 97 | 175
Age (years) | 25 to 44 | 238 | 273 | 335 | 385
Age (years) | 45 to 54 | 97 | 234 | 163 | 390
Age (years) | 55 to 64 | 88 | 208 | 179 | 423
Age (years) | 65 to 74 | 71 | 234 | 169 | 553
Age (years) | 75 plus | 67 | 305 | 205 | 935
Sex | Female | 437 | 260 | 734 | 417
Sex | Male | 196 | 117 | 416 | 243
Total | | 633 | 188 | 1,149 | 328

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gallstones contributed to an estimated 1.1 million emergency department visits in 2018 (Table 170). Emergency department visit rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men.

Table 171 Gallstones: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 1 | 2 | 4
Age (years) | 12 to 24 | 18 | 32 | 29 | 52
Age (years) | 25 to 44 | 67 | 78 | 114 | 131
Age (years) | 45 to 54 | 38 | 91 | 77 | 186
Age (years) | 55 to 64 | 45 | 107 | 108 | 256
Age (years) | 65 to 74 | 46 | 149 | 121 | 397
Age (years) | 75 plus | 53 | 243 | 164 | 746
Race | White | 222 | 78 | 502 | 169
Race | Black | 27 | 61 | 72 | 165
Race | Other | 21 | 82 | 48 | 188
Ethnicity | Hispanic | 58 | 112 | 112 | 233
Ethnicity | Not Hispanic | 213 | 69 | 510 | 158
Sex | Female | 166 | 92 | 353 | 186
Sex | Male | 102 | 59 | 263 | 151
Total | | 268 | 75 | 615 | 167

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gallstones contributed to an estimated 615,000 hospital discharges in 2018 (Table 171). Hospital discharge rates (all-listed diagnoses) increased with age. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and Hispanics compared with non-Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis decreased by 21% from 212 to 167.(7) Hospital discharge rates underestimate the actual burden because most hospitalizations with gallstones were for cholecystectomy and a high proportion of cholecystectomies were performed laparoscopically without an overnight stay, and therefore, were not included in hospitalization statistics.

Table 172 Gallstones: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 1 | 0.0 | 0.1 | 3 | 0.0 | 0.2
Age (years) | 25 to 44 | 21 | 0.0 | 0.9 | 61 | 0.1 | 2.6
Age (years) | 45 to 54 | 38 | 0.1 | 1.2 | 66 | 0.2 | 2.1
Age (years) | 55 to 64 | 99 | 0.2 | 2.3 | 190 | 0.4 | 4.4
Age (years) | 65 to 74 | 181 | 0.6 | 2.8 | 307 | 1.0 | 4.8
Age (years) | 75 plus | 710 | 3.1 | 4.4 | 1,169 | 5.2 | 7.4
Race | White | 892 | 0.3 | 9.8 | 1,517 | 0.4 | 17.6
Race | Black | 77 | 0.2 | 1.0 | 154 | 0.4 | 2.4
Race | Other | 81 | 0.4 | 0.9 | 125 | 0.5 | 1.5
Ethnicity | Hispanic | 99 | 0.3 | 1.4 | 157 | 0.4 | 2.5
Ethnicity | Not Hispanic | 951 | 0.3 | 10.3 | 1,639 | 0.4 | 19.0
Sex | Female | 564 | 0.2 | 5.9 | 959 | 0.4 | 10.9
Sex | Male | 486 | 0.3 | 5.7 | 837 | 0.5 | 10.5
Total | | 1,050 | 0.3 | 11.7 | 1,796 | 0.4 | 21.5

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Gallstones contributed to an estimated 2,000 deaths in 2019 (Table 172). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men and did not differ by race or ethnicity. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with gallstone disease as underlying or other cause decreased by 43% from 0.7 to 0.4.(4)

Table 173 Gallstones: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 36 | 0.0% | 82 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 1,211 | 0.1% | 1,547 | 0.1%
Age (years) | 25 to 44 | 2,656,672 | 8,239 | 0.3% | 10,843 | 0.4%
Age (years) | 45 to 54 | 1,452,320 | 5,509 | 0.4% | 8,212 | 0.6%
Age (years) | 55 to 64 | 1,640,216 | 6,963 | 0.4% | 12,254 | 0.7%
Age (years) | 65 to 74 | 2,840,615 | 13,714 | 0.5% | 26,749 | 0.9%
Age (years) | 75 plus | 2,576,241 | 12,840 | 0.5% | 30,192 | 1.2%
Race-ethnicity | White | 8,657,702 | 31,245 | 0.4% | 57,469 | 0.7%
Race-ethnicity | Black | 1,242,477 | 4,746 | 0.4% | 9,305 | 0.7%
Race-ethnicity | Hispanic | 1,493,457 | 7,159 | 0.5% | 12,949 | 0.9%
Race-ethnicity | Asian | 607,284 | 1,460 | 0.2% | 3,019 | 0.5%
Race-ethnicity | Unknown | 1,719,014 | 3,902 | 0.2% | 7,137 | 0.4%
Sex | Female | 7,199,363 | 30,418 | 0.4% | 52,778 | 0.7%
Sex | Male | 6,520,571 | 18,094 | 0.3% | 37,101 | 0.6%
Region | Northeast | 1,526,275 | 5,166 | 0.3% | 10,209 | 0.7%
Region | Midwest | 3,322,846 | 10,772 | 0.3% | 18,438 | 0.6%
Region | South | 5,619,435 | 22,296 | 0.4% | 41,418 | 0.7%
Region | West | 3,251,378 | 10,278 | 0.3% | 19,814 | 0.6%
Total | | 13,719,934 | 48,512 | 0.4% | 89,879 | 0.7%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of gallstones (based on all-listed diagnoses) was 0.7% (Table 173). Prevalence increased with age and was higher among women. It was highest among Hispanics, similar among Whites and Blacks, and lowest among Asians. It differed little by region.

Table 174 Gallstones: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 51 | 5 | 115 | 10
Age (years) | 12 to 24 | 2,211 | 152 | 2,883 | 199
Age (years) | 25 to 44 | 14,812 | 558 | 20,158 | 759
Age (years) | 45 to 54 | 9,409 | 648 | 14,121 | 972
Age (years) | 55 to 64 | 10,982 | 670 | 19,041 | 1,161
Age (years) | 65 to 74 | 19,796 | 697 | 37,835 | 1,332
Age (years) | 75 plus | 16,815 | 653 | 38,397 | 1,490
Race-ethnicity | White | 47,672 | 551 | 84,416 | 975
Race-ethnicity | Black | 7,180 | 578 | 13,137 | 1,057
Race-ethnicity | Hispanic | 11,029 | 738 | 19,525 | 1,307
Race-ethnicity | Asian | 2,152 | 354 | 4,656 | 767
Race-ethnicity | Unknown | 6,043 | 352 | 10,816 | 629
Sex | Female | 48,371 | 672 | 82,723 | 1,149
Sex | Male | 25,705 | 394 | 49,827 | 764
Region | Northeast | 7,416 | 486 | 14,458 | 947
Region | Midwest | 16,514 | 497 | 27,831 | 838
Region | South | 34,550 | 615 | 61,224 | 1,090
Region | West | 15,596 | 480 | 29,037 | 893
Total | | 74,076 | 540 | 132,550 | 966

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with gallstones (all-listed diagnoses) increased with age and were higher among women compared with men (Table 174). Among persons with known race-ethnicity, rates were highest among Hispanics, followed by Blacks, then Whites, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 175 Gallstones: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 33 | 2 | 52 | 4
Age (years) | 25 to 44 | 328 | 12 | 542 | 20
Age (years) | 45 to 54 | 301 | 21 | 503 | 35
Age (years) | 55 to 64 | 693 | 42 | 1,215 | 74
Age (years) | 65 to 74 | 2,783 | 98 | 5,048 | 178
Age (years) | 75 plus | 2,979 | 116 | 6,000 | 233
Race-ethnicity | White | 4,534 | 52 | 8,558 | 99
Race-ethnicity | Black | 789 | 64 | 1,515 | 122
Race-ethnicity | Hispanic | 1,016 | 68 | 1,814 | 121
Race-ethnicity | Asian | 172 | 28 | 340 | 56
Race-ethnicity | Unknown | 606 | 35 | 1,133 | 66
Sex | Female | 4,215 | 59 | 7,754 | 108
Sex | Male | 2,902 | 45 | 5,606 | 86
Region | Northeast | 921 | 60 | 1,545 | 101
Region | Midwest | 1,499 | 45 | 2,706 | 81
Region | South | 2,981 | 53 | 5,800 | 103
Region | West | 1,716 | 53 | 3,309 | 102
Total | | 7,117 | 52 | 13,360 | 97

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with gallstones (all-listed diagnoses) increased with age and were higher among women compared with men (Table 175). Among persons with known race-ethnicity, rates were highest among Blacks and Hispanics, followed by Whites, and lowest among Asians. Rates were lower in the Midwest compared with the South, West, and Northeast.

Table 176 Gallstones: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 3 | 0 | 29 | 3
Age (years) | 12 to 24 | 132 | 9 | 259 | 18
Age (years) | 25 to 44 | 830 | 31 | 1,766 | 66
Age (years) | 45 to 54 | 670 | 46 | 1,716 | 118
Age (years) | 55 to 64 | 1,109 | 68 | 3,526 | 215
Age (years) | 65 to 74 | 2,847 | 100 | 9,549 | 336
Age (years) | 75 plus | 4,128 | 160 | 15,044 | 584
Race-ethnicity | White | 6,342 | 73 | 20,616 | 238
Race-ethnicity | Black | 926 | 75 | 3,565 | 287
Race-ethnicity | Hispanic | 1,441 | 96 | 4,412 | 295
Race-ethnicity | Asian | 264 | 43 | 837 | 138
Race-ethnicity | Unknown | 746 | 43 | 2,459 | 143
Sex | Female | 5,441 | 76 | 16,727 | 232
Sex | Male | 4,278 | 66 | 15,162 | 233
Region | Northeast | 1,320 | 86 | 4,145 | 272
Region | Midwest | 2,059 | 62 | 6,564 | 198
Region | South | 4,204 | 75 | 14,278 | 254
Region | West | 2,136 | 66 | 6,902 | 212
Total | | 9,719 | 71 | 31,889 | 232

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with gallstones (all-listed diagnoses) increased with age and differed little by sex (Table 176). Among persons with known race-ethnicity, rates were highest among Hispanics, followed by Blacks, then Whites, and lowest among Asians. Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 177 Gallstones: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 56,600 | 0.7% | 105,120 | 1.3%
Age (years) | 70 to 74 | 6,936,940 | 53,220 | 0.8% | 105,220 | 1.5%
Age (years) | 75 to 79 | 4,894,060 | 41,060 | 0.8% | 84,680 | 1.7%
Age (years) | 80 to 84 | 3,335,340 | 32,620 | 1.0% | 70,320 | 2.1%
Age (years) | 85+ | 3,578,120 | 34,720 | 1.0% | 77,220 | 2.2%
Race | White | 22,023,800 | 178,220 | 0.8% | 359,020 | 1.6%
Race | Black | 1,861,660 | 13,680 | 0.7% | 29,380 | 1.6%
Race | Other | 2,925,320 | 26,320 | 0.9% | 54,160 | 1.9%
Sex | Female | 14,975,560 | 121,980 | 0.8% | 237,800 | 1.6%
Sex | Male | 11,835,220 | 96,240 | 0.8% | 204,760 | 1.7%
Region | Northeast | 4,748,700 | 37,900 | 0.8% | 80,840 | 1.7%
Region | Midwest | 6,069,800 | 46,320 | 0.8% | 91,140 | 1.5%
Region | South | 10,595,900 | 90,360 | 0.9% | 181,020 | 1.7%
Region | West | 5,396,380 | 43,640 | 0.8% | 89,560 | 1.7%
Total | | 26,810,780 | 218,220 | 0.8% | 442,560 | 1.7%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of gallstones (based on all-listed diagnoses) was 1.7% (Table 177). Prevalence increased with age, was higher among men, and did not differ by race. It was lower in the Midwest compared with other regions.

Table 178 Gallstones: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 67,100 | 832 | 132,220 | 1,639
Age (years) | 70 to 74 | 60,220 | 868 | 127,760 | 1,842
Age (years) | 75 to 79 | 44,580 | 911 | 98,400 | 2,011
Age (years) | 80 to 84 | 32,480 | 974 | 75,720 | 2,270
Age (years) | 85+ | 29,720 | 831 | 73,600 | 2,057
Race | White | 192,640 | 875 | 410,820 | 1,865
Race | Black | 12,440 | 668 | 29,220 | 1,570
Race | Other | 29,020 | 992 | 67,660 | 2,313
Sex | Female | 135,260 | 903 | 286,460 | 1,913
Sex | Male | 98,840 | 835 | 221,240 | 1,869
Region | Northeast | 41,460 | 873 | 99,840 | 2,102
Region | Midwest | 49,200 | 811 | 101,620 | 1,674
Region | South | 98,260 | 927 | 203,340 | 1,919
Region | West | 45,180 | 837 | 102,900 | 1,907
Total | | 234,100 | 873 | 507,700 | 1,894

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with gallstones (all-listed diagnoses) increased with age until 85 years and were higher among women compared with men and Whites compared with Blacks (Table 178). Rates were highest in the Northeast, intermediate in the South and West, and lowest in the Midwest.

Table 179 Gallstones: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 25,800 | 320 | 53,680 | 665
Age (years) | 70 to 74 | 25,340 | 365 | 55,220 | 796
Age (years) | 75 to 79 | 20,860 | 426 | 47,900 | 979
Age (years) | 80 to 84 | 17,760 | 532 | 43,640 | 1,308
Age (years) | 85+ | 23,180 | 648 | 58,780 | 1,643
Race | White | 90,480 | 411 | 206,440 | 937
Race | Black | 8,400 | 451 | 21,460 | 1,153
Race | Other | 14,060 | 481 | 31,320 | 1,071
Sex | Female | 60,720 | 405 | 134,780 | 900
Sex | Male | 52,220 | 441 | 124,440 | 1,051
Region | Northeast | 19,600 | 413 | 44,740 | 942
Region | Midwest | 23,120 | 381 | 54,360 | 896
Region | South | 46,140 | 435 | 107,020 | 1,010
Region | West | 24,080 | 446 | 53,100 | 984
Total | | 112,940 | 421 | 259,220 | 967

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with gallstones (all-listed diagnoses) increased with age and were higher among men compared with women and Blacks compared with Whites (Table 179). Rates were highest in the South, followed by the West, then the Northeast, and lowest in the Midwest.

Table 180 Gallstones: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 10,680 | 132 | 30,300 | 376
Age (years) | 70 to 74 | 11,620 | 168 | 33,480 | 483
Age (years) | 75 to 79 | 10,120 | 207 | 29,180 | 596
Age (years) | 80 to 84 | 8,980 | 269 | 28,700 | 860
Age (years) | 85+ | 12,040 | 336 | 37,040 | 1,035
Race | White | 43,540 | 198 | 126,060 | 572
Race | Black | 3,220 | 173 | 12,360 | 664
Race | Other | 6,680 | 228 | 20,280 | 693
Sex | Female | 27,600 | 184 | 82,140 | 548
Sex | Male | 25,840 | 218 | 76,560 | 647
Region | Northeast | 9,700 | 204 | 27,380 | 577
Region | Midwest | 12,480 | 206 | 35,660 | 587
Region | South | 21,100 | 199 | 64,320 | 607
Region | West | 10,160 | 188 | 31,340 | 581
Total | | 53,440 | 199 | 158,700 | 592

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with gallstones (all-listed diagnoses) increased with age and were higher among men compared with women and Blacks compared with Whites (Table 180). Rates were higher in the South compared with the Northeast, West, and Midwest.

## Bile Duct Cancer

Table 256 Bile Duct Cancer: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | . | 0.0
Age (years) | 12 to 24 | . | .
Age (years) | 25 to 44 | 425 | 0.5
Age (years) | 45 to 54 | 936 | 2.2
Age (years) | 55 to 64 | 2,889 | 6.8
Age (years) | 65 to 74 | 4,056 | 13.3
Age (years) | 75 plus | 4,932 | 22.5
Race | White | 10,361 | 3.2
Race | Black | 1,217 | 3.0
Race | Other | 1,090 | 4.0
Ethnicity | Hispanic | 1,542 | 4.1
Ethnicity | Not Hispanic | 11,007 | 3.2
Sex | Female | 5,878 | 2.8
Sex | Male | 6,840 | 3.9
Total | | 12,720 | 3.3

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Bile duct cancer accounted for 13,000 incident cases in 2016 (Table 256). Bile duct cancer was rare among children and adolescents and incidence rates increased with age throughout adulthood. Age-adjusted mortality rates (underlying or other cause) were higher among men compared with women, Whites compared with Blacks, and Hispanics compared with non-Hispanics. Between 2004 and 2016, age-adjusted incidence rates (per 100,000) increased by 43% from 2.3 to 3.3.(4)

Table 257 Bile Duct Cancer: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 0 | 0
Age (years) | 12 to 24 | 0 | 0 | 0 | 0
Age (years) | 25 to 44 | 0 | 0 | 2 | 2
Age (years) | 45 to 54 | 1 | 3 | 3 | 8
Age (years) | 55 to 64 | 3 | 7 | 8 | 19
Age (years) | 65 to 74 | 4 | 12 | 11 | 35
Age (years) | 75 plus | 3 | 16 | 10 | 44
Race | White | 9 | 3 | 27 | 8
Race | Black | 1 | 3 | 3 | 8
Race | Other | 1 | 5 | 4 | 14
Ethnicity | Hispanic | 1 | 4 | 4 | 10
Ethnicity | Not Hispanic | 10 | 3 | 30 | 8
Sex | Female | 5 | 2 | 16 | 7
Sex | Male | 6 | 3 | 18 | 10
Total | | 11 | 3 | 34 | 8

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Bile duct cancer contributed to 34,000 hospital discharges in 2018 (Table 257). Bile duct cancer hospitalization was rare among children and adolescents and hospital discharge rates increased with age throughout adulthood. Age-adjusted hospital discharge rates (all-listed diagnoses) were higher among men compared with women and Hispanics compared with non-Hispanics but did not differ by race. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by a third from 6 to 8.(4)

Table 258 Bile Duct Cancer: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 10 | 0.0 | 0.6 | 11 | 0.0 | 0.6
Age (years) | 25 to 44 | 247 | 0.3 | 10.5 | 267 | 0.3 | 11.4
Age (years) | 45 to 54 | 617 | 1.5 | 19.3 | 664 | 1.6 | 20.8
Age (years) | 55 to 64 | 1,963 | 4.6 | 45.1 | 2,142 | 5.0 | 49.1
Age (years) | 65 to 74 | 3,130 | 9.9 | 49.8 | 3,422 | 10.9 | 54.4
Age (years) | 75 plus | 3,871 | 17.1 | 31.4 | 4,250 | 18.8 | 34.5
Race | White | 8,175 | 2.4 | 129.5 | 8,942 | 2.6 | 141.2
Race | Black | 946 | 2.2 | 15.8 | 1,045 | 2.4 | 17.5
Race | Other | 717 | 2.9 | 11.4 | 769 | 3.1 | 12.0
Ethnicity | Hispanic | 909 | 2.2 | 18.2 | 1,004 | 2.4 | 20.0
Ethnicity | Not Hispanic | 8,929 | 2.4 | 138.5 | 9,752 | 2.6 | 150.9
Sex | Female | 4,756 | 2.1 | 78.4 | 5,147 | 2.3 | 84.7
Sex | Male | 5,082 | 2.7 | 78.3 | 5,609 | 3.0 | 86.2
Total | | 9,838 | 2.4 | 156.7 | 10,756 | 2.6 | 170.8

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Bile duct cancer contributed to 11,000 deaths in 2019 (Table 258). Bile duct cancer mortality was rare among children and adolescents and mortality rates increased with age throughout adulthood. Age-adjusted mortality rates (underlying or other cause) were higher among men compared with women, Whites compared with Blacks, and non-Hispanics compared with Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with bile duct cancer as underlying or other cause increased by 44% from 1.8 to 2.6.(4)

## Gallbladder Cancer

Table 259 Gallbladder Cancer: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | . | .
Age (years) | 12 to 24 | . | .
Age (years) | 25 to 44 | . | 0.1
Age (years) | 45 to 54 | 326 | 0.8
Age (years) | 55 to 64 | 604 | 1.4
Age (years) | 65 to 74 | 1,315 | 4.3
Age (years) | 75 plus | 2,009 | 9.2
Race | White | 2,886 | 0.9
Race | Black | 748 | 1.9
Race | Other | 433 | 1.6
Ethnicity | Hispanic | 583 | 1.6
Ethnicity | Not Hispanic | 3,551 | 1.1
Sex | Female | 2,923 | 1.4
Sex | Male | 1,254 | 0.8
Total | | 4,173 | 1.1

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gallbladder cancer accounted for an estimated 4,000 incident cases in 2016 (Table 259). Gallbladder cancer was rare among children, adolescents, and younger adults and incidence rates increased with age throughout middle and older age. In contrast to all other common digestive cancers, age-adjusted incidence rates were higher among women compared with men. Incidence rates were higher among Blacks compared with Whites and among Hispanics compared with non-Hispanics. Since 2004, age-adjusted rates (per 100,000) for incidence have remained stable at 1.1.(4)

Table 260 Gallbladder Cancer: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 0 | 0
Age (years) | 12 to 24 | . | . | . | .
Age (years) | 25 to 44 | 0 | 0 | 0 | 0
Age (years) | 45 to 54 | 0 | 1 | 1 | 2
Age (years) | 55 to 64 | 1 | 2 | 2 | 4
Age (years) | 65 to 74 | 1 | 3 | 2 | 8
Age (years) | 75 plus | 1 | 4 | 3 | 11
Race | White | 2 | 1 | 5 | 2
Race | Black | 1 | 1 | 1 | 3
Race | Other | 0 | 1 | 1 | 4
Ethnicity | Hispanic | 0 | 1 | 1 | 3
Ethnicity | Not Hispanic | 2 | 1 | 7 | 2
Sex | Female | 2 | 1 | 5 | 2
Sex | Male | 1 | 0 | 2 | 1
Total | | 3 | 1 | 8 | 2

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Gallbladder cancer contributed to 8,000 hospital discharges in 2018 (Table 260). Gallbladder cancer hospitalization was rare among children, adolescents, and younger adults and hospital discharge rates increased with age throughout middle and older age. In contrast to all other common digestive cancers, age-adjusted hospital discharge rates (all-listed diagnoses) were higher among women compared with men. Hospital discharge rates were higher among Blacks compared with Whites and among Hispanics compared with non-Hispanics. Since 2004, age-adjusted hospital discharge rates have remained stable at 2.(4)

Table 261 Gallbladder Cancer: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | . | . | . | . | . | .
Age (years) | 25 to 44 | 18 | 0.0 | 0.8 | 21 | 0.0 | 0.9
Age (years) | 45 to 54 | 138 | 0.3 | 4.4 | 147 | 0.4 | 4.7
Age (years) | 55 to 64 | 404 | 1.0 | 9.5 | 429 | 1.0 | 10.1
Age (years) | 65 to 74 | 628 | 2.0 | 10.2 | 671 | 2.1 | 10.9
Age (years) | 75 plus | 952 | 4.2 | 7.7 | 1,036 | 4.6 | 8.3
Race | White | 1,614 | 0.5 | 24.4 | 1,732 | 0.5 | 26.1
Race | Black | 374 | 0.9 | 5.9 | 404 | 0.9 | 6.3
Race | Other | 152 | 0.6 | 2.3 | 168 | 0.7 | 2.6
Ethnicity | Hispanic | 289 | 0.7 | 5.8 | 312 | 0.8 | 6.4
Ethnicity | Not Hispanic | 1,851 | 0.5 | 26.8 | 1,992 | 0.5 | 28.6
Sex | Female | 1,436 | 0.6 | 22.9 | 1,537 | 0.7 | 24.4
Sex | Male | 704 | 0.4 | 9.8 | 767 | 0.4 | 10.6
Total | | 2,140 | 0.5 | 32.6 | 2,304 | 0.6 | 34.9

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Gallbladder cancer contributed to 2,000 deaths in 2019 (Table 261). Gallbladder cancer mortality was rare among children, adolescents, and younger adults and mortality rates increased with age throughout middle and older age. In contrast to all other common digestive cancers, age-adjusted mortality rates (underlying or other cause) were higher among women compared with men. Mortality rates were higher among Blacks compared with Whites and among Hispanics compared with non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with gallbladder cancer as underlying or other cause decreased by 14% from 0.7 to 0.6.(4)