# Chapter 10 Liver disease

## Liver Disease (Acute and Chronic)

Table 121 Liver Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 6 | 12
Age (years) | 12 to 24 | 19 | 34 | 88 | 157
Age (years) | 25 to 44 | 212 | 251 | 729 | 862
Age (years) | 45 to 54 | 356 | 826 | 1,111 | 2,578
Age (years) | 55 to 64 | 214 | 523 | 1,174 | 2,878
Age (years) | 65 to 74 | 145 | 527 | 501 | 1,819
Age (years) | 75 plus | 195 | 963 | 558 | 2,759
Race | White | 875 | 332 | 3,145 | 1,112
Race | Black | 203 | 466 | 670 | 1,602
Race | Other | 62 | 238 | 351 | 1,440
Ethnicity | Hispanic | 78 | 172 | 530 | 1,149
Ethnicity | Not Hispanic | 1,062 | 366 | 3,636 | 1,195
Sex | Female | 627 | 370 | 2,441 | 1,362
Sex | Male | 513 | 312 | 1,725 | 1,023
Total | | 1,140 | 340 | 4,166 | 1,196

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Liver disease (acute and chronic) contributed to 4.2 million ambulatory visits (2015) (Table 121). Ambulatory care visit rates (all-listed diagnoses) were highest among persons 55–64 years. Age-adjusted ambulatory care visit rates were higher among women compared with men, Blacks compared with Whites, and non-Hispanics compared with Hispanics.

Table 122 Liver Disease: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 2 | 7 | 14
Age (years) | 12 to 24 | 6 | 11 | 53 | 96
Age (years) | 25 to 44 | 58 | 66 | 428 | 492
Age (years) | 45 to 54 | 76 | 182 | 453 | 1,089
Age (years) | 55 to 64 | 99 | 234 | 593 | 1,404
Age (years) | 65 to 74 | 55 | 181 | 398 | 1,305
Age (years) | 75 plus | 26 | 117 | 265 | 1,208
Sex | Female | 133 | 70 | 1,011 | 536
Sex | Male | 187 | 105 | 1,187 | 672
Total | | 320 | 87 | 2,198 | 601

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Liver disease (acute and chronic) contributed to 2.2 million emergency department visits in 2018 (Table 122). Emergency department visit rates (all-listed diagnoses) were highest among persons 55–64 years. Age-adjusted emergency department visit rates were higher among men compared with women.

Table 123 Liver Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 1 | 2 | 10 | 20
Age (years) | 12 to 24 | 2 | 4 | 29 | 53
Age (years) | 25 to 44 | 37 | 42 | 262 | 301
Age (years) | 45 to 54 | 56 | 134 | 309 | 741
Age (years) | 55 to 64 | 81 | 193 | 460 | 1,089
Age (years) | 65 to 74 | 52 | 170 | 357 | 1,171
Age (years) | 75 plus | 24 | 107 | 242 | 1,105
Race | White | 214 | 71 | 1,370 | 455
Race | Black | 23 | 48 | 202 | 439
Race | Other | 18 | 68 | 115 | 442
Ethnicity | Hispanic | 45 | 94 | 252 | 528
Ethnicity | Not Hispanic | 210 | 65 | 1,435 | 442
Sex | Female | 105 | 53 | 742 | 381
Sex | Male | 148 | 82 | 928 | 517
Total | | 253 | 67 | 1,670 | 446

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Liver disease (acute and chronic) contributed to 1.7 million hospital discharges in 2018 (Table 123). Hospital discharge rates (all-listed diagnoses) increased with age until the oldest age group. Age-adjusted hospital discharge rates were higher among men compared with women, Whites compared with Blacks, and Hispanics compared with non-Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by 72% from 259 to 446.(7)

Table 124 Liver Disease: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 58 | 0.1 | 4.4 | 284 | 0.6 | 21.8
Age (years) | 12 to 24 | 80 | 0.1 | 4.7 | 274 | 0.5 | 16.2
Age (years) | 25 to 44 | 5,395 | 6.2 | 229.1 | 8,317 | 9.5 | 353.7
Age (years) | 45 to 54 | 9,669 | 23.7 | 300.3 | 15,314 | 37.5 | 474.3
Age (years) | 55 to 64 | 17,669 | 41.6 | 409.6 | 31,960 | 75.3 | 735.4
Age (years) | 65 to 74 | 14,466 | 45.9 | 233.1 | 29,011 | 92.1 | 464.9
Age (years) | 75 plus | 10,620 | 47.0 | 90.7 | 22,318 | 98.9 | 187.9
Race | White | 50,610 | 15.8 | 1,102.0 | 91,676 | 28.1 | 1,911.8
Race | Black | 4,771 | 10.1 | 102.7 | 10,688 | 22.6 | 222.3
Race | Other | 2,576 | 9.6 | 67.1 | 5,114 | 19.3 | 120.1
Ethnicity | Hispanic | 7,093 | 15.3 | 178.7 | 12,662 | 27.7 | 310.3
Ethnicity | Not Hispanic | 50,864 | 14.8 | 1,093.1 | 94,816 | 27.0 | 1,943.9
Sex | Female | 23,008 | 11.1 | 521.6 | 41,890 | 19.8 | 914.5
Sex | Male | 34,949 | 18.7 | 750.3 | 65,588 | 34.7 | 1,339.7
Total | | 57,957 | 14.7 | 1,271.8 | 107,478 | 26.8 | 2,254.1

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Liver disease (acute and chronic) contributed to 107,000 deaths in 2019 (Table 124). Mortality rates (underlying or other cause) increased with age. Age-adjusted mortality rates were higher among men, Whites, and Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with liver disease as underlying or other cause increased by 7% from 24.9 to 26.8.(7)

Table 125 Liver Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 123 | 0.0% | 386 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 852 | 0.1% | 2,888 | 0.2%
Age (years) | 25 to 44 | 2,656,672 | 6,458 | 0.2% | 26,241 | 1.0%
Age (years) | 45 to 54 | 1,452,320 | 7,930 | 0.5% | 32,265 | 2.2%
Age (years) | 55 to 64 | 1,640,216 | 15,046 | 0.9% | 52,772 | 3.2%
Age (years) | 65 to 74 | 2,840,615 | 27,402 | 1.0% | 90,425 | 3.2%
Age (years) | 75 plus | 2,576,241 | 14,230 | 0.6% | 55,117 | 2.1%
Race-ethnicity | White | 8,657,702 | 44,576 | 0.5% | 160,260 | 1.9%
Race-ethnicity | Black | 1,242,477 | 6,693 | 0.5% | 25,368 | 2.0%
Race-ethnicity | Hispanic | 1,493,457 | 12,177 | 0.8% | 42,511 | 2.8%
Race-ethnicity | Asian | 607,284 | 2,683 | 0.4% | 10,887 | 1.8%
Race-ethnicity | Unknown | 1,719,014 | 5,912 | 0.3% | 21,068 | 1.2%
Sex | Female | 7,199,363 | 39,176 | 0.5% | 137,573 | 1.9%
Sex | Male | 6,520,571 | 32,865 | 0.5% | 122,521 | 1.9%
Region | Northeast | 1,526,275 | 8,884 | 0.6% | 30,224 | 2.0%
Region | Midwest | 3,322,846 | 13,224 | 0.4% | 47,748 | 1.4%
Region | South | 5,619,435 | 34,360 | 0.6% | 125,392 | 2.2%
Region | West | 3,251,378 | 15,573 | 0.5% | 56,730 | 1.7%
Total | | 13,719,934 | 72,041 | 0.5% | 260,094 | 1.9%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of liver disease (acute and chronic) (based on all-listed diagnoses) was 1.9% (Table 125). Prevalence increased with age until the oldest age groups and did not differ by sex. It was highest among Hispanics, followed by Blacks, Whites, and Asians. It was highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 126 Liver Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 187 | 17 | 566 | 51
Age (years) | 12 to 24 | 1,236 | 85 | 4,298 | 296
Age (years) | 25 to 44 | 10,065 | 379 | 42,212 | 1,589
Age (years) | 45 to 54 | 14,285 | 984 | 59,571 | 4,102
Age (years) | 55 to 64 | 30,013 | 1,830 | 109,754 | 6,691
Age (years) | 65 to 74 | 52,917 | 1,863 | 187,580 | 6,603
Age (years) | 75 plus | 26,787 | 1,040 | 100,440 | 3,899
Race-ethnicity | White | 85,369 | 986 | 309,883 | 3,579
Race-ethnicity | Black | 11,445 | 921 | 44,891 | 3,613
Race-ethnicity | Hispanic | 22,988 | 1,539 | 88,304 | 5,913
Race-ethnicity | Asian | 4,117 | 678 | 19,051 | 3,137
Race-ethnicity | Unknown | 11,571 | 673 | 42,292 | 2,460
Sex | Female | 71,955 | 999 | 269,807 | 3,748
Sex | Male | 63,535 | 974 | 234,614 | 3,598
Region | Northeast | 16,417 | 1,076 | 57,007 | 3,735
Region | Midwest | 25,280 | 761 | 88,765 | 2,671
Region | South | 64,350 | 1,145 | 247,770 | 4,409
Region | West | 29,443 | 906 | 110,879 | 3,410
Total | | 135,490 | 988 | 504,421 | 3,677

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with liver disease (acute and chronic) (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among women compared with men (Table 126). Among persons with known race-ethnicity, rates were much higher among Hispanics, followed by Blacks and Whites, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 127 Liver Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | 2 | 0
Age (years) | 12 to 24 | 4 | 0 | 41 | 3
Age (years) | 25 to 44 | 129 | 5 | 492 | 19
Age (years) | 45 to 54 | 387 | 27 | 1,100 | 76
Age (years) | 55 to 64 | 1,222 | 75 | 3,291 | 201
Age (years) | 65 to 74 | 2,208 | 78 | 6,410 | 226
Age (years) | 75 plus | 1,146 | 44 | 3,909 | 152
Race-ethnicity | White | 3,031 | 35 | 9,169 | 106
Race-ethnicity | Black | 516 | 42 | 1,592 | 128
Race-ethnicity | Hispanic | 861 | 58 | 2,550 | 171
Race-ethnicity | Asian | 93 | 15 | 258 | 42
Race-ethnicity | Unknown | 595 | 35 | 1,676 | 97
Sex | Female | 2,419 | 34 | 7,529 | 105
Sex | Male | 2,677 | 41 | 7,716 | 118
Region | Northeast | 613 | 40 | 1,698 | 111
Region | Midwest | 911 | 27 | 2,749 | 83
Region | South | 2,502 | 45 | 7,429 | 132
Region | West | 1,070 | 33 | 3,369 | 104
Total | | 5,096 | 37 | 15,245 | 111

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with liver disease (acute and chronic) (all-listed diagnoses) increased with age until 75 years and were higher among men compared with women (Table 127). Among persons with known race-ethnicity, rates were highest among Hispanics, followed by Blacks, then Whites, and much lower among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 128 Liver Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 17 | 2 | 175 | 16
Age (years) | 12 to 24 | 42 | 3 | 550 | 38
Age (years) | 25 to 44 | 500 | 19 | 4,633 | 174
Age (years) | 45 to 54 | 983 | 68 | 7,118 | 490
Age (years) | 55 to 64 | 2,425 | 148 | 16,633 | 1,014
Age (years) | 65 to 74 | 3,682 | 130 | 30,344 | 1,068
Age (years) | 75 plus | 1,969 | 76 | 24,973 | 969
Race-ethnicity | White | 6,073 | 70 | 53,614 | 619
Race-ethnicity | Black | 897 | 72 | 10,366 | 834
Race-ethnicity | Hispanic | 1,543 | 103 | 11,083 | 742
Race-ethnicity | Asian | 156 | 26 | 1,774 | 292
Race-ethnicity | Unknown | 949 | 55 | 7,589 | 441
Sex | Female | 4,453 | 62 | 40,315 | 560
Sex | Male | 5,165 | 79 | 44,111 | 676
Region | Northeast | 1,153 | 76 | 9,973 | 653
Region | Midwest | 1,936 | 58 | 17,470 | 526
Region | South | 4,774 | 85 | 40,528 | 721
Region | West | 1,755 | 54 | 16,455 | 506
Total | | 9,618 | 70 | 84,426 | 615

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with liver disease (acute and chronic) (all-listed diagnoses) increased with age until 75 years were higher among men compared with women (Table 128). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics, then Whites, and much lower among Asians. Rates were highest in the South, followed by the Northeast, then the Midwest, and lowest in the West.

Table 129 Liver Disease: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 114,920 | 1.4% | 336,660 | 4.2%
Age (years) | 70 to 74 | 6,936,940 | 89,120 | 1.3% | 272,700 | 3.9%
Age (years) | 75 to 79 | 4,894,060 | 52,720 | 1.1% | 173,560 | 3.5%
Age (years) | 80 to 84 | 3,335,340 | 28,440 | 0.9% | 101,500 | 3.0%
Age (years) | 85+ | 3,578,120 | 18,160 | 0.5% | 78,280 | 2.2%
Race | White | 22,023,800 | 237,340 | 1.1% | 761,080 | 3.5%
Race | Black | 1,861,660 | 19,540 | 1.0% | 65,800 | 3.5%
Race | Other | 2,925,320 | 46,480 | 1.6% | 135,820 | 4.6%
Sex | Female | 14,975,560 | 172,140 | 1.1% | 534,800 | 3.6%
Sex | Male | 11,835,220 | 131,220 | 1.1% | 427,900 | 3.6%
Region | Northeast | 4,748,700 | 58,360 | 1.2% | 179,960 | 3.8%
Region | Midwest | 6,069,800 | 56,460 | 0.9% | 183,960 | 3.0%
Region | South | 10,595,900 | 125,600 | 1.2% | 402,560 | 3.8%
Region | West | 5,396,380 | 62,940 | 1.2% | 196,220 | 3.6%
Total | | 26,810,780 | 303,360 | 1.1% | 962,700 | 3.6%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of liver disease (acute and chronic) (based on all-listed diagnoses) was 3.6% (Table 129). Prevalence decreased with age and did not differ by sex or race. It was highest in the Northeast and South, followed by the West, and lowest in the Midwest.

Table 130 Liver Disease: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 221,020 | 2,740 | 710,440 | 8,807
Age (years) | 70 to 74 | 165,860 | 2,391 | 567,200 | 8,177
Age (years) | 75 to 79 | 93,380 | 1,908 | 324,020 | 6,621
Age (years) | 80 to 84 | 52,540 | 1,575 | 177,080 | 5,309
Age (years) | 85+ | 28,500 | 797 | 105,940 | 2,961
Race | White | 439,940 | 1,998 | 1,470,640 | 6,678
Race | Black | 30,620 | 1,645 | 108,720 | 5,840
Race | Other | 90,740 | 3,102 | 305,320 | 10,437
Sex | Female | 314,120 | 2,098 | 1,050,940 | 7,018
Sex | Male | 247,180 | 2,089 | 833,740 | 7,045
Region | Northeast | 105,260 | 2,217 | 354,740 | 7,470
Region | Midwest | 109,520 | 1,804 | 354,700 | 5,844
Region | South | 229,600 | 2,167 | 786,040 | 7,418
Region | West | 116,920 | 2,167 | 389,200 | 7,212
Total | | 561,300 | 2,094 | 1,884,680 | 7,030

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with liver disease (acute and chronic) (all-listed diagnoses) decreased with age, differed little by sex, and were higher among Whites compared with Blacks (Table 130). Rates were lower in the Midwest compared with the Northeast, South, and West.

Table 131 Liver Disease: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 25,540 | 317 | 135,220 | 1,676
Age (years) | 70 to 74 | 16,360 | 236 | 109,040 | 1,572
Age (years) | 75 to 79 | 11,300 | 231 | 78,760 | 1,609
Age (years) | 80 to 84 | 6,900 | 207 | 54,220 | 1,626
Age (years) | 85+ | 5,340 | 149 | 50,800 | 1,420
Race | White | 48,600 | 221 | 328,820 | 1,493
Race | Black | 4,380 | 235 | 37,980 | 2,040
Race | Other | 12,460 | 426 | 61,240 | 2,093
Sex | Female | 32,980 | 220 | 221,960 | 1,482
Sex | Male | 32,460 | 274 | 206,080 | 1,741
Region | Northeast | 11,160 | 235 | 73,620 | 1,550
Region | Midwest | 11,960 | 197 | 83,540 | 1,376
Region | South | 27,540 | 260 | 183,360 | 1,730
Region | West | 14,780 | 274 | 87,520 | 1,622
Total | | 65,440 | 244 | 428,040 | 1,597

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with liver disease (acute and chronic) (all-listed diagnoses) were lowest among persons 85 years and over and were higher among men compared with women and Blacks compared with Whites (Table 131). Rates were highest in the South, followed by the West, then the Northeast, and lowest in the Midwest.

Table 132 Liver Disease: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 17,200 | 213 | 111,100 | 1,377
Age (years) | 70 to 74 | 10,600 | 153 | 88,960 | 1,282
Age (years) | 75 to 79 | 7,040 | 144 | 64,720 | 1,322
Age (years) | 80 to 84 | 4,100 | 123 | 44,620 | 1,338
Age (years) | 85+ | 2,840 | 79 | 39,600 | 1,107
Race | White | 31,240 | 142 | 269,620 | 1,224
Race | Black | 2,300 | 124 | 30,060 | 1,615
Race | Other | 8,240 | 282 | 49,320 | 1,686
Sex | Female | 20,220 | 135 | 172,760 | 1,154
Sex | Male | 21,560 | 182 | 176,240 | 1,489
Region | Northeast | 6,300 | 133 | 58,420 | 1,230
Region | Midwest | 9,280 | 153 | 75,620 | 1,246
Region | South | 17,400 | 164 | 145,820 | 1,376
Region | West | 8,800 | 163 | 69,140 | 1,281
Total | | 41,780 | 156 | 349,000 | 1,302

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with liver disease (acute and chronic) (all-listed diagnoses) were lowest among persons 85 years and over and were higher among men compared with women and Blacks compared with Whites (Table 132). Rates were higher in the South compared with the Northeast, Midwest, and West.

## Hepatitis A

Table 133 Hepatitis A: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | .
Age (years) | 12 to 24 | . | .
Age (years) | 25 to 44 | . | .
Age (years) | 45 to 54 | . | .
Age (years) | 55 to 64 | 10 | 25
Age (years) | 65 to 74 | . | .
Age (years) | 75 plus | 2 | 8
Race | White | 11 | 3
Race | Black | 0 | 1
Race | Other | . | .
Ethnicity | Hispanic | 5 | 10
Ethnicity | Not Hispanic | 7 | 2
Sex | Female | 10 | 4
Sex | Male | 2 | 1
Total | | 12 | 3

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis A contributed to 12,000 ambulatory visits (2015) (Table 133). Ambulatory care visits were uncommon, and rates (all-listed diagnoses) were highest among persons 55–64 years. Age-adjusted ambulatory care visit rates were higher among women compared with men, Whites compared with Blacks, and Hispanics compared with non-Hispanics.

Table 134 Hepatitis A: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 0
Age (years) | 12 to 24 | 1 | 1 | 1 | 2
Age (years) | 25 to 44 | 4 | 5 | 8 | 9
Age (years) | 45 to 54 | 1 | 2 | 3 | 7
Age (years) | 55 to 64 | 1 | 1 | 3 | 7
Age (years) | 65 to 74 | 0 | 1 | 2 | 6
Age (years) | 75 plus | 0 | 1 | 2 | 7
Sex | Female | 3 | 2 | 8 | 5
Sex | Male | 4 | 3 | 10 | 6
Total | | 7 | 2 | 19 | 6

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis A contributed to 19,000 emergency department visits in 2018 (Table 134). Emergency department visit rates (all-listed diagnoses) were uncommon among children and highest among persons 25–44 years. Age-adjusted emergency department visit rates were higher among men compared with women.

Table 135 Hepatitis A: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 0
Age (years) | 12 to 24 | 0 | 1 | 1 | 2
Age (years) | 25 to 44 | 3 | 4 | 6 | 7
Age (years) | 45 to 54 | 1 | 3 | 3 | 6
Age (years) | 55 to 64 | 0 | 1 | 2 | 6
Age (years) | 65 to 74 | 0 | 1 | 2 | 6
Age (years) | 75 plus | 0 | 0 | 1 | 6
Race | White | 5 | 2 | 13 | 5
Race | Black | 0 | 1 | 1 | 3
Race | Other | 0 | 1 | 1 | 3
Ethnicity | Hispanic | 0 | 0 | 1 | 2
Ethnicity | Not Hispanic | 5 | 2 | 14 | 5
Sex | Female | 2 | 1 | 6 | 4
Sex | Male | 4 | 2 | 9 | 5
Total | | 6 | 2 | 15 | 4

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis A contributed to 15,000 hospital discharges in 2018 (Table 135). Hospital discharges were uncommon among children and rates (all-listed diagnoses) were highest among persons 25–44 years. Age-adjusted hospital discharge rates were higher among men compared with women, Whites compared with Blacks, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by a third from 3 to 4.(4)

Table 136 Hepatitis A: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | . | . | . | . | . | .
Age (years) | 25 to 44 | 14 | 0.0 | 0.6 | 25 | 0.0 | 1.0
Age (years) | 45 to 54 | 30 | 0.1 | 0.9 | 56 | 0.1 | 1.7
Age (years) | 55 to 64 | 40 | 0.1 | 0.9 | 62 | 0.1 | 1.4
Age (years) | 65 to 74 | 26 | 0.1 | 0.4 | 46 | 0.1 | 0.7
Age (years) | 75 plus | 29 | 0.1 | 0.2 | 37 | 0.2 | 0.3
Race | White | 131 | 0.0 | 2.8 | 206 | 0.1 | 4.7
Race | Black | 5 | 0.0 | 0.2 | 13 | 0.0 | 0.3
Race | Other | 3 | 0.0 | 0.1 | 7 | 0.0 | 0.2
Ethnicity | Hispanic | 4 | 0.0 | 0.1 | 11 | 0.0 | 0.3
Ethnicity | Not Hispanic | 135 | 0.0 | 3.0 | 215 | 0.1 | 4.9
Sex | Female | 38 | 0.0 | 0.9 | 66 | 0.0 | 1.6
Sex | Male | 101 | 0.1 | 2.2 | 160 | 0.1 | 3.6
Total | | 139 | 0.0 | 3.1 | 226 | 0.1 | 5.2

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Hepatitis A contributed to <1,000 deaths in 2019 (Table 136). Mortality was uncommon among children and young adults and rates (underlying or other cause) were highest among persons 75 years and over. Age-adjusted mortality rates were higher among men, Whites, and non-Hispanics. Between 2004 and 2019, mortality with hepatitis A as underlying or other cause remained uncommon.(4)

Table 137 Hepatitis A: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 3 | 0.0% | 6 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 18 | 0.0% | 36 | 0.0%
Age (years) | 25 to 44 | 2,656,672 | 57 | 0.0% | 126 | 0.0%
Age (years) | 45 to 54 | 1,452,320 | 33 | 0.0% | 122 | 0.0%
Age (years) | 55 to 64 | 1,640,216 | 73 | 0.0% | 240 | 0.0%
Age (years) | 65 to 74 | 2,840,615 | 80 | 0.0% | 492 | 0.0%
Age (years) | 75 plus | 2,576,241 | 54 | 0.0% | 391 | 0.0%
Race-ethnicity | White | 8,657,702 | 190 | 0.0% | 863 | 0.0%
Race-ethnicity | Black | 1,242,477 | 37 | 0.0% | 156 | 0.0%
Race-ethnicity | Hispanic | 1,493,457 | 41 | 0.0% | 199 | 0.0%
Race-ethnicity | Asian | 607,284 | 24 | 0.0% | 72 | 0.0%
Race-ethnicity | Unknown | 1,719,014 | 26 | 0.0% | 123 | 0.0%
Sex | Female | 7,199,363 | 161 | 0.0% | 717 | 0.0%
Sex | Male | 6,520,571 | 157 | 0.0% | 696 | 0.0%
Region | Northeast | 1,526,275 | 48 | 0.0% | 209 | 0.0%
Region | Midwest | 3,322,846 | 41 | 0.0% | 203 | 0.0%
Region | South | 5,619,435 | 177 | 0.0% | 734 | 0.0%
Region | West | 3,251,378 | 52 | 0.0% | 267 | 0.0%
Total | | 13,719,934 | 318 | 0.0% | 1,413 | 0.0%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, the claims-based prevalence of hepatitis A (based on all-listed diagnoses) was <0.1% (Table 137).

Table 138 Hepatitis A: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 3 | 0 | 5 | 0
Age (years) | 12 to 24 | 20 | 1 | 37 | 3
Age (years) | 25 to 44 | 70 | 3 | 158 | 6
Age (years) | 45 to 54 | 47 | 3 | 155 | 11
Age (years) | 55 to 64 | 89 | 5 | 294 | 18
Age (years) | 65 to 74 | 103 | 4 | 607 | 21
Age (years) | 75 plus | 66 | 3 | 507 | 20
Race-ethnicity | White | 256 | 3 | 1,111 | 13
Race-ethnicity | Black | 38 | 3 | 169 | 14
Race-ethnicity | Hispanic | 44 | 3 | 263 | 18
Race-ethnicity | Asian | 31 | 5 | 91 | 15
Race-ethnicity | Unknown | 29 | 2 | 129 | 8
Sex | Female | 198 | 3 | 926 | 13
Sex | Male | 200 | 3 | 837 | 13
Region | Northeast | 67 | 4 | 310 | 20
Region | Midwest | 61 | 2 | 231 | 7
Region | South | 207 | 4 | 879 | 16
Region | West | 63 | 2 | 343 | 11
Total | | 398 | 3 | 1,763 | 13

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with hepatitis A (all-listed diagnoses) increased with age until 75 years and did not differ by sex (Table 138). Among persons with known race-ethnicity, rates were highest among Hispanics, followed by Asians, Blacks, and Whites. Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 139 Hepatitis A: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | . | . | . | .
Age (years) | 25 to 44 | 2 | 0 | 6 | 0
Age (years) | 45 to 54 | . | . | 3 | 0
Age (years) | 55 to 64 | 5 | 0 | 10 | 1
Age (years) | 65 to 74 | 5 | 0 | 14 | 0
Age (years) | 75 plus | 1 | 0 | 9 | 0
Race-ethnicity | White | 8 | 0 | 29 | 0
Race-ethnicity | Black | . | . | 2 | 0
Race-ethnicity | Hispanic | 1 | 0 | 3 | 0
Race-ethnicity | Asian | . | . | 1 | 0
Race-ethnicity | Unknown | 4 | 0 | 7 | 0
Sex | Female | 5 | 0 | 16 | 0
Sex | Male | 8 | 0 | 26 | 0
Region | Northeast | 1 | 0 | 7 | 0
Region | Midwest | 1 | 0 | 8 | 0
Region | South | 9 | 0 | 20 | 0
Region | West | 2 | 0 | 7 | 0
Total | | 13 | 0 | 42 | 0

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, the emergency department visit rate with hepatitis A (all-listed diagnoses) was less than 1 per 100,000 (Table 139).

Table 140 Hepatitis A: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | 1 | 0
Age (years) | 12 to 24 | . | . | 11 | 1
Age (years) | 25 to 44 | 15 | 1 | 32 | 1
Age (years) | 45 to 54 | 12 | 1 | 39 | 3
Age (years) | 55 to 64 | 26 | 2 | 90 | 5
Age (years) | 65 to 74 | 18 | 1 | 177 | 6
Age (years) | 75 plus | 11 | 0 | 145 | 6
Race-ethnicity | White | 55 | 1 | 321 | 4
Race-ethnicity | Black | 13 | 1 | 59 | 5
Race-ethnicity | Hispanic | 6 | 0 | 58 | 4
Race-ethnicity | Asian | 2 | 0 | 17 | 3
Race-ethnicity | Unknown | 6 | 0 | 40 | 2
Sex | Female | 37 | 1 | 235 | 3
Sex | Male | 45 | 1 | 260 | 4
Region | Northeast | 9 | 1 | 56 | 4
Region | Midwest | 11 | 0 | 82 | 2
Region | South | 48 | 1 | 260 | 5
Region | West | 14 | 0 | 97 | 3
Total | | 82 | 1 | 495 | 4

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with hepatitis A (all-listed diagnoses) increased with age and differed little by sex (Table 140). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 141 Hepatitis A: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 300 | 0.0% | 1,660 | 0.0%
Age (years) | 70 to 74 | 6,936,940 | . | . | 1,120 | 0.0%
Age (years) | 75 to 79 | 4,894,060 | . | . | 880 | 0.0%
Age (years) | 80 to 84 | 3,335,340 | . | . | 580 | 0.0%
Age (years) | 85+ | 3,578,120 | . | . | 400 | 0.0%
Race | White | 22,023,800 | 640 | 0.0% | 3,720 | 0.0%
Race | Black | 1,861,660 | . | . | 220 | 0.0%
Race | Other | 2,925,320 | . | . | 700 | 0.0%
Sex | Female | 14,975,560 | 500 | 0.0% | 2,540 | 0.0%
Sex | Male | 11,835,220 | 240 | 0.0% | 2,100 | 0.0%
Region | Northeast | 4,748,700 | . | . | 620 | 0.0%
Region | Midwest | 6,069,800 | . | . | 780 | 0.0%
Region | South | 10,595,900 | 360 | 0.0% | 2,280 | 0.0%
Region | West | 5,396,380 | . | . | 960 | 0.0%
Total | | 26,810,780 | 740 | 0.0% | 4,640 | 0.0%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of hepatitis A (based on all-listed diagnoses) was <0.1% (Table 141).

Table 142 Hepatitis A: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 400 | 5 | 2,060 | 26
Age (years) | 70 to 74 | . | . | 1,000 | 14
Age (years) | 75 to 79 | . | . | 1,700 | 35
Age (years) | 80 to 84 | . | . | . | .
Age (years) | 85+ | . | . | . | .
Race | White | 840 | 4 | 4,700 | 21
Race | Black | . | . | . | .
Race | Other | . | . | . | .
Sex | Female | . | . | 2,740 | 18
Sex | Male | . | . | 2,880 | 24
Region | Northeast | . | . | 720 | 15
Region | Midwest | . | . | 480 | 8
Region | South | 520 | 5 | 3,780 | 36
Region | West | . | . | 640 | 12
Total | | 960 | 4 | 5,620 | 21

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visits with hepatitis A were uncommon among persons over 80 years and Blacks (Table 142). Rates (all-listed diagnoses) were higher among men compared with women. Rates were much higher in the South, intermediate in the Northeast and West, and lowest in the Midwest.

Table 143 Hepatitis A: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | . | . | 600 | 7
Age (years) | 70 to 74 | . | . | 480 | 7
Age (years) | 75 to 79 | . | . | 400 | 8
Age (years) | 80 to 84 | . | . | 320 | 10
Age (years) | 85+ | . | . | 260 | 7
Race | White | 280 | 1 | 1,780 | 8
Race | Black | . | . | . | .
Race | Other | . | . | . | .
Sex | Female | . | . | 1,020 | 7
Sex | Male | . | . | 1,040 | 9
Region | Northeast | . | . | 260 | 5
Region | Midwest | . | . | 420 | 7
Region | South | . | . | 1,040 | 10
Region | West | . | . | 340 | 6
Total | | 280 | 1 | 2,060 | 8

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visits with hepatitis A were uncommon among Blacks (Table 143). Rates (all-listed diagnoses) were highest among persons 80 to 84 years and higher among men compared with women. Rates were higher in the South compared with Northeast, West, and Midwest.

Table 144 Hepatitis A: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | . | . | 680 | 8
Age (years) | 70 to 74 | . | . | 520 | 7
Age (years) | 75 to 79 | . | . | 420 | 9
Age (years) | 80 to 84 | . | . | . | .
Age (years) | 85+ | . | . | . | .
Race | White | . | . | 1,700 | 8
Race | Black | . | . | . | .
Race | Other | . | . | . | .
Sex | Female | . | . | 900 | 6
Sex | Male | . | . | 1,140 | 10
Region | Northeast | . | . | . | .
Region | Midwest | . | . | . | .
Region | South | . | . | 1,060 | 10
Region | West | . | . | 380 | 7
Total | | . | . | 2,040 | 8

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharges with hepatitis A were uncommon among persons over 80 years and Blacks (Table 144). Rates (all-listed diagnoses) were higher among men compared with women. Rates were higher in the South and West compared with the Northeast and Midwest.

## Hepatitis B

Table 145 Hepatitis B: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 31 | 56 | 31 | 56
Age (years) | 25 to 44 | 2 | 2 | 79 | 94
Age (years) | 45 to 54 | 100 | 231 | 191 | 444
Age (years) | 55 to 64 | 5 | 13 | 111 | 273
Age (years) | 65 to 74 | 2 | 9 | 62 | 224
Age (years) | 75 plus | 0 | 1 | 289 | 1,431
Race | White | 6 | 2 | 148 | 45
Race | Black | 46 | 98 | 64 | 131
Race | Other | 88 | 350 | 553 | 2,863
Ethnicity | Hispanic | . | . | 17 | 34
Ethnicity | Not Hispanic | 141 | 49 | 747 | 255
Sex | Female | 4 | 2 | 196 | 123
Sex | Male | 136 | 81 | 568 | 362
Total | | 141 | 41 | 764 | 228

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis B contributed to 764,000 ambulatory visits (2015) (Table 145). Ambulatory care visits were uncommon among children and rates (all-listed diagnoses) were much higher among persons 75 years and over compared to younger age groups. Age-adjusted ambulatory care visit rates were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics.

Table 146 Hepatitis B: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 0
Age (years) | 12 to 24 | 0 | 0 | 1 | 3
Age (years) | 25 to 44 | 1 | 2 | 20 | 23
Age (years) | 45 to 54 | 1 | 2 | 20 | 48
Age (years) | 55 to 64 | 0 | 1 | 25 | 59
Age (years) | 65 to 74 | 0 | 1 | 14 | 47
Age (years) | 75 plus | 0 | 0 | 8 | 35
Sex | Female | 1 | 1 | 34 | 19
Sex | Male | 2 | 1 | 55 | 31
Total | | 3 | 1 | 89 | 25

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis B contributed to 89,000 emergency department visits in 2018 (Table 146). Emergency department visits were uncommon among children and rates (all-listed diagnoses) peaked at 55–64 years. Age-adjusted rates were higher among men compared with women.

Table 147 Hepatitis B: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 0 | 0
Age (years) | 12 to 24 | 0 | 0 | 1 | 3
Age (years) | 25 to 44 | 1 | 1 | 22 | 25
Age (years) | 45 to 54 | 1 | 2 | 16 | 38
Age (years) | 55 to 64 | 0 | 1 | 21 | 50
Age (years) | 65 to 74 | 0 | 1 | 14 | 47
Age (years) | 75 plus | 0 | 0 | 7 | 34
Race | White | 2 | 1 | 43 | 15
Race | Black | 0 | 1 | 20 | 42
Race | Other | 0 | 1 | 20 | 75
Ethnicity | Hispanic | 0 | 0 | 7 | 15
Ethnicity | Not Hispanic | 3 | 1 | 75 | 25
Sex | Female | 1 | 1 | 34 | 19
Sex | Male | 2 | 1 | 48 | 27
Total | | 3 | 1 | 82 | 23

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis B contributed to 82,000 hospital discharges in 2018 (Table 147). Hospital discharges were uncommon among children and rates (all-listed diagnoses) peaked at 55–64 years. Age-adjusted rates were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis remained stable at 23.(4)

Table 148 Hepatitis B: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 1 | 0.0 | 0.0 | 4 | 0.0 | 0.2
Age (years) | 25 to 44 | 42 | 0.0 | 1.7 | 153 | 0.2 | 6.3
Age (years) | 45 to 54 | 86 | 0.2 | 2.6 | 256 | 0.6 | 7.7
Age (years) | 55 to 64 | 118 | 0.3 | 2.7 | 506 | 1.2 | 11.3
Age (years) | 65 to 74 | 113 | 0.4 | 1.8 | 486 | 1.5 | 7.7
Age (years) | 75 plus | 77 | 0.3 | 0.7 | 267 | 1.2 | 2.2
Race | White | 249 | 0.1 | 5.7 | 879 | 0.3 | 19.0
Race | Black | 59 | 0.1 | 1.3 | 299 | 0.6 | 6.6
Race | Other | 129 | 0.5 | 2.6 | 494 | 1.8 | 9.8
Ethnicity | Hispanic | 33 | 0.1 | 0.8 | 84 | 0.2 | 1.9
Ethnicity | Not Hispanic | 404 | 0.1 | 8.8 | 1,588 | 0.5 | 33.5
Sex | Female | 128 | 0.1 | 2.8 | 416 | 0.2 | 9.4
Sex | Male | 309 | 0.2 | 6.7 | 1,256 | 0.7 | 26.0
Total | | 437 | 0.1 | 9.6 | 1,672 | 0.4 | 35.4

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Hepatitis B contributed to 2,000 deaths in 2019 (Table 148). Mortality was uncommon among the youngest age groups after which rates (underlying or other cause) increased with age until the oldest age group. Like health care use rates, age-adjusted mortality rates were higher among men, Blacks, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with hepatitis B as underlying or other cause decreased by a third from 0.6 to 0.4.(4)

Table 149 Hepatitis B: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 8 | 0.0% | 27 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 83 | 0.0% | 114 | 0.0%
Age (years) | 25 to 44 | 2,656,672 | 1,178 | 0.0% | 1,911 | 0.1%
Age (years) | 45 to 54 | 1,452,320 | 1,146 | 0.1% | 2,105 | 0.1%
Age (years) | 55 to 64 | 1,640,216 | 1,035 | 0.1% | 2,563 | 0.2%
Age (years) | 65 to 74 | 2,840,615 | 1,996 | 0.1% | 5,001 | 0.2%
Age (years) | 75 plus | 2,576,241 | 732 | 0.0% | 2,180 | 0.1%
Race-ethnicity | White | 8,657,702 | 1,325 | 0.0% | 3,977 | 0.0%
Race-ethnicity | Black | 1,242,477 | 614 | 0.0% | 1,617 | 0.1%
Race-ethnicity | Hispanic | 1,493,457 | 344 | 0.0% | 991 | 0.1%
Race-ethnicity | Asian | 607,284 | 3,215 | 0.5% | 5,828 | 1.0%
Race-ethnicity | Unknown | 1,719,014 | 680 | 0.0% | 1,488 | 0.1%
Sex | Female | 7,199,363 | 2,806 | 0.0% | 6,211 | 0.1%
Sex | Male | 6,520,571 | 3,372 | 0.1% | 7,690 | 0.1%
Region | Northeast | 1,526,275 | 1,253 | 0.1% | 2,465 | 0.2%
Region | Midwest | 3,322,846 | 736 | 0.0% | 1,621 | 0.0%
Region | South | 5,619,435 | 2,166 | 0.0% | 5,480 | 0.1%
Region | West | 3,251,378 | 2,023 | 0.1% | 4,335 | 0.1%
Total | | 13,719,934 | 6,178 | 0.0% | 13,901 | 0.1%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of hepatitis B (based on all-listed diagnoses) was 0.1% (Table 149). Hepatitis B was uncommon among children and adolescents and the youngest adults and prevalence was highest among persons 55–74 years. Prevalence did not differ by sex and was highest among Asians, similar among Blacks and Hispanics, and lowest among Whites. It was highest in the Northeast and lowest in the Midwest.

Table 150 Hepatitis B: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 9 | 1 | 34 | 3
Age (years) | 12 to 24 | 107 | 7 | 172 | 12
Age (years) | 25 to 44 | 1,740 | 65 | 3,365 | 127
Age (years) | 45 to 54 | 1,733 | 119 | 4,102 | 282
Age (years) | 55 to 64 | 1,586 | 97 | 4,978 | 303
Age (years) | 65 to 74 | 3,166 | 111 | 10,367 | 365
Age (years) | 75 plus | 1,175 | 46 | 4,360 | 169
Race-ethnicity | White | 1,992 | 23 | 6,877 | 79
Race-ethnicity | Black | 931 | 75 | 2,886 | 232
Race-ethnicity | Hispanic | 536 | 36 | 1,940 | 130
Race-ethnicity | Asian | 5,005 | 824 | 12,783 | 2,105
Race-ethnicity | Unknown | 1,052 | 61 | 2,892 | 168
Sex | Female | 4,282 | 59 | 12,101 | 168
Sex | Male | 5,234 | 80 | 15,277 | 234
Region | Northeast | 2,049 | 134 | 5,761 | 377
Region | Midwest | 999 | 30 | 2,647 | 80
Region | South | 3,400 | 61 | 10,329 | 184
Region | West | 3,068 | 94 | 8,641 | 266
Total | | 9,516 | 69 | 27,378 | 200

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with hepatitis B (all-listed diagnoses) increased with age until 75 years and were higher among men compared with women (Table 150). Among persons with known race-ethnicity, rates were much higher among Asians, followed by Blacks, then Hispanics, and lowest among Whites. Rates were highest in the Northeast, followed by the West, then the South, and lowest in the Midwest.

Table 151 Hepatitis B: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | 3 | 0 | 3 | 0
Age (years) | 25 to 44 | 37 | 1 | 121 | 5
Age (years) | 45 to 54 | 2 | 0 | 16 | 1
Age (years) | 55 to 64 | 1 | 0 | 27 | 2
Age (years) | 65 to 74 | 1 | 0 | 25 | 1
Age (years) | 75 plus | . | . | 23 | 1
Race-ethnicity | White | 10 | 0 | 63 | 1
Race-ethnicity | Black | 5 | 0 | 26 | 2
Race-ethnicity | Hispanic | . | . | 8 | 1
Race-ethnicity | Asian | 14 | 2 | 52 | 9
Race-ethnicity | Unknown | 15 | 1 | 66 | 4
Sex | Female | 43 | 1 | 162 | 2
Sex | Male | 1 | 0 | 53 | 1
Region | Northeast | 7 | 0 | 28 | 2
Region | Midwest | 5 | 0 | 49 | 1
Region | South | 21 | 0 | 96 | 2
Region | West | 11 | 0 | 42 | 1
Total | | 44 | 0 | 215 | 2

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with hepatitis B (all-listed diagnoses) were highest among persons 25 to 44 years and differed little by sex (Table 151). Among persons with known race-ethnicity, rates were much higher among Asians compared with other race-ethnicities. Rates were higher in the Northeast and South compared with the Midwest and West.

Table 152 Hepatitis B: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | 4 | 0
Age (years) | 12 to 24 | . | . | 14 | 1
Age (years) | 25 to 44 | 8 | 0 | 211 | 8
Age (years) | 45 to 54 | 6 | 0 | 225 | 15
Age (years) | 55 to 64 | 6 | 0 | 457 | 28
Age (years) | 65 to 74 | 7 | 0 | 870 | 31
Age (years) | 75 plus | 4 | 0 | 504 | 20
Race-ethnicity | White | 17 | 0 | 1,030 | 12
Race-ethnicity | Black | 4 | 0 | 434 | 35
Race-ethnicity | Hispanic | 7 | 0 | 189 | 13
Race-ethnicity | Asian | 2 | 0 | 414 | 68
Race-ethnicity | Unknown | 1 | 0 | 218 | 13
Sex | Female | 12 | 0 | 900 | 13
Sex | Male | 19 | 0 | 1,385 | 21
Region | Northeast | 3 | 0 | 354 | 23
Region | Midwest | 3 | 0 | 327 | 10
Region | South | 23 | 0 | 1,110 | 20
Region | West | 2 | 0 | 494 | 15
Total | | 31 | 0 | 2,285 | 17

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with hepatitis B (all-listed diagnoses) increased with age until 75 years and were higher among men compared with women (Table 152). Among persons with known race-ethnicity, rates were highest among Asians, followed by Blacks, and lowest among Whites and Hispanics. Rates were highest in the Northeast, followed by the South, then the West, and lowest in the Midwest.

Table 153 Hepatitis B: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 6,500 | 0.1% | 15,680 | 0.2%
Age (years) | 70 to 74 | 6,936,940 | 4,720 | 0.1% | 11,560 | 0.2%
Age (years) | 75 to 79 | 4,894,060 | 2,140 | 0.0% | 5,540 | 0.1%
Age (years) | 80 to 84 | 3,335,340 | 1,580 | 0.0% | 3,900 | 0.1%
Age (years) | 85+ | 3,578,120 | 740 | 0.0% | 2,280 | 0.1%
Race | White | 22,023,800 | 4,120 | 0.0% | 14,740 | 0.1%
Race | Black | 1,861,660 | 1,480 | 0.1% | 4,560 | 0.2%
Race | Other | 2,925,320 | 10,080 | 0.3% | 19,660 | 0.7%
Sex | Female | 14,975,560 | 8,060 | 0.1% | 18,960 | 0.1%
Sex | Male | 11,835,220 | 7,620 | 0.1% | 20,000 | 0.2%
Region | Northeast | 4,748,700 | 2,980 | 0.1% | 7,740 | 0.2%
Region | Midwest | 6,069,800 | 1,780 | 0.0% | 5,080 | 0.1%
Region | South | 10,595,900 | 4,700 | 0.0% | 12,300 | 0.1%
Region | West | 5,396,380 | 6,220 | 0.1% | 13,840 | 0.3%
Total | | 26,810,780 | 15,680 | 0.1% | 38,960 | 0.1%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of hepatitis B (based on all-listed diagnoses) was 0.1% (Table 153). Prevalence was highest among persons 65–74 years and was higher among men and Blacks. It was highest in the West, and lowest in the Midwest and South.

Table 154 Hepatitis B: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 12,000 | 149 | 36,920 | 458
Age (years) | 70 to 74 | 8,980 | 129 | 30,120 | 434
Age (years) | 75 to 79 | 3,700 | 76 | 14,260 | 291
Age (years) | 80 to 84 | 3,060 | 92 | 11,340 | 340
Age (years) | 85+ | 1,180 | 33 | 5,700 | 159
Race | White | 6,900 | 31 | 25,840 | 117
Race | Black | 2,660 | 143 | 9,540 | 512
Race | Other | 19,360 | 662 | 62,960 | 2,152
Sex | Female | 14,860 | 99 | 48,540 | 324
Sex | Male | 14,060 | 119 | 49,800 | 421
Region | Northeast | 5,540 | 117 | 22,660 | 477
Region | Midwest | 2,960 | 49 | 9,700 | 160
Region | South | 8,500 | 80 | 26,100 | 246
Region | West | 11,920 | 221 | 39,880 | 739
Total | | 28,920 | 108 | 98,340 | 367

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with hepatitis B (all-listed diagnoses) generally decreased with age and were higher among men compared with women and over four times higher among Blacks compared with Whites (Table 154). Rates were highest in the West, followed by the Northeast, then the South, and lowest in the Midwest.

Table 155 Hepatitis B: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | . | . | 3,920 | 49
Age (years) | 70 to 74 | . | . | 2,860 | 41
Age (years) | 75 to 79 | . | . | 1,240 | 25
Age (years) | 80 to 84 | . | . | 1,460 | 44
Age (years) | 85+ | . | . | 1,020 | 29
Race | White | . | . | 4,640 | 21
Race | Black | . | . | 2,540 | 136
Race | Other | . | . | 3,320 | 113
Sex | Female | . | . | 4,400 | 29
Sex | Male | . | . | 6,100 | 52
Region | Northeast | . | . | 1,820 | 38
Region | Midwest | . | . | 2,160 | 36
Region | South | . | . | 3,700 | 35
Region | West | . | . | 2,820 | 52
Total | | . | . | 10,500 | 39

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year. Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with hepatitis B (all-listed diagnoses) were highest among persons 65 to 69 years and were higher among men compared with women and over six times higher among Blacks compared with Whites (Table 155). Rates were higher in the West compared with the South, Midwest, and Northeast.

Table 156 Hepatitis B: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | . | . | 3,940 | 49
Age (years) | 70 to 74 | . | . | 3,040 | 44
Age (years) | 75 to 79 | . | . | 1,440 | 29
Age (years) | 80 to 84 | . | . | 1,440 | 43
Age (years) | 85+ | . | . | 880 | 25
Race | White | . | . | 5,240 | 24
Race | Black | . | . | 2,320 | 125
Race | Other | . | . | 3,180 | 109
Sex | Female | . | . | 4,500 | 30
Sex | Male | . | . | 6,240 | 53
Region | Northeast | . | . | 2,080 | 44
Region | Midwest | . | . | 1,960 | 32
Region | South | . | . | 3,920 | 37
Region | West | . | . | 2,780 | 52
Total | | . | . | 10,740 | 40

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with hepatitis B (all-listed diagnoses) were highest among persons 65 to 69 years and were higher among men compared with women and five times higher among Blacks compared with Whites (Table 156). Rates were highest in the West, followed by the Northeast, then the South, and lowest in the Midwest.

## Hepatitis C

Table 157 Hepatitis C: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2015

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 1 | 2
Age (years) | 12 to 24 | 31 | 56 | 48 | 85
Age (years) | 25 to 44 | 95 | 112 | 314 | 372
Age (years) | 45 to 54 | 151 | 349 | 371 | 861
Age (years) | 55 to 64 | 242 | 592 | 831 | 2,037
Age (years) | 65 to 74 | 61 | 223 | 392 | 1,425
Age (years) | 75 plus | . | . | 114 | 565
Race | White | 478 | 165 | 1,719 | 561
Race | Black | 97 | 203 | 271 | 567
Race | Other | 5 | 21 | 82 | 309
Ethnicity | Hispanic | 15 | 29 | 352 | 818
Ethnicity | Not Hispanic | 565 | 176 | 1,719 | 525
Sex | Female | 280 | 138 | 888 | 434
Sex | Male | 300 | 174 | 1,184 | 665
Total | | 580 | 156 | 2,072 | 542

Source: National Ambulatory Medical Care Survey (3-year average, 2014–2016).

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis C contributed to 2.1 million ambulatory visits (2015) (Table 157). Ambulatory care visit rates (all-listed diagnoses) peaked among persons 55–64 years. Age-adjusted rates were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 158 Hepatitis C: Emergency department visits with first-listed and all-listed diagnoses by age and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 0 | 0 | 1
Age (years) | 12 to 24 | 1 | 1 | 15 | 27
Age (years) | 25 to 44 | 4 | 4 | 217 | 249
Age (years) | 45 to 54 | 1 | 3 | 182 | 436
Age (years) | 55 to 64 | 1 | 4 | 300 | 710
Age (years) | 65 to 74 | 1 | 2 | 124 | 407
Age (years) | 75 plus | 0 | 1 | 26 | 120
Sex | Female | 3 | 2 | 333 | 181
Sex | Male | 5 | 3 | 531 | 290
Total | | 8 | 2 | 865 | 234

Source: Healthcare Cost and Utilization Project Nationwide Emergency Department Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis C contributed to 865,000 emergency department visits in 2018 (Table 158). Emergency department visit rates (all-listed diagnoses) peaked among persons 55–64 years. Age-adjusted rates were higher among men compared with women.

Table 159 Hepatitis C: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | . | . | 0 | 0
Age (years) | 12 to 24 | 0 | 0 | 13 | 23
Age (years) | 25 to 44 | 1 | 2 | 146 | 168
Age (years) | 45 to 54 | 1 | 1 | 112 | 270
Age (years) | 55 to 64 | 1 | 2 | 209 | 495
Age (years) | 65 to 74 | 0 | 1 | 98 | 321
Age (years) | 75 plus | 0 | 0 | 21 | 97
Race | White | 3 | 1 | 453 | 158
Race | Black | 0 | 1 | 126 | 250
Race | Other | 0 | 1 | 29 | 106
Ethnicity | Hispanic | 0 | 1 | 71 | 140
Ethnicity | Not Hispanic | 3 | 1 | 537 | 169
Sex | Female | 1 | 1 | 233 | 125
Sex | Male | 2 | 1 | 367 | 197
Total | | 3 | 1 | 600 | 160

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Hepatitis C contributed to 600,000 hospital discharges in 2018 (Table 159). Hospital discharge rates (all-listed diagnoses) peaked among persons 55–64 years. Age-adjusted rates were higher among men compared with women, Blacks compared with Whites, and non-Hispanics compared with Hispanics. Between 2004 and 2018, age-adjusted hospital discharge rates (per 100,000) with an all-listed diagnosis increased by 12% from 143 to 160.(7)

Table 160 Hepatitis C: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | . | . | . | . | . | .
Age (years) | 12 to 24 | 2 | 0.0 | 0.1 | 7 | 0.0 | 0.4
Age (years) | 25 to 44 | 144 | 0.2 | 6.0 | 643 | 0.7 | 27.2
Age (years) | 45 to 54 | 478 | 1.2 | 14.6 | 1,685 | 4.1 | 50.9
Age (years) | 55 to 64 | 1,525 | 3.6 | 34.8 | 6,343 | 14.9 | 141.7
Age (years) | 65 to 74 | 1,045 | 3.3 | 17.1 | 4,515 | 14.3 | 72.6
Age (years) | 75 plus | 327 | 1.4 | 2.8 | 1,120 | 5.0 | 9.6
Race | White | 2,826 | 0.8 | 62.4 | 10,999 | 3.2 | 241.5
Race | Black | 550 | 1.1 | 10.1 | 2,693 | 5.2 | 48.1
Race | Other | 145 | 0.5 | 2.9 | 621 | 2.3 | 12.9
Ethnicity | Hispanic | 451 | 0.9 | 10.7 | 1,457 | 3.0 | 34.1
Ethnicity | Not Hispanic | 3,070 | 0.8 | 64.7 | 12,856 | 3.4 | 268.4
Sex | Female | 1,258 | 0.6 | 28.6 | 4,030 | 1.8 | 93.6
Sex | Male | 2,263 | 1.1 | 46.8 | 10,283 | 4.9 | 208.9
Total | | 3,521 | 0.8 | 75.4 | 14,313 | 3.3 | 302.5

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Hepatitis C contributed to 14,000 deaths in 2019 (Table 160). Mortality rates (underlying or other cause) peaked among persons 55–64 years. Age-adjusted mortality rates were higher among men, Blacks, and non-Hispanics. Between 2004 and 2019, age-adjusted mortality rates (per 100,000) with hepatitis C as underlying or other cause decreased by 13% from 3.8 to 3.3. (4)

Table 161 Hepatitis C: Claims-based prevalence with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 0 to 11 | 1,101,978 | 9 | 0.0% | 23 | 0.0%
Age (years) | 12 to 24 | 1,451,892 | 78 | 0.0% | 143 | 0.0%
Age (years) | 25 to 44 | 2,656,672 | 855 | 0.0% | 1,904 | 0.1%
Age (years) | 45 to 54 | 1,452,320 | 788 | 0.1% | 2,502 | 0.2%
Age (years) | 55 to 64 | 1,640,216 | 2,851 | 0.2% | 10,497 | 0.6%
Age (years) | 65 to 74 | 2,840,615 | 4,838 | 0.2% | 18,032 | 0.6%
Age (years) | 75 plus | 2,576,241 | 923 | 0.0% | 4,272 | 0.2%
Race-ethnicity | White | 8,657,702 | 5,560 | 0.1% | 20,564 | 0.2%
Race-ethnicity | Black | 1,242,477 | 2,102 | 0.2% | 7,171 | 0.6%
Race-ethnicity | Hispanic | 1,493,457 | 1,197 | 0.1% | 4,562 | 0.3%
Race-ethnicity | Asian | 607,284 | 276 | 0.0% | 1,047 | 0.2%
Race-ethnicity | Unknown | 1,719,014 | 1,207 | 0.1% | 4,029 | 0.2%
Sex | Female | 7,199,363 | 4,044 | 0.1% | 14,997 | 0.2%
Sex | Male | 6,520,571 | 6,298 | 0.1% | 22,376 | 0.3%
Region | Northeast | 1,526,275 | 1,188 | 0.1% | 4,269 | 0.3%
Region | Midwest | 3,322,846 | 1,356 | 0.0% | 4,930 | 0.1%
Region | South | 5,619,435 | 5,668 | 0.1% | 20,093 | 0.4%
Region | West | 3,251,378 | 2,130 | 0.1% | 8,081 | 0.2%
Total | | 13,719,934 | 10,342 | 0.1% | 37,373 | 0.3%

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among privately insured enrollees, the claims-based prevalence of hepatitis C (based on all-listed diagnoses) was 0.3% (Table 161). Prevalence peaked among persons 55–74 years and was higher among men. It was highest among Blacks, followed by Hispanics, and lowest among Whites and Asians. It was highest in the South and lowest in the Midwest.

Table 162 Hepatitis C: Ambulatory care visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | 16 | 1 | 45 | 4
Age (years) | 12 to 24 | 126 | 9 | 271 | 19
Age (years) | 25 to 44 | 1,457 | 55 | 3,692 | 139
Age (years) | 45 to 54 | 1,606 | 111 | 5,314 | 366
Age (years) | 55 to 64 | 4,825 | 294 | 21,782 | 1,328
Age (years) | 65 to 74 | 7,997 | 282 | 36,232 | 1,275
Age (years) | 75 plus | 1,459 | 57 | 8,009 | 311
Race-ethnicity | White | 9,257 | 107 | 40,491 | 468
Race-ethnicity | Black | 3,514 | 283 | 14,905 | 1,200
Race-ethnicity | Hispanic | 1,946 | 130 | 9,346 | 626
Race-ethnicity | Asian | 408 | 67 | 1,923 | 317
Race-ethnicity | Unknown | 2,361 | 137 | 8,680 | 505
Sex | Female | 6,530 | 91 | 29,672 | 412
Sex | Male | 10,956 | 168 | 45,673 | 700
Region | Northeast | 1,902 | 125 | 8,348 | 547
Region | Midwest | 2,427 | 73 | 9,366 | 282
Region | South | 9,675 | 172 | 41,631 | 741
Region | West | 3,482 | 107 | 16,000 | 492
Total | | 17,486 | 127 | 75,345 | 549

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, ambulatory care visit rates with hepatitis C (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among men compared with women (Table 162). Among persons with known race-ethnicity, rates were much higher among Blacks, followed by Hispanics, then Whites, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 163 Hepatitis C: Emergency department visits with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | . | .
Age (years) | 12 to 24 | . | . | 4 | 0
Age (years) | 25 to 44 | 5 | 0 | 65 | 2
Age (years) | 45 to 54 | 3 | 0 | 55 | 4
Age (years) | 55 to 64 | 19 | 1 | 213 | 13
Age (years) | 65 to 74 | 10 | 0 | 234 | 8
Age (years) | 75 plus | 3 | 0 | 56 | 2
Race-ethnicity | White | 24 | 0 | 347 | 4
Race-ethnicity | Black | 12 | 1 | 114 | 9
Race-ethnicity | Hispanic | 2 | 0 | 60 | 4
Race-ethnicity | Asian | . | . | 11 | 2
Race-ethnicity | Unknown | 2 | 0 | 95 | 6
Sex | Female | 17 | 0 | 228 | 3
Sex | Male | 23 | 0 | 399 | 6
Region | Northeast | 1 | 0 | 95 | 6
Region | Midwest | 7 | 0 | 93 | 3
Region | South | 27 | 0 | 315 | 6
Region | West | 5 | 0 | 124 | 4
Total | | 40 | 0 | 627 | 5

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, emergency department visit rates with hepatitis C (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among men compared with women (Table 163). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Rates were higher in the Northeast and South compared with the West and Midwest.

Table 164 Hepatitis C: Hospital discharges with first-listed and all-listed diagnoses by age, race-ethnicity, sex and region among privately insured enrollees, 2020

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 0 to 11 | . | . | 1 | 0
Age (years) | 12 to 24 | . | . | 41 | 3
Age (years) | 25 to 44 | 1 | 0 | 436 | 16
Age (years) | 45 to 54 | 2 | 0 | 924 | 64
Age (years) | 55 to 64 | 6 | 0 | 3,968 | 242
Age (years) | 65 to 74 | 18 | 1 | 5,690 | 200
Age (years) | 75 plus | 3 | 0 | 1,480 | 57
Race-ethnicity | White | 16 | 0 | 6,740 | 78
Race-ethnicity | Black | 5 | 0 | 2,771 | 223
Race-ethnicity | Hispanic | 2 | 0 | 1,281 | 86
Race-ethnicity | Asian | . | . | 196 | 32
Race-ethnicity | Unknown | 7 | 0 | 1,552 | 90
Sex | Female | 14 | 0 | 4,904 | 68
Sex | Male | 16 | 0 | 7,636 | 117
Region | Northeast | 1 | 0 | 1,405 | 92
Region | Midwest | 5 | 0 | 1,764 | 53
Region | South | 18 | 0 | 7,127 | 127
Region | West | 6 | 0 | 2,244 | 69
Total | | 30 | 0 | 12,540 | 91

Source: De-identified Optum Clinformatic ® Data Mart.

Enrollees with full enrollment in a commercial health plan or Medicare during the year.

Among commercial insurance enrollees, hospital discharge rates with hepatitis C (all-listed diagnoses) peaked among persons 55 to 64 years and were higher among men compared with women (Table 164). Among persons with known race-ethnicity, rates were highest among Blacks, followed by Hispanics, then Whites, and lowest among Asians. Rates were highest in the South, followed by the Northeast, then the West, and lowest in the Midwest.

Table 165 Hepatitis C: Claims-based prevalence with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | Number of enrollees | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of enrollees | Number of enrollees with disease | Percent of enrollees with disease | Number of enrollees with disease | Percent of enrollees with disease
Age (years) | 65 to 69 | 8,066,320 | 23,280 | 0.3% | 69,660 | 0.9%
Age (years) | 70 to 74 | 6,936,940 | 8,880 | 0.1% | 28,340 | 0.4%
Age (years) | 75 to 79 | 4,894,060 | 3,620 | 0.1% | 11,460 | 0.2%
Age (years) | 80 to 84 | 3,335,340 | 1,880 | 0.1% | 6,420 | 0.2%
Age (years) | 85+ | 3,578,120 | 920 | 0.0% | 4,920 | 0.1%
Race | White | 22,023,800 | 23,820 | 0.1% | 74,000 | 0.3%
Race | Black | 1,861,660 | 9,280 | 0.5% | 29,360 | 1.6%
Race | Other | 2,925,320 | 5,480 | 0.2% | 17,440 | 0.6%
Sex | Female | 14,975,560 | 15,740 | 0.1% | 46,860 | 0.3%
Sex | Male | 11,835,220 | 22,840 | 0.2% | 73,940 | 0.6%
Region | Northeast | 4,748,700 | 6,700 | 0.1% | 24,040 | 0.5%
Region | Midwest | 6,069,800 | 5,660 | 0.1% | 18,840 | 0.3%
Region | South | 10,595,900 | 14,940 | 0.1% | 46,500 | 0.4%
Region | West | 5,396,380 | 11,280 | 0.2% | 31,420 | 0.6%
Total | | 26,810,780 | 38,580 | 0.1% | 120,800 | 0.5%

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, the claims-based prevalence of hepatitis C (based on all-listed diagnoses) was 0.5% (Table 165). Prevalence decreased with age and was higher among men and Blacks. It was highest in the West, and lowest in the Midwest.

Table 166 Hepatitis C: Ambulatory care visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 42,580 | 528 | 154,180 | 1,911
Age (years) | 70 to 74 | 16,240 | 234 | 63,940 | 922
Age (years) | 75 to 79 | 6,720 | 137 | 25,720 | 526
Age (years) | 80 to 84 | 4,420 | 133 | 14,380 | 431
Age (years) | 85+ | 1,840 | 51 | 9,300 | 260
Race | White | 41,560 | 189 | 154,420 | 701
Race | Black | 18,460 | 992 | 70,440 | 3,784
Race | Other | 11,780 | 403 | 42,660 | 1,458
Sex | Female | 29,940 | 200 | 102,340 | 683
Sex | Male | 41,860 | 354 | 165,180 | 1,396
Region | Northeast | 12,240 | 258 | 51,280 | 1,080
Region | Midwest | 9,460 | 156 | 38,660 | 637
Region | South | 28,120 | 265 | 107,020 | 1,010
Region | West | 21,980 | 407 | 70,560 | 1,308
Total | | 71,800 | 268 | 267,520 | 998

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, ambulatory care visit rates with hepatitis C (all-listed diagnoses) decreased with age and were twice as high among men compared with women and over five times higher among Blacks compared with Whites (Table 166). Rates were highest in the West, followed by the Northeast and South, and lowest in the Midwest.

Table 167 Hepatitis C: Emergency department visits with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | 240 | 3 | 36,740 | 455
Age (years) | 70 to 74 | . | . | 14,120 | 204
Age (years) | 75 to 79 | . | . | 6,280 | 128
Age (years) | 80 to 84 | . | . | 2,920 | 88
Age (years) | 85+ | . | . | 2,940 | 82
Race | White | . | . | 34,500 | 157
Race | Black | . | . | 20,620 | 1,108
Race | Other | . | . | 7,880 | 269
Sex | Female | . | . | 23,300 | 156
Sex | Male | . | . | 39,700 | 335
Region | Northeast | . | . | 12,780 | 269
Region | Midwest | . | . | 10,660 | 176
Region | South | . | . | 23,600 | 223
Region | West | . | . | 15,960 | 296
Total | | 400 | 1 | 63,000 | 235

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, emergency department visit rates with hepatitis C (all-listed diagnoses) decreased with age and were over twice as high among men compared with women and seven times higher among Blacks compared with Whites (Table 167). Rates were highest in the West, followed by the Northeast, then the South, and lowest in the Midwest.

Table 168 Hepatitis C: Hospital discharges with first-listed and all-listed diagnoses by age, race, sex and region among fee-for-service, age-eligible Medicare beneficiaries, 2019

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number of events | Event rate per 100,000 | Number of events | Event rate per 100,000
Age (years) | 65 to 69 | . | . | 30,660 | 380
Age (years) | 70 to 74 | . | . | 11,920 | 172
Age (years) | 75 to 79 | . | . | 5,460 | 112
Age (years) | 80 to 84 | . | . | 2,500 | 75
Age (years) | 85+ | . | . | 2,520 | 70
Race | White | . | . | 30,080 | 137
Race | Black | . | . | 16,160 | 868
Race | Other | . | . | 6,820 | 233
Sex | Female | . | . | 19,280 | 129
Sex | Male | . | . | 33,780 | 285
Region | Northeast | . | . | 11,400 | 240
Region | Midwest | . | . | 8,940 | 147
Region | South | . | . | 20,100 | 190
Region | West | . | . | 12,620 | 234
Total | | . | . | 53,060 | 198

Source: Centers for Medicare & Medicaid Services, 5% Denominator and Claims Files.

Beneficiaries aged 65+ years with continuous and full Parts A and B enrollment and no Health Maintenance Organization enrollment during the year.

Unweighted counts were multiplied by 20 to produce counts for this table.

Among Medicare beneficiaries, hospital discharge rates with hepatitis C (all-listed diagnoses) decreased with age and were over twice as high among men compared with women and over six times higher among Blacks compared with Whites (Table 168). Rates were highest in the Northeast, followed by the West, then the South, and lowest in the Midwest.

## Primary Liver Cancer

Table 253 Primary Liver Cancer: Incidence rates by age, race, ethnicity, and sex, 2016

Demographic Characteristics | | Number of cases | Incidence per 100,000
Age (years) | 0 to 11 | 179 | 0.4
Age (years) | 12 to 24 | . | 0.2
Age (years) | 25 to 44 | 385 | 0.4
Age (years) | 45 to 54 | 1,852 | 4.4
Age (years) | 55 to 64 | 8,495 | 20.1
Age (years) | 65 to 74 | 9,980 | 32.7
Age (years) | 75 plus | 6,524 | 29.7
Race | White | 18,768 | 5.5
Race | Black | 4,365 | 9.5
Race | Other | 2,726 | 9.9
Ethnicity | Hispanic | 4,316 | 10.8
Ethnicity | Not Hispanic | 22,065 | 6.1
Sex | Female | 6,640 | 3.1
Sex | Male | 19,823 | 10.4
Total | | 26,497 | 6.5

Source: Surveillance, Epidemiology, and End Results (SEER) Program.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Primary liver cancer accounted for 26,000 incident cases in 2016 (Table 253). Primary liver cancer was uncommon in childhood through young adulthood and incidence rates peaked among persons 65–74 years. Age-adjusted incidence rates were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 254 Primary Liver Cancer: Hospital discharges with first-listed and all-listed diagnoses by age, race, ethnicity, and sex in the United States, 2018

Demographic Characteristics | | First-Listed Diagnosis | | All-Listed Diagnoses
Demographic Characteristics | | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000
Age (years) | 0 to 11 | 0 | 1 | 2 | 4
Age (years) | 12 to 24 | 0 | 0 | 0 | 1
Age (years) | 25 to 44 | 0 | 0 | 2 | 2
Age (years) | 45 to 54 | 1 | 3 | 6 | 14
Age (years) | 55 to 64 | 6 | 13 | 23 | 54
Age (years) | 65 to 74 | 5 | 16 | 21 | 67
Age (years) | 75 plus | 3 | 14 | 13 | 58
Race | White | 11 | 3 | 49 | 14
Race | Black | 2 | 5 | 10 | 20
Race | Other | 2 | 9 | 7 | 28
Ethnicity | Hispanic | 3 | 6 | 11 | 26
Ethnicity | Not Hispanic | 13 | 4 | 55 | 15
Sex | Female | 4 | 2 | 18 | 8
Sex | Male | 11 | 6 | 47 | 24
Total | | 16 | 4 | 65 | 16

Source: Healthcare Cost and Utilization Project National Inpatient Sample.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Primary liver cancer contributed to 65,000 hospital discharges in 2018 (Table 254). Primary liver cancer hospitalization was uncommon in childhood through young adulthood and rates peaked among persons 65–74 years. Age-adjusted hospital discharge rates (all-listed diagnoses) were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.

Table 255 Primary Liver Cancer: Deaths with underlying or underlying/other cause and lifetime years of life lost by age, race, ethnicity, and sex in the United States, 2019

Demographic Characteristics | | Underlying Cause | | | Underlying/Other Cause
Demographic Characteristics | | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands | Number of Deaths | Rate per 100,000 | Years of potential life lost in thousands
Age (years) | 0 to 11 | 28 | 0.1 | 2.1 | 32 | 0.1 | 2.4
Age (years) | 12 to 24 | 29 | 0.1 | 1.7 | 30 | 0.1 | 1.8
Age (years) | 25 to 44 | 233 | 0.3 | 9.6 | 260 | 0.3 | 10.7
Age (years) | 45 to 54 | 963 | 2.4 | 28.4 | 1,110 | 2.7 | 32.8
Age (years) | 55 to 64 | 5,547 | 13.1 | 121.0 | 6,235 | 14.7 | 136.2
Age (years) | 65 to 74 | 7,041 | 22.4 | 110.0 | 7,957 | 25.3 | 124.2
Age (years) | 75 plus | 6,353 | 28.1 | 51.1 | 7,051 | 31.2 | 56.7
Race | White | 15,745 | 4.4 | 250.6 | 17,711 | 4.9 | 283.0
Race | Black | 2,971 | 6.2 | 49.2 | 3,314 | 6.9 | 54.9
Race | Other | 1,478 | 5.8 | 24.2 | 1,650 | 6.5 | 26.9
Ethnicity | Hispanic | 2,410 | 5.8 | 44.9 | 2,722 | 6.5 | 51.3
Ethnicity | Not Hispanic | 17,784 | 4.6 | 279.1 | 19,953 | 5.1 | 313.6
Sex | Female | 5,513 | 2.4 | 85.9 | 6,118 | 2.6 | 95.9
Sex | Male | 14,681 | 7.4 | 238.1 | 16,557 | 8.3 | 269.0
Total | | 20,194 | 4.7 | 324.0 | 22,675 | 5.3 | 364.9

Source: Vital Statistics of the United States.

Rates for age groups are unadjusted and all other rates are age-adjusted.

Years of potential life lost is based on U.S. life table 2006–2018 estimates of life expectancy at age of death.

Primary liver cancer contributed to 23,000 deaths in 2019 (Table 255). Primary liver cancer mortality rates increased with age. Age-adjusted mortality rates (underlying or other cause) were higher among men compared with women, Blacks compared with Whites, and Hispanics compared with non-Hispanics.