# Chapter 1 Burden of Digestive Diseases in the United States

## ABSTRACT

Background & Aims. Digestive diseases are common in the United States (U.S.) and lead to significant morbidity, mortality, and health care utilization. We used national survey and claims databases to investigate rates and trends in the digestive disease burden over the past two decades in the U.S. Methods. The National Ambulatory Medical Care Survey, Nationwide Emergency Department Sample, National Inpatient Sample, Vital Statistics of the U.S.: Multiple Cause-of-Death Data, Optum Clinformatics® Data Mart, and Centers for Medicare and Medicaid Services Medicare 5% Sample and Medicaid files were used to estimate medical care, mortality, and claims-based prevalence among covered events and persons with a digestive disease diagnosis. Results. Digestive diseases contributed to 126 million ambulatory care visits (2018-2019), 39 million emergency department visits (2022), 15 million hospital stays (2022), and 527,000 deaths (2023). Women had higher medical care rates with a digestive disease diagnosis, but mortality rates were higher among men. Blacks and American Indians / Alaska Natives had higher digestive disease mortality rates compared with Whites and higher emergency department visit and hospitalization rates. Hispanics, Asians, and Native Hawaiians / Pacific Islanders had lower mortality rates compared with Whites, and Asians and Native Hawaiians / Pacific Islanders had lower medical care use rates. Hispanics had higher ambulatory care visit rates and lower hospitalization rates compared with Whites. During the study period (2006 through the most recent year available for each data source), the digestive disease mortality rate declined and then stabilized before rising since the COVID-19 pandemic. National ambulatory care and emergency department visit rates with a digestive disease diagnosis rose, while hospitalization rates declined. Digestive disease prevalence (claims-based) was 25% among private insurance enrollees (2023) and Medicaid beneficiaries (2022) and 52% among Medicare beneficiaries (2022) and rose over the previous decade among private insurance enrollees and Medicare beneficiaries. Conclusions. The digestive disease burden in the U.S. is substantial, particularly among Blacks, American Indians / Alaska Natives, older adults, and lower income Medicaid beneficiaries. Further research is needed to better understand reasons for group differences and trends in health care use and mortality reported in this paper.

## INTRODUCTION

Diseases of the digestive system include acute and chronic conditions affecting the gastrointestinal tract, liver, pancreas, and gallbladder. Causes include congenital and genetic anomalies, acute and chronic infections, cancer, adverse drug and toxin effects, and idiopathic. Digestive diseases are common in the United States (U.S.) and lead to significant morbidity, mortality, and health care utilization. In 2008, in conjunction with the mission of the National Commission on Digestive Diseases (NCDD) to develop a digestive disease research plan, the National Institute of Diabetes and Digestive and Kidney Diseases (NIDDK) published the Burden of Digestive Diseases in the United States report.(1,2) Based on those data, digestive diseases (all-listed) contributed to an estimated 105 million ambulatory care visits, 14 million hospital stays, and over 366,000 deaths in 2004.(3) Age-adjusted ambulatory care visit rates increased by a third between 1992 and 2005.(3) This trend in increasing ambulatory care visit rates started at least as early as 1985.(3,4) Hospitalization rates fell between 1983 and 1988, were stable over the next decade, and rose by a third between 1998 and 2004 to equal the previous 1982 peak.(3) In contrast to health care use rates, mortality rates gradually declined by around 20% between 1979 and 2004 both as underlying and as underlying or other cause.(3)

The literature on the burden of digestive diseases overall is limited.(5, 6) A more recent paper on the gastrointestinal, liver, and pancreatic disease burden in the U.S. found an estimated 47 million visits across ambulatory settings with a first-listed digestive disease diagnosis in 2019.(7) There were 15 million emergency department visits and 2.9 million hospital admissions with a first-listed digestive disease diagnosis in 2021.(7) Digestive cancers and non-malignant digestive diseases were the underlying cause of 281,413 deaths in 2021.(7)

Since publication of the above paper by Peery et al., additional years of health care use and mortality data have become available. More recently we examined the U.S. digestive disease burden focusing on pre-COVID-19 pandemic rates and trends.(6) In addition to representative samples of national data, we included private insurance, Medicare, and Medicaid claims data with the advantage of much larger sample sizes. While earlier papers primarily focused on the overall U.S. population, we also examined the digestive disease burden in population groups in order to reveal demographic differences in health care use and mortality. Understanding where population group differences exist is a necessary first step to achieving health for all.(8) In the current report, we used national survey and claims databases to expand on earlier findings and investigate rates and trends in the U.S. digestive disease burden, overall and among population groups, over the past two decades, including the initial years immediately following the COVID-19 pandemic.(2-4,9-13) The burden of selected digestive diseases will be described separately in subsequent chapters. Current digestive disease burden estimates are useful to multidisciplinary clinicians, researchers, public health professionals, and policy makers for better planning and implementation.

## METHODS

### Data sources

The National Ambulatory Medical Care Survey (NAMCS), 2005-2019, Healthcare Cost and Utilization Project (HCUP) Nationwide Emergency Department Sample (NEDS), 2006-2022, HCUP National Inpatient Sample (NIS), 2006-2022, Vital Statistics of the U.S.: Multiple Cause-of-Death Data, 2006-2023, Optum Clinformatics® Data Mart (CDM), 2007-2023, and the Centers for Medicare and Medicaid Services (CMS) Medicare 5% Sample, 2006-2022, and Medicaid files, 2017-2022, were used to estimate health care utilization, mortality, years of potential life lost, and claims-based prevalence with a first-listed or other digestive disease diagnosis (i.e. all-listed diagnosis). Data sources are described briefly below and in more detail in Appendix 1 and online.(14-19)

The NAMCS is conducted by the National Center for Health Statistics of the Centers for Disease Control and Prevention (CDC) and consists of a nationally representative sample of visits to office-based healthcare providers.(14) The HCUP NEDS and NIS are maintained by the Agency for Healthcare Research and Quality. The NEDS consists of a nationally representative sample of visits to emergency departments.(15) The NIS consists of a nationally representative sample of hospital discharges.(16) The Vital Statistics of the U.S.: Multiple Cause-of-Death Data include all deaths occurring within the U.S.(17)

Optum’s CDM is comprised of administrative health care claims for members of large private health plans.(18) Most private insurance enrollees are employed persons who receive health insurance through their employer. The Medicare 5% sample files were created by CMS to be representative of all Medicare beneficiaries. The CMS Medicaid files include all Medicaid beneficiaries. Both CMS data files are housed in the Chronic Conditions Data Warehouse.(19) Medicaid eligibility is based on income below a certain level that varies among states, so Medicaid beneficiaries represent a low-income population.

### Digestive disease definitions

Digestive disease morbidity was identified by International Classification of Diseases (ICD), Ninth Revision, Clinical Modification (ICD-9-CM) codes before October 1, 2015, or ICD, Tenth Revision, Clinical Modification (ICD-10-CM) codes from October 1, 2015 on, and digestive disease mortality by ICD, Tenth Revision (ICD-10) codes (Appendix 2).

### Statistical analysis

Methodology for tables and figures is described briefly below and in more detail in Appendix 1.

#### National databases

Estimates for the total population and by age, sex, and race-ethnicity were calculated for each year of national data. For calculating U.S. population rates, annual population data were derived from the national population estimates program of the U.S. Census Bureau and the CDC. For all rate calculations, population estimates used as the denominator were mid-year population counts by age, sex, and race-ethnicity. Rates were age-adjusted by direct standardization using the 2000 population estimates and 18 age groups (age 0–4, 5-year age groups through age 84, and age 85 and older) and are shown per 100,000 population.(20) NAMCS, NEDS, and NIS data were weighted to generate national estimates. “Years of Potential Life Lost to Age 75 Years” assumed life expectancy of 75 years had individuals not died before that age.

#### Claims databases

Enrollees were considered to have digestive disease if they had one or more claims with an ICD-9-CM or ICD-10-CM code indicative of digestive disease in any diagnostic field (i.e., all-listed diagnosis). The claims-based prevalence was calculated as the percentage of enrollees who qualified as having digestive disease each year. Estimates were reported overall and stratified by age, sex, race-ethnicity, and region.

Optum© CDM member files containing birth year, demographics, and eligibility period were linked to inpatient (acute care hospital or skilled nursing facility stay), medical (health care professional services), diagnosis, and pharmacy claims files. Hospital stays were defined as having an inpatient hospital place of service. Ambulatory visits were evaluation and management visits with an office, outpatient hospital, or ambulatory surgical center place of service.

The Medicare 5% sample study population consisted of beneficiaries who were 65 years or older and enrolled in fee-for-service Part A or Part B Medicare benefits or in Medicare Advantage. The study file contains demographic and enrollment data linked by the beneficiary unique identifier to institutional (hospital inpatient stays, hospital outpatient services, skilled nursing facilities, home health agencies and hospice care organizations) or non-institutional (health care professionals, supplies, and services) medical claims. Estimates from the 5% sample were multiplied by 20 to represent national estimates. The Medicaid study population consisted of beneficiaries who were 19 to 64 years of age and enrolled in Medicaid benefits. The study file contains demographic and enrollment data linked by the beneficiary unique identifier to institutional or non-institutional medical claims.

All analyses were conducted using SAS 9.4 (SAS Institute, Cary, NC). Trend figures were created using R 4.3.2 (R Foundation for Statistical Computing, Vienna, Austria).

## RESULTS

### Health care utilization - national data (Table 1, Figure 1A-1I)

#### Ambulatory care visits

There were an estimated 66 million ambulatory care visits with a first-listed digestive disease diagnosis and 126 million visits with an all-listed diagnosis in 2019. The ambulatory care visit rate (per 100,000) was 18,226 with a first-listed diagnosis and 34,585 with an all-listed diagnosis. This equates to 18 ambulatory care visits per 100 U.S. residents with a first-listed digestive disease diagnosis and 35 visits with an all-listed diagnosis. All-listed diagnosis rates were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among women compared with men, Whites compared with Blacks, and Hispanics compared with non-Hispanics. Between 2005 and 2019, the number of ambulatory care visits with a first-listed digestive disease diagnosis increased from an estimated 52 million to 66 million and the number of visits with an all-listed diagnosis increased from 80 million to 126 million. The age-adjusted ambulatory care visit rate (per 100,000) with a first-listed digestive disease diagnosis increased by 6% overall (17,130 to 18,226). All-listed diagnosis rates increased by 30% overall (26,594 to 34,585) and increased among age, sex, and race-ethnicity groups but not among younger adults and Blacks.

#### Emergency department visits

There were an estimated 17 million emergency department visits with a first-listed digestive disease diagnosis and 39 million visits with an all-listed diagnosis in 2022. The emergency department visit rate (per 100,000) was 5,182 with a first-listed diagnosis and 11,237 with an all-listed diagnosis. This equates to 5 emergency department visits per 100 U.S. residents with a first-listed digestive disease diagnosis and 11 visits with an all-listed diagnosis. All-listed diagnosis rates increased with age and age-adjusted rates were higher among women compared with men. Between 2006 and 2022, the number of emergency department visits with a first-listed digestive disease diagnosis increased from an estimated 15 million to 17 million and the number of visits with an all-listed diagnosis increased from 26 million to 39 million. The age-adjusted emergency department visit rate (per 100,000) with a first-listed digestive disease diagnosis increased from 4,862 in 2006 to 6,014 in 2015, decreased to 5,649 in 2019, further decreased in 2020, and rose to 5,182 in 2022. The all-listed diagnosis rate increased by 42% overall (8,597 to 12,180) between 2006 and 2019, decreased in 2020, was flat in 2021, and rose to 11,237 in 2022. Similar trends were observed among age and sex groups.

#### Hospital stays

There were an estimated 3.5 million hospital stays with a first-listed digestive disease diagnosis and 15 million stays with an all-listed diagnosis in 2022. The hospital stay rate (per 100,000) was 938 with a first-listed diagnosis and 4,051 with an all-listed diagnosis. This equates to 1 overnight hospital stay per 100 U.S. residents with a first-listed digestive disease diagnosis and 4 stays with an all-listed diagnosis. All-listed diagnosis rates were over twice as high among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among women compared with men. Rates were higher among Blacks and American Indians / Alaska Natives compared with Whites and were lower among Hispanics and Asians / Native Hawaiians / Pacific Islanders. Between 2006 and 2022, the number of hospital stays with a first-listed digestive disease diagnosis decreased from an estimated 4.5 million to 3.5 million while the number of stays with an all-listed diagnosis increased from 14 million to 15 million. The age-adjusted hospital stay rate (per 100,000) with a first-listed digestive disease diagnosis decreased by 37% overall (1,483 to 938). The all-listed diagnosis rate rose from 4,643 in 2006 to 5,221 in 2011, fell to 4,483 in 2016, stabilized through 2019, fell in 2020, and further declined to 4,051 in 2022. All-listed diagnosis rates declined between 2006 and 2022 among sex and race-ethnicity groups and older adults but not among younger and middle-aged adults.

### Mortality - national data (Table 1, Figure 1J-1L)

A digestive disease was the underlying cause of 318,000 deaths and an underlying or other cause of 527,000 deaths in 2023. The mortality rate (per 100,000) was 75 as underlying cause and 125 as underlying or other cause. Mortality rates as underlying or other cause were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among men compared with women. They were higher among American Indians / Alaska Natives and Blacks compared with Whites and were lower among Hispanics and Asians / Native Hawaiians / Pacific Islanders. There were 2.5 million years of potential life lost (YPLL) prior to age 75 years due to digestive diseases representing 8.0 years per death with a digestive disease as the underlying cause. Between 2006 and 2023, the number of deaths with a digestive disease as underlying cause increased from 243,000 to 318,000 and the number of deaths as underlying or other cause increased from 374,000 to 527,000. The age-adjusted mortality rate (per 100,000) with a digestive disease as underlying cause decreased by 8% overall (78 to 72) between 2006 and 2019, increased to 78 in 2021, and declined to 75 in 2023. The rate as underlying or other cause decreased from 120 in 2006 to 115 in 2009, was relatively stable through 2019, increased to 132 in 2021, and declined to 125 in 2023. A similar trend was observed among age, sex, and race-ethnicity groups with the highest rate and sharpest pandemic increase (40%) among American Indians / Alaska Natives.

### Claims-based prevalence – private insurance enrollees (Table 2, Figure 2A-2C)

In contrast to national data that represent events, Optum claims data are at the person level which enables calculation of claims-based prevalence. Among 21 million private insurance enrollees in 2023, 6.3 million had an all-listed digestive disease diagnosis for a claims-based prevalence of 24.7%. Prevalence with an all-listed diagnosis was higher among children compared with adolescents and the youngest adults and then increased with age until the oldest age group. Age-adjusted prevalence was higher among women compared with men. Prevalence was highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Between 2007 and 2023 age-adjusted prevalence of an all-listed digestive disease diagnosis rose by 28% overall (19.3% to 24.7%) despite a pandemic drop in 2020. A similar trend was observed among age, sex, and race-ethnicity groups.

### Health care utilization – private insurance enrollees (Table 2, Figure 2D-2M)

#### Ambulatory care visits

Among private insurance enrollees, there were 15 million ambulatory care visits with an all-listed digestive disease diagnosis in 2023. The ambulatory care visit rate (per 100,000) with an all-listed diagnosis was 55,746. All-listed diagnosis rates were higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among women compared with men. Rates were highest among Blacks, followed by Hispanics and Whites, and lowest among Asians. Between 2007 and 2023, age-adjusted ambulatory care visit rates (per 100,000) with an all-listed digestive disease diagnosis increased by 43% overall (38,966 to 55,746) despite a pandemic drop in 2020. A similar trend was observed among age, sex, and race-ethnicity groups.

#### Emergency department visits

Among private insurance enrollees, there were 915,000 emergency department visits with an all-listed digestive disease diagnosis in 2023. The emergency department visit rate (per 100,000) with an all-listed diagnosis was 2,786. All-listed diagnosis rates increased with age and age-adjusted rates were higher among women compared with men. Rates were highest among Blacks, followed by Hispanics and Whites, and lowest among Asians. Between 2007 and 2023, age-adjusted emergency department visit rates (per 100,000) with an all-listed digestive disease diagnosis increased by 91% overall (1,458 to 2,786) despite a pandemic drop in 2020. A similar trend was observed among age, sex, and race-ethnicity groups.

#### Hospital stays

Among private insurance enrollees, there were 1.1 million hospital stays with an all-listed digestive disease diagnosis in 2023. The hospital stay rate (per 100,000) with an all-listed diagnosis was 3,340. All-listed diagnosis rates were over three times higher among children compared with adolescents and the youngest adults and then increased with age. Age-adjusted rates were higher among women compared with men. Rates were highest among Blacks, followed by Whites and Hispanics, and lowest among Asians. Age-adjusted hospital stay rates (per 100,000) with an all-listed digestive disease diagnosis increased by 35% overall (2,764 to 3,724) between 2007 and 2019 and then decreased to 3340 in 2023. A generally similar trend was seen among age, sex, and race-ethnicity groups.

### Claims-based prevalence –Medicare beneficiaries (Table 3, Figure 3A-3B)

In contrast to national data that represent events, Medicare claims data are at the person level which enables calculation of claims-based prevalence. Among 59 million age-eligible Medicare beneficiaries in 2022, an estimated 31 million had an all-listed digestive disease diagnosis for a claims-based prevalence of 51.7%. Prevalence with an all-listed diagnosis increased with age, was higher among women compared with men, and was similar among Whites and Blacks. Between 2015 when Medicare Advantage data became available and 2022, prevalence with an all-listed digestive disease diagnosis rose by 9% overall (47.4% to 51.7%) despite a pandemic drop in 2020. A similar trend was observed among sex and race groups.

### Health care utilization - Medicare beneficiaries (Table 3, Figure 3C-3I)

#### Ambulatory care visits

Among age-eligible Medicare beneficiaries, there were an estimated 104 million ambulatory care visits with an all-listed digestive disease diagnosis in 2022. The ambulatory care visit rate (per 100,000) with an all-listed diagnosis was 176,983. All-listed diagnosis rates increased with age until 85 years and were higher among women compared with men and among Blacks compared with Whites. Between 2015 when Medicare Advantage data became available and 2022, ambulatory care visit rates (per 100,000) with an all-listed digestive disease diagnosis increased by 24% overall (142,210 to 176,983) despite a pandemic drop in 2020. A similar trend was observed among sex and race groups.

#### Emergency department visits

Among age-eligible Medicare beneficiaries, there were an estimated 14 million emergency department visits with an all-listed digestive disease diagnosis in 2022. The emergency department visit rate (per 100,000) with an all-listed diagnosis was 23,145. All-listed diagnosis rates increased with age and were higher among women compared with men and Blacks compared with Whites. Between 2015 when Medicare Advantage data became available and 2022, emergency department visit rates (per 100,000) with an all-listed digestive disease diagnosis increased from 22,483 in 2015 to 24,739 in 2019, decreased in 2020, and rose to 23,145 in 2022. A similar trend was observed among sex and race groups.

#### Hospital stays

Among age-eligible Medicare beneficiaries, there were an estimated 7.4 million hospital stays with an all-listed digestive disease diagnosis in 2022. The hospital stay rate (per 100,000) with an all-listed diagnosis was 12,557. All-listed diagnosis rates increased with age and were slightly higher among women compared with men and higher among Blacks compared with Whites. Between 2015 when Medicare Advantage data became available and 2022, hospital stay rates (per 100,000) with an all-listed digestive disease diagnosis increased slightly from 14,196 in 2015 to 14,494 in 2019, decreased in 2020, and remained stable at 12,557 in 2022. A similar trend was observed among sex and race groups.

### Mortality – Medicare beneficiaries (Figure 3J-3K)

Among age-eligible Medicare beneficiaries, a digestive disease was an underlying or other cause of an estimated 357,000 deaths in 2021. The mortality rate (per 100,000) as an underlying or other cause was 622. Mortality rates increased with age and were higher among men compared with women and among Blacks compared with Whites. Between 2015 when Medicare Advantage data became available and 2021, mortality rates (per 100,000) with a digestive disease as underlying or other cause were stable between 2015 and 2019, increased in 2020, and remained stable at 622 in 2021. A similar trend was observed among sex and race groups.

### Claims-based prevalence – Medicaid beneficiaries (Table 4, Figure 4A-4C)

In contrast to national data that represent events, Medicaid claims data are at the person level which enables calculation of claims-based prevalence. Among 49 million Medicaid beneficiaries aged 19 to 64 years in 2022, 12 million had an all-listed digestive disease diagnosis for a claims-based prevalence of 25.0%. Prevalence with an all-listed diagnosis increased with age and age-adjusted prevalence was higher among women compared with men. Prevalence was highest among American Indians / Alaska Natives, followed by Whites and Hispanics, Blacks, Hawaiians / Pacific Islanders, and lowest among Asians. Age-adjusted prevalence of an all-listed digestive disease diagnosis was relatively stable between 2017 and 2019, decreased in 2020, and remained stable at 25.0% in 2022. A generally similar trend was seen among age, sex, and race-ethnicity groups.

### Health care utilization - Medicaid beneficiaries (Table 4, Figure 4D-4M)

#### Ambulatory care visits

Among Medicaid beneficiaries aged 19 to 64 years, there were 19 million ambulatory care visits with an all-listed digestive disease diagnosis in 2022. The ambulatory care visit rate (per 100,000) with an all-listed diagnosis was 41,626. All-listed diagnosis rates increased with age and age-adjusted rates were higher among women compared with men. Rates were highest among Asians, followed by Hispanics, Whites, Hawaiians / Pacific Islanders, American Indians / Alaska Natives, and lowest among Blacks. Age-adjusted ambulatory care visit rates (per 100,000) with an all-listed digestive disease diagnosis were stable between 2017 and 2019 and decreased from 50,578 in 2019 to 41,626 in 2022. A similar trend was observed among age, sex, and race-ethnicity groups.

#### Emergency department visits

Among Medicaid beneficiaries aged 19 to 64 years, there were 6.2 million emergency department visits with an all-listed digestive disease diagnosis in 2022. The emergency department visit rate (per 100,000) with an all-listed diagnosis was 12,703. All-listed diagnosis rates were lowest among persons aged 55 to 64 years. Age-adjusted rates were higher among women compared with men. Rates were highest among Blacks, followed by American Indians / Alaska Natives, Whites, Hispanics, Hawaiians / Pacific Islanders, and lowest among Asians. Age-adjusted emergency department visit rates (per 100,000) with an all-listed digestive disease diagnosis were relatively stable between 2017 and 2019 and decreased from 15,564 in 2019 to 12,703 in 2022. A similar trend was observed among age, sex, and race-ethnicity groups.

#### Hospital stays

Among Medicaid beneficiaries aged 19 to 64 years, there were 2.1 million hospital stays with an all-listed digestive disease diagnosis in 2022. The hospital stay rate (per 100,000) with an all-listed diagnosis was 4,675. All-listed diagnosis rates increased with age and age-adjusted rates were higher among men compared with women. Rates were highest among American Indians / Alaska Natives, followed by Blacks, Whites, Hispanics, Hawaiians / Pacific Islanders, and lowest among Asians. Age-adjusted hospital stay rates (per 100,000) with an all-listed digestive disease diagnosis were relatively stable between 2017 and 2019 and decreased from 6,002 in 2019 to 4,675 in 2022. A similar trend was observed among age, sex, and race-ethnicity groups.

### Summary of burden of selected digestive diseases (Table 5)

Summary data for individual digestive diseases are shown in Table 5, ordered by underlying or other cause of death (i.e., all-listed cause of death). Number of deaths (2023), hospital stays (2022), emergency department visits (2022), and ambulatory care visits (2-year average, 2018-2019) are shown. The burden of selected digestive diseases will be described separately in subsequent chapters.

## DISCUSSION

We expanded on earlier findings and investigated current trends in the digestive disease burden over the past two decades in the U.S. using national survey and claims databases.(11) We found that the digestive disease burden in the U.S. is substantial and increasing. Digestive diseases contribute significantly to mortality. Among 3,090,964 total deaths in 2023, digestive diseases accounted for 317,510 (10%) as underlying cause and contributed to 527,368 (17%) as underlying or other cause.(21) Chronic liver disease and cirrhosis was the 9th or 10th leading cause of death in 2021 through 2023, and colorectal and pancreatic cancers are the second and third leading causes of cancer deaths, respectively, in 2024.(13,21-23) A decrease, in digestive disease mortality has been documented since at least 1950.(4) With a digestive disease as underlying or other cause, the gradual decline in the age-adjusted mortality rate between 1979 and 2004 continued through 2009, after which the rate was relatively stable through 2019.(3) In 2020, the year of the COVID-19 pandemic, the mortality rate increased and continued to rise in 2021 and then declined through 2023. With a digestive disease as underlying cause, the gradual decline in the mortality rate between 1979 and 2004 continued through 2019 and the rate then rose in 2020 and 2021 and then declined through 2023.(3) A similar trend beginning in 2020 was seen among both sexes and all race-ethnicity groups. Whether mortality rates decline to pre-pandemic levels will become clearer when additional years of data are available. Similar to overall mortality, age-adjusted digestive disease mortality rates were higher among men compared with women.(21) Like overall mortality, digestive disease mortality rates were much higher among American Indians / Alaska Natives compared with other race-ethnicity groups, higher among Blacks compared with Whites, lower among Hispanics, and lowest among Asians.(21)

Among claims data sources used, overall prevalence of an all-listed digestive disease diagnosis was similar among private insurance enrollees (24.7%) and Medicaid beneficiaries (25.0%) and twice as high among Medicare beneficiaries (51.7%). Medicare data used were restricted to age-eligible beneficiaries 65 years and over who would be expected to have the highest prevalence of most digestive diseases due to age-related changes to the digestive system.(24). Commercial insurance enrollees included persons of all ages, while Medicaid beneficiaries were limited to persons 19 to 64 years. When comparison was limited to middle-aged persons (45-54 and 55-64 years), claims-based prevalence was higher among private insurance enrollees. When medical care use rates were compared, ambulatory care visit rates were also higher among private insurance enrollees, while Medicaid beneficiaries had higher hospital stay rates and 2 to 4 times higher emergency department visit rates. Private insurance enrollees are primarily employed persons who receive health insurance through their employer and represent a higher income group compared with Medicaid enrollees for whom eligibility is based on income below a certain level that varies among states. Although higher income privately insured persons might be expected to have a lower prevalence of most digestive diseases, they also might be expected to have greater access to health care compared with Medicaid beneficiaries which could have contributed to differences in prevalence and medical care use among these two populations.

The prevalence of digestive disease has increased based on claims diagnoses among private insurance and Medicare enrollees. Among Medicaid enrollees, prevalence has decreased, though data are limited to the last 5 years. Because claims-based prevalence is based on health care use, changes in prevalence may reflect variation in both disease frequency and health care use. Prevalence was higher in women among all three groups. Taken together across groups, prevalence was highest among American Indians / Alaska Natives and lowest among Hawaiians / Pacific Islanders and Asians.

Digestive diseases contribute significantly to health care use in the U.S. With regard to national hospitalization rates, after falling between 1983 and 1988, stabilizing over a decade, and rising between 1998 and 2004 to equal the previous 1982 peak, age-adjusted rates continued to rise through 2011, fell through 2016, stabilized through 2019, and declined during the COVID-19 pandemic.(3) With regard to national ambulatory care visit rates, the trend in increasing rates that started at least as early as 1985 continued through 2019.(3,4) National emergency department visit rates increased across the study period (2006 through 2022) despite a drop in 2020. In contrast to mortality rates that were higher among men, digestive disease health care use rates were higher among women, with the exception of higher Medicaid hospitalization rates among men. Compared with Whites, Blacks had higher emergency department visit and hospital stay rates while ambulatory care visit rates were inconsistent. American Indians / Alaska Natives had higher emergency department visit and hospital stay rates, but not ambulatory care visit rates compared with Whites. Hispanics had higher ambulatory care visit rates and lower hospital stay rates compared with Whites. Asians and Native Hawaiians / Pacific Islanders had lower medical care use rates compared with whites, except that among Medicaid beneficiaries, Asians had the highest ambulatory care visit rates among race-ethnicity groups. These differences may reflect variation in digestive disease prevalence and / or access to or likelihood to seek heath care.(25)

The data used in this report have limitations. For national data sources, ambulatory care and emergency department numbers and rates represent visits, not persons with a visit. Hospital numbers and rates represent stays, not persons with a hospital stay. National health care data do not include care in federal facilities and the NEDS sample includes only hospital-owned emergency departments; therefore, rates based on the U.S. population are underestimates. The NAMCS sample is limited to office-based providers, a group that has become a less inclusive source for ambulatory care and samples are small, so estimates are less statistically reliable. HCUP data sources do not include all states and not all participating states collect data on race-ethnicity. Mortality data are dependent on the accuracy of death certificate diagnoses. This may vary by condition and chronic diseases that contribute to mortality are frequently underreported.

The limitations are offset by the following strengths. NAMCS data were obtained from provider records. HCUP data sources are the largest all-payer emergency department and inpatient databases in the U.S. National health care and Medicare data were weighted to provide national estimates, and mortality data include all deaths occurring in the U.S. CDM, Medicare, and Medicaid data are at the person-level so claims-based prevalence can be calculated. Medicare covers approximately 96 percent of all U.S. citizens aged 65 years and over permitting generalization to the U.S. older adult population.(26) NIS, Vital Statistics of the U.S., and Medicaid include information on Asians / Hawaiians / Pacific Islanders and American Indians / Alaska Natives, and CDM includes information on Asians, groups for which data are less commonly available.

The COVID-19 pandemic affected digestive disease healthcare utilization and mortality. Between 2019 and 2020, there were generally decreases in digestive disease medical care use rates and increases in digestive disease mortality rates. Since 2020, medical care use rates have generally increased, but not among Medicaid enrollees. The overall mortality rate continued to rise between 2020 and 2021 and then declined through 2023. Whether these changes represent only temporary fluctuations will become clearer when additional years of data are available.

## CONCLUSION

The digestive disease burden in the U.S. is substantial. Although the digestive disease mortality rate gradually declined over the past four decades before rising since the COVID-19 pandemic, digestive diseases remain a significant cause of mortality with chronic liver disease and cirrhosis among the top nine leading causes of death. Medical care devoted to digestive diseases is also significant. Ambulatory care and emergency department visit rates with a digestive disease diagnosis are increasing, and hospital stay rates increased among persons with private insurance. Significant group differences exist with a disproportionately high digestive disease burden among Blacks, American Indians / Alaska Natives, older adults, and lower income Medicaid beneficiaries. Further research is needed to better understand reasons for group differences and trends in health care use and mortality.(8) Public health measures are informed by continuous surveillance and descriptive epidemiology such as this Burden of Digestive Diseases in the United States report to address the substantial and increasing digestive disease burden.

## ACKNOWLEDGMENTS

The authors thank Helen Corns, MPH and Ying Li, PhD for statistical analysis and Helen Corns, MPH, for table and figure creation.

## REFERENCES

1 Opportunities and challenges in digestive diseases research: recommendations of the National Commission on Digestive Diseases. US Department of Health and Human Services, National Institutes of Health. NIH Publication No. 08-6514, Mar. 2009. Available at: https://www.niddk.nih.gov/about-niddk/strategic-plans-reports/opportunities-challenges-digestive-diseases-research-recommendations-national-commission. Accessed November 2025.
2 Everhart JE, ed. The burden of digestive diseases in the United States. US Department of Health and Human Services, Public Health Service, National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases. Washington, DC: US Government Printing Office, 2008; NIH Publication No. 09-6443. Available at: https://www.niddk.nih.gov/about-niddk/strategic-plans-reports/burden-of-digestive-diseases-in-united-states. Accessed November 2025.
3 Everhart JE, Ruhl CE. Burden of digestive diseases in the United States part I: Overall and upper gastrointestinal diseases. Gastroenterology 2009;136:376-386.19124023
4 Everhart JE. Overview. In: Everhart JE, ed. Digestive Diseases in the United States: Epidemiology and Impact. US Department of Health and Human Services, Public Health Service, National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases. Washington, DC: US Government Printing Office, 1994; NIH publication no. 94-1447 pp.1–50.
5 Aldhaleei WA, Wallace MB, Bi Y, et al. Racial, Ethnic, and Geographic Disparities in Digestive Diseases Mortality in the United States, 2000-2019. Clin Gastroenterol Hepatol. 2024 Aug 28:S1542-3565(24)00768-7.
6 Unalp-Arida A, Ruhl CE. Burden of Digestive Diseases in the United States Population: Rates and Trends. Am J Gastroenterol. 2024 Dec 31;120(9):1987-1997.39588980
7 Gastroenterology. 2025 May;168(5):1000-1024.39920892
8 National Institute of Diabetes and Digestive and Kidney Diseases. NIDDK Strategic Plan for Research. Pathways to health for all. Dec. 2021. Updated April 2025. Available at: https://www.niddk.nih.gov/about-niddk/strategic-plans-reports/niddk-strategic-plan-for-research. Accessed November 2025.
9 Everhart JE, Ruhl CE. Burden of digestive diseases in the United States part II: Lower gastrointestinal diseases. Gastroenterology 2009;136:741-754.19166855
10 Everhart JE, Ruhl CE. Burden of digestive diseases in the United States Part III: Liver, biliary tract, and pancreas. Gastroenterology 2009;136:1134-1144.19245868
11 Unalp-Arida A, Ruhl CE. The burden of digestive diseases in the United States population. medRxiv [Preprint]. 2023 Aug 21:2023.08.16.23294166. doi: .10.1101/2023.08.16.23294166
12 Unalp-Arida A, Ruhl CE. Burden of gallstone disease in the United States population: Prepandemic rates and trends. World J Gastrointest Surg. 2024 Apr 27;16(4):1130-1148.38690054
13 Unalp-Arida A, Ruhl CE. Clin Gastroenterol Hepatol. 2025 Sep;23(10):1679-1692.40147498
14 Centers for Disease Control and Prevention, National Center for Health Statistics. Available from: https://www.cdc.gov/nchs/namcs/about/index.html. Accessed November 2025.
15 Agency for Healthcare Research and Quality. Available from: https://hcup-us.ahrq.gov/nedsoverview.jsp. Accessed November 2025.
16 Agency for Healthcare Research and Quality. Available from: https://hcup-us.ahrq.gov/nisoverview.jsp. Accessed November 2025.
17 National Bureau of Economic Research. Mortality Data - Vital Statistics NCHS Multiple Cause of Death Data. Available from: https://www.nber.org/research/data/mortality-data-vital-statistics-nchs-multiple-cause-death-data. Accessed November 2025.
18 OPTUM^®^. Clinformatics® Data Mart Database. Available from: https://www.optum.com/content/dam/optum/resources/productSheets/Clinformatics_for_Data_Mart.pdf. Accessed November 2025.
19 Chronic Conditions Data Warehouse. Centers for Medicare & Medicaid Services. Available from: https://www2.ccwdata.org/web/guest/home/. Accessed November 2025.
20 Anderson RN, Rosenberg HM. Age standardization of death rates: implementation of the year 2000 standard. Natl Vital Stat Rep 1998; 47: 1-16, 20. Available from: https://www.cdc.gov/nchs/data/nvsr/nvsr47/nvs47_03.pdf. Accessed November 2025.9796247
21 Murphy SL, Kochanek KD, Xu JQ, Arias E. Mortality in the United States, 2023. NCHS Data Brief, no 521. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: . Accessed November 2025.10.15620/cdc/170564
22 Murphy SL, Kochanek KD, Xu JQ, Arias E. Deaths: Final data for 2021. National Vital Statistics Reports; vol 73 no 8. Hyattsville, MD: National Center for Health Statistics. 2024. DOI: . Accessed November 2025.10.15620/cdc/158787
23 National Cancer Institute (NCI). Cancer Stat Facts: Common Cancer Sites. Available at: https://seer.cancer.gov/statfacts/html/common.html#:~:text=Breast%2C%20lung%20and%20bronchus%2C%20prostate,nearly%2050%25%20of%20all%20death (https://seer.cancer.gov/statfacts/html/common.html%23:~:text=Breast%2C%20lung%20and%20bronchus%2C%20prostate,nearly%2050%25%20of%20all%20death). Accessed November 2025.
24 Dumic I, Nordin T, Jecmenica M, et al. Gastrointestinal tract disorders in older age. Can J Gastroenterol Hepatol. 2019 Jan 17;2019:6757524. eCollection 2019.PMID: 30792972.
25 Brett KM, Burt CW. Utilization of ambulatory medical care by women: United States, 1997-98. Vital Health Stat 13 2001 Jul:(149):1-46.11478128
26 Research Data Assistance Center (ResDAC). Getting Started with CMS Data. 2022. Available from: https://www.resdac.org/getting-started-cms-data#who-is-in-the-data (https://www.resdac.org/getting-started-cms-data%23who-is-in-the-data). Accessed November 2025.

Figure 1.

Age-adjusted rates with all-listed digestive disease diagnoses in the United States (Source: National Ambulatory Medical Care Survey, 2005-2019 (averages, 2005-2007, 2008-2010, 2011-2013, 2014-2016, 2018-2019); Healthcare Cost and Utilization Project (HCUP) Nationwide Emergency Department Sample, 2006-2022; HCUP National Inpatient Sample, 2006-2022; and Vital Statistics of the U.S.: Multiple Cause-of-Death Data, 2006-2023)

A: Total visits

B: Ambulatory care visits by sex

C: Ambulatory care visits by race-ethnicity

D: Ambulatory care visits by age

E: Emergency department visits by sex

F: Emergency department visits by age

G: Hospital stays by sex

H: Hospital stays by age

I: Hospital stays by race-ethnicity

J: Mortality by sex

K: Mortality by race-ethnicity

L: Mortality by age

Figure 2.

Age-adjusted rates with all-listed digestive disease diagnoses among persons with private insurance in the United States, 2007-2023 (Source: Optum Clinformatics® Data Mart)

A: Claims-based prevalence by sex

B: Claims-based prevalence by race-ethnicity

C: Claims-based prevalence by age

D: Total visits

E: Ambulatory care visits by sex

F: Ambulatory care visits by race-ethnicity

G: Ambulatory care visits by age

H: Emergency department visits by sex

I: Emergency department visits by race-ethnicity

J: Emergency department visits by age

K: Hospital stays by sex

L: Hospital stays by race-ethnicity

M: Hospital stays by age

Figure 3.

Rates with all-listed digestive disease diagnoses among age-eligible fee-for-service and Advantage Medicare beneficiaries in the United States, 2006-2022 (Source: Medicare 5% file)

A: Claims-based prevalence by sex

B: Claims-based prevalence by race

C: Total visits

D: Ambulatory care visits by sex

E: Ambulatory care visits by race

F: Emergency department visits by sex

G: Emergency department visits by race

H: Hospital stays by sex

I: Hospital stays by race

J: Mortality by sex

K: Mortality by race

Figure 4.

Age-adjusted rates with all-listed digestive disease diagnoses among 19- to 64-year-old Medicaid beneficiaries in the United States, 2017-2022 (Source: Medicaid file)

A: Claims-based prevalence by sex

B: Claims-based prevalence by race-ethnicity

C: Claims-based prevalence by age

D: Total visits

E: Ambulatory care visits by sex

F: Ambulatory care visits by race-ethnicity

G: Ambulatory care visits by age

H: Emergency department visits by sex

I: Emergency department visits by race-ethnicity

J: Emergency department visits by age

K: Hospital stays by sex

L: Hospital stays by race-ethnicity

M: Hospital stays by age

Table 1.

Number and age-adjusted rates of ambulatory care visits, emergency department visits, hospital stays, and deaths with all digestive diseases (all-listed diagnoses) by age, race-ethnicity and sex in the United States

Demographic characteristics | Ambulatory care visits (2018-2019) | | Emergency department visits (2022) | | Hospital stays (2022) | | Mortality (2023)
Demographic characteristics | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000 | Number in thousands | Rate per 100,000 | Number of deaths | Rate per 100,000
Age (years)
0 to 11 | 8,999 | 18,595 | 3,556 | 7,547 | 1,090 | 2,313 | 2,144 | 4.6
12 to 24 | 6,215 | 11,205 | 4,289 | 7,599 | 503 | 892 | 1,322 | 2.3
25 to 44 | 16,172 | 18,594 | 9,397 | 10,510 | 2,139 | 2,392 | 21,824 | 24.3
45 to 54 | 19,796 | 47,551 | 4,628 | 11,421 | 1,569 | 3,871 | 36,658 | 90.5
55 to 64 | 30,308 | 71,698 | 5,582 | 13,194 | 2,609 | 6,166 | 88,831 | 212.2
65 to 74 | 22,136 | 72,595 | 5,438 | 15,994 | 3,227 | 9,492 | 137,457 | 396.3
75 + | 22,122 | 100,836 | 6,549 | 27,902 | 4,205 | 17,915 | 239,123 | 973.5
Race-ethnicity
White | 106,583 | 36,312 | * | * | 10,339 | 4,065 | 390,414 | 128.9
Black | 10,868 | 23,981 | * | * | 2,227 | 5,224 | 58,519 | 135.5
Hispanic | * | * | * | * | 1,895 | 3,518 | 52,507 | 110.5
Asian/Native Hawaiian/Pacific Islander | * | * | * | * | 434 | 2,055 | 18,099 | 78.3
American Indian/Alaska Native | * | * | * | * | 112 | 4,558 | 4,981 | 190.7
Two or more races/Other | 8,298 | 33,018 | * | * | 454 | 8,889 | 2,839 | 62.7
Hispanic origin
Hispanic | 19,487 | 40,066 | * | * | * | * | * | *
Not Hispanic | 106,262 | 34,236 | * | * | * | * | * | *
Sex
Female | 72,235 | 38,185 | 22,977 | 12,878 | 8,205 | 4,150 | 244,784 | 105.1
Male | 53,514 | 31,012 | 16,459 | 9,616 | 7,135 | 3,974 | 282,575 | 147.4
Total | 125,749 | 34,585 | 39,439 | 11,237 | 15,341 | 4,051 | 527,359 | 124.5

Source: National Ambulatory Medical Care Survey (2-year average, 2018-2019), Healthcare Cost and Utilization Project Nationwide Emergency Department Sample and National Inpatient Sample, and Vital Statistics of the United States.

* Data not available.

Table 2.

Number and age-adjusted rates of claims-based prevalence, ambulatory care visits, emergency department visits, and hospital stays with all digestive diseases (all-listed diagnoses) by age, race-ethnicity, sex and region among persons with private insurance in the United States, 2023

Demographic characteristics | Number of enrollees | No. of enrollees with disease | Claims-based prevalence (%) | Ambulatory care visits | | Emergency department visits | | Hospital stays
Demographic characteristics | Number of enrollees | No. of enrollees with disease | Claims-based prevalence (%) | Number | Rate per 100,000 | Number | Rate per 100,000 | Number | Rate per 100,000
Age (years)
0 to 11 | 1,562,858 | 272,614 | 17.44 | 441,715 | 28,263 | 5,447 | 349 | 25,691 | 1,644
12 to 24 | 2,113,969 | 235,101 | 11.12 | 413,072 | 19,540 | 11,340 | 536 | 10,877 | 515
25 to 44 | 4,646,733 | 745,915 | 16.05 | 1,488,518 | 32,034 | 65,979 | 1,420 | 58,331 | 1,255
45 to 54 | 2,143,408 | 733,174 | 34.21 | 1,577,976 | 73,620 | 57,284 | 2,673 | 61,287 | 2,859
55 to 64 | 2,302,599 | 879,950 | 38.22 | 2,156,010 | 93,634 | 109,053 | 4,736 | 133,403 | 5,794
65 to 74 | 4,507,860 | 1,873,318 | 41.56 | 4,843,325 | 107,442 | 305,327 | 6,773 | 334,386 | 7,418
75+ | 3,766,190 | 1,536,169 | 40.79 | 4,440,859 | 117,914 | 360,582 | 9,574 | 467,902 | 12,424
Race-ethnicity
White | 11,840,647 | 3,927,209 | 25.51 | 9,757,760 | 57,438 | 566,935 | 2,620 | 704,327 | 3,179
Black | 1,748,532 | 607,607 | 26.16 | 1,616,294 | 62,882 | 125,070 | 4,217 | 139,659 | 4,653
Hispanic | 1,779,548 | 535,456 | 25.09 | 1,366,122 | 60,278 | 80,038 | 2,679 | 80,161 | 2,960
Asian | 729,247 | 191,185 | 22.59 | 435,746 | 47,553 | 15,441 | 1,362 | 18,404 | 1,687
Unknown | 4,945,643 | 1,014,784 | 21.19 | 2,185,553 | 46,858 | 127,528 | 2,914 | 149,326 | 3,148
Sex
Female | 10,939,521 | 3,596,240 | 27.21 | 9,044,696 | 62,548 | 559,738 | 3,255 | 605,359 | 3,460
Male | 10,104,096 | 2,680,001 | 22.20 | 6,316,779 | 48,752 | 355,274 | 2,301 | 486,518 | 3,235
Region
Northeast | 2,287,084 | 765,032 | 26.50 | 1,936,901 | 60,447 | 112,081 | 2,780 | 143,144 | 3,549
Midwest | 5,103,978 | 1,440,549 | 24.20 | 3,271,033 | 51,704 | 198,763 | 2,720 | 250,881 | 3,377
South | 9,053,850 | 2,891,692 | 26.18 | 7,372,724 | 61,409 | 444,218 | 3,165 | 531,583 | 3,830
West | 4,598,705 | 1,178,968 | 21.66 | 2,780,817 | 47,115 | 159,950 | 2,132 | 166,269 | 2,322
Total | 21,043,617 | 6,276,241 | 24.71 | 15,361,475 | 55,746 | 915,012 | 2,786 | 1,091,877 | 3,340

Source: Optum ClinformaticsⓇ Data Mart.

-- Indicates cells too small to present.

Table 3.

Number and rates of claims-based prevalence, ambulatory care visits, emergency department visits, and hospital stays with all digestive diseases (all-listed diagnoses) by age, race, sex and region among Medicare beneficiaries in the United States, 2022

Demographic characteristics | Number of enrollees | No. of enrollees with disease | Claims-based prevalence (%) | Ambulatory care visits | | Emergency department visits | | Hospital stays
Demographic characteristics | Number of enrollees | No. of enrollees with disease | Claims-based prevalence (%) | Number | Rate per 100,000 | Number | Rate per 100,000 | Number | Rate per 100,000
Age (years)
65 to 69 | 21,521,420 | 9,720,000 | 45.16 | 31,455,020 | 146,157 | 3,377,300 | 15,693 | 1,714,020 | 7,964
70 to 74 | 14,907,280 | 8,032,980 | 53.89 | 27,321,980 | 183,279 | 2,970,600 | 19,927 | 1,614,380 | 10,829
75 to 79 | 10,230,700 | 5,716,380 | 55.87 | 20,375,040 | 199,156 | 2,670,680 | 26,105 | 1,479,420 | 14,461
80 to 84 | 6,329,060 | 3,615,060 | 57.12 | 13,116,660 | 207,245 | 2,129,300 | 33,643 | 1,185,320 | 18,728
85+ | 5,987,760 | 3,430,180 | 57.29 | 12,109,020 | 202,230 | 2,502,160 | 41,788 | 1,412,340 | 23,587
Race
White | 44,090,080 | 22,938,660 | 52.03 | 77,478,140 | 175,727 | 10,141,080 | 23,001 | 5,673,320 | 12,868
Black | 5,539,400 | 2,905,620 | 52.45 | 10,614,140 | 191,612 | 1,696,640 | 30,629 | 828,540 | 14,957
Other | 9,346,740 | 4,670,320 | 49.97 | 16,285,440 | 174,237 | 1,812,320 | 19,390 | 903,620 | 9,668
Sex
Female | 32,350,540 | 17,729,100 | 54.80 | 62,345,680 | 192,719 | 8,005,680 | 24,747 | 4,102,160 | 12,680
Male | 26,625,680 | 12,785,500 | 48.02 | 42,032,040 | 157,863 | 5,644,360 | 21,199 | 3,303,320 | 12,407
Region
Northeast | 10,614,360 | 5,540,460 | 52.20 | 19,812,940 | 186,662 | 2,524,940 | 23,788 | 1,398,380 | 13,174
Midwest | 12,701,620 | 6,447,880 | 50.76 | 21,085,040 | 166,003 | 2,987,980 | 23,524 | 1,684,320 | 13,261
South | 22,335,320 | 12,157,140 | 54.43 | 43,129,080 | 193,098 | 5,530,900 | 24,763 | 3,012,480 | 13,488
West | 13,324,920 | 6,369,120 | 47.80 | 20,350,660 | 152,726 | 2,606,220 | 19,559 | 1,310,300 | 9,833
Total | 58,976,220 | 30,514,600 | 51.74 | 104,377,720 | 176,983 | 13,650,040 | 23,145 | 7,405,480 | 12,557

Source: CMS Medicare 5% file.

-- Indicates cells too small to present.

Table 4.

Number and age-adjusted rates of claims-based prevalence, ambulatory care visits, emergency department visits, and hospital stays with all digestive diseases (all-listed diagnoses) by age, race-ethnicity, sex and region among Medicaid beneficiaries in the United States, 2022

Demographic characteristics | Number of enrollees | No. of enrollees with disease | Claims-based prevalence (%) | Ambulatory care visits | | Emergency department visits | | Hospital stays
Demographic characteristics | Number of enrollees | No. of enrollees with disease | Claims-based prevalence (%) | Number | Rate per 100,000 | Number | Rate per 100,000 | Number | Rate per 100,000
Age (years)
19 to 34 | 22,476,820 | 4,445,777 | 19.78 | 5,544,766 | 24,669 | 2,868,697 | 12,763 | 559,113 | 2,488
35 to 44 | 10,425,540 | 2,359,077 | 22.63 | 3,843,317 | 36,864 | 1,366,404 | 13,106 | 422,227 | 4,050
45 to 54 | 7,672,094 | 2,254,596 | 29.39 | 4,232,770 | 55,171 | 1,014,856 | 13,228 | 454,407 | 5,923
55 to 64 | 8,210,583 | 2,597,151 | 31.63 | 5,049,488 | 61,500 | 961,943 | 11,716 | 633,806 | 7,719
Race-ethnicity
White | 19,855,693 | 4,995,257 | 25.81 | 8,480,783 | 44,757 | 2,631,894 | 13,229 | 924,661 | 4,982
Black | 9,222,994 | 2,131,689 | 24.30 | 2,748,611 | 33,274 | 1,359,782 | 14,573 | 406,836 | 4,993
Hispanic | 9,725,791 | 2,318,104 | 25.85 | 3,702,038 | 44,810 | 1,261,764 | 13,044 | 374,954 | 4,491
Asian | 2,118,132 | 472,846 | 23.07 | 971,694 | 48,007 | 110,847 | 5,260 | 41,664 | 2,028
American Indian/Alaska Native | 703,598 | 178,079 | 26.47 | 230,422 | 36,211 | 101,220 | 14,521 | 43,166 | 6,771
Hawaiian/Pacific Islander | 386,994 | 87,295 | 23.67 | 151,958 | 42,599 | 37,600 | 9,755 | 10,511 | 2,901
Multiracial/Other/Unknown | 6,771,835 | 1,473,331 | 24.33 | 2,384,835 | 40,757 | 708,793 | 11,278 | 267,761 | 4,601
Sex
Female | 28,357,681 | 7,636,808 | 28.08 | 12,178,163 | 47,296 | 4,188,971 | 14,422 | 1,152,448 | 4,487
Male | 20,427,356 | 4,019,793 | 20.62 | 6,492,178 | 34,029 | 2,022,929 | 10,170 | 917,105 | 4,862
Region
Northeast | 10,425,435 | 2,688,003 | 26.74 | 4,216,541 | 42,979 | 1,040,214 | 9,977 | 488,440 | 5,017
Midwest | 9,842,985 | 2,551,039 | 26.80 | 4,218,091 | 45,780 | 1,485,139 | 14,957 | 420,472 | 4,675
South | 14,420,919 | 3,282,711 | 23.79 | 4,964,909 | 38,217 | 2,010,517 | 13,856 | 637,944 | 5,051
West | 14,095,698 | 3,134,848 | 23.41 | 5,270,800 | 40,987 | 1,676,030 | 11,995 | 522,697 | 4,048
Total | 48,785,037 | 11,656,601 | 24.96 | 18,670,341 | 41,626 | 6,211,900 | 12,703 | 2,069,553 | 4,675

Source: CMS Medicaid.

-- Indicates cells too small to present.

Table 5.

Burden of selected digestive diseases (all-listed diagnoses) in the United States

Digestive disease | Deaths (2023) | | Hospital stays (2022) | Emergency department visits (2022) | Ambulatory care visits (2018-2019)
All digestive diseases | 527,359 | 15,341,000 | | 39,439,000 | 125,749,000
All digestive cancers | 220,274 | 849,000 | | 847,000 | 5,156,000
Colorectal cancer | 62,798 | 251,000 | | 219,000 | 1,782,000
Pancreatic cancer | 52,689 | 116,000 | | 132,000 | 820,000
Primary liver cancer | 23,614 | 65,000 | | 76,000 | 570,000
Esophageal cancer | 17,896 | 43,000 | | 50,000 | 811,000
Bile duct cancer | 13,232 | 38,000 | | 37,000 | --
Gastric cancer | 12,175 | 42,000 | | 46,000 | 560,000
Gallbladder cancer | 2,385 | 8,000 | | 7,000 | --
Cancer of the small intestine | 2,310 | 11,000 | | 9,000 | 9,000
Liver disease (acute and chronic) | 126,065 | 2,009,000 | | 2,747,000 | 5,618,000
All viral hepatitis | 13,388 | 465,000 | | 586,000 | 1,433,000
Hepatitis C | 11,273 | 383,000 | | 492,000 | 862,000
Hepatitis B | 1,785 | 67,000 | | 74,000 | 402,000
Hepatitis A | 85 | 9,000 | | 10,000 | --
Gastroesophageal reflux disease | 14,562 | 5,237,000 | | 8,388,000 | 31,061,000
Peptic ulcer disease | 8,282 | 405,000 | | 444,000 | 127,000
Pancreatitis | 8,123 | 528,000 | | 735,000 | 725,000
Acute | 6,492 | 413,000 | | 560,000 | 375,000
Chronic | 1,800 | 185,000 | | 251,000 | 351,000
Clostridium difficile | 7,339 | 216,000 | | 223,000 | 479,000
Gastrointestinal infections (excluding Clostridium difficile) | 6,356 | 230,000 | | 652,000 | 442,000
Diverticular disease | 5,766 | 839,000 | | 1,533,000 | 3,618,000
All functional intestinal disorders | 5,432 | 2,563,000 | | 4,554,000 | 13,938,000
Chronic constipation | 1,561 | 1,858,000 | | 3,435,000 | 8,425,000
Irritable bowel syndrome | 558 | 261,000 | | 486,000 | 4,323,000
All inflammatory bowel disease | 4,537 | 322,000 | | 522,000 | 2,970,000
Crohn’s disease | 2,702 | 192,000 | | 344,000 | 801,000
Ulcerative colitis | 1,852 | 131,000 | | 179,000 | 2,169,000
Abdominal wall hernia | 3,115 | 449,000 | | 819,000 | 5,240,000
Gallstones | 2,059 | 639,000 | | 1,257,000 | 1,131,000
Appendicitis | 849 | 175,000 | | 436,000 | 509,000
Celiac disease | 336 | 41,000 | | 67,000 | 817,000
Hemorrhoids | 112 | 344,000 | | 600,000 | 2,178,000

Source: Vital Statistics of the United States, Healthcare Cost and Utilization Project (HCUP) National Inpatient Sample, HCUP Nationwide Emergency Department Sample, and National Ambulatory Medical Care Survey (2-year average, 2018-2019).