# Acknowledgments

The authors thank Bryan Sayer, Helen Corns, Laura Fang, Ying Li, and Joe Evans for statistical programming.

Financial Support: The work was supported by contracts from the National Institute of Diabetes and Digestive and Kidney Diseases (HHSN275201700074U and 75N94022F00050).