# Appendix 1. Data Sources and Methodology for Tables and Figures

This appendix provides information on the data sources and computations for the tables and figures used in the Digestive Disease articles and updates Appendices 2 and 3 in the Burden of Digestive Diseases in the United States.(1,2)

## Part 1. Data Sources

NATIONAL AMBULATORY MEDICAL CARE SURVEY (NAMCS)

SPONSOR: | National Center for Health Statistics Centers for Disease Control and Prevention https://www.cdc.gov/nchs/namcs/about/index.html
DESIGN: | The National Ambulatory Medical Care Survey (NAMCS) is a continuing series of nationally representative sample surveys of office-based outpatient visits to health care providers in the United States. The survey includes all non-federal office-based physicians who are primarily engaged in direct patient care. Anesthesiologists, pathologists, and radiologists are excluded. The design is a multistage stratified probability sample of geographically defined areas, physician practices within these areas, and patient visits within physician practices. Physicians are asked to complete a patient encounter form for a systematic sample of office visits occurring during a randomly assigned one-week reporting period. The study design is described in: E Bryant (https://pubmed.ncbi.nlm.nih.gov/?sort=date&term=Bryant+E&cauthor_id=3227663), I Shimizu (https://pubmed.ncbi.nlm.nih.gov/?sort=date&term=Shimizu+I&cauthor_id=3227663). Sample design, sampling variance, and estimation procedures for the National Ambulatory Medical Care Survey. Vital Health Stat 2. 1988;Sep:(108):1-39.
TIMEFRAME: | Data were collected annually from 1973 through 1981, again in 1985, and annually since 1989.
SAMPLE SIZE: | Through 1981, the sample included 3,000 total physicians, about 1,925 responding physicians, and about 51,000 patient visits. The 1985 sample included about 5,000 total physicians, 2,900 responding physicians, and 70,000 patient visits. Beginning in 1989, the sample included 2,500 total physicians, about 1,600 responding physicians, and about 42,000 patient visits (unweighted). Sample size for patient visits decreased in 2015 to 28,332, in 2016 to 13,165, in 2018 to 9,953 and in 2019 to 8,250.
CONTENT RELEVANT TO DIGESTIVE DISEASES: | Demographic data, reason for visit, physician's diagnostic and therapeutic services ordered or provided, diagnosis and disposition decision, and drugs prescribed are included. International Classification of Diseases (ICD) codes are given for the first four physician diagnoses. The reason for office visit is the principal reason given by the patient, which in the physician's judgment is the most appropriate one. Up to two or four additional symptoms or other reasons for visit can be coded.
STRENGTHS: | Survey form is completed from provider records. Trend data are available for about 45 years. Visits can be compared with those of the National Health Interview Survey, in which the conditions are similarly defined. Since 1980, data have been collected on the number and names of specific drugs prescribed in office-based practice. The sample allows estimates for specific physician subspecialties. ICD codes are used for diagnoses. Data are weighted to provide national estimates.
LIMITATIONS: | The sample is limited to office-based health care providers, a group that has become a less inclusive source for ambulatory care. There may be more than one report per person, because the report reflects a visit rather than an individual. The sample size is small, so estimates of fewer than 200,000 are statistically unreliable. Because ambulatory care in federal facilities is not included, ambulatory care rates based on the U.S. population are underestimates.
AVAILABILITY OF DATA: | Published data are found in the National Center for Health Statistics Vital and Health Statistics, Series 13 (https://www.cdc.gov/nchs/products/series/series13.htm) and in Advance Data (http://www.cdc.gov/nchs/products/pubs/pubd/ad/ad.htm). Data are publicly available on the National Center for Health Statistics website in an easy-to-use form with input statements. However, full seven-digit ICD-10 codes needed to define digestive diseases are restricted to use through the National Center for Health Statistics Research Data Center (https://www.cdc.gov/rdc/index.html).

HEALTHCARE COST AND UTILIZATION PROJECT-NATIONWIDE EMERGENCY DEPARTMENT SAMPLE (HCUP NEDS)

SPONSORS: | Agency for Healthcare Research and Quality https://www.hcup-us.ahrq.gov/nedsoverview.jsp
DESIGN: | The Healthcare Cost and Utilization Project Nationwide Emergency Department Sample (HCUP NEDS) consists of a nationally representative sample of non-federal hospital-owned emergency department visits collected annually regardless of whether they result in admission. The universe of hospital-owned emergency departments is defined as American Hospital Association (AHA) community, non-rehabilitation hospitals that reported total emergency departments visits. The AHA defines community hospitals as "all non-federal, short-term, general, and other specialty hospitals." Included among community hospitals are pediatric institutions, public hospitals, and academic medical centers. The NEDS includes discharge data for ED visits from 993 hospitals located in 41 States and the District of Columbia, approximating a 20-percent stratified sample of U.S. hospital-owned Eds. The NEDS is sampled from the State Inpatient Databases (SID) (https://hcup-us.ahrq.gov/sidoverview.jsp), which contain information on patients initially seen in the ED and subsequently admitted to the same hospital, and State Emergency Department Databases (SEDD) (https://hcup-us.ahrq.gov/seddoverview.jsp), which contain information on ED visits that do not result in an admission (i.e., treat-and-release visits and transfers to another hospital).
TIMEFRAME: | Data have been collected annually since 2006.
SAMPLE SIZE: | It contains data from approximately 32 million emergency department visits each year (unweighted) and estimates approximately 137 million emergency department visits (weighted).
CONTENT RELEVANT TO DIGESTIVE DISEASES: | Data for each emergency department visit include patient demographics (e.g., sex, age, urban-rural designation of residence, national quartile of median household income for patient's ZIP Code), discharge status, total charges, expected payment source, diagnosis and surgical procedure ICD codes, procedure Current Procedural Terminology (CPT) codes (for ED visits that do not result in an admission to the same hospital), hospital characteristics (e.g., region, trauma center indicator, urban-rural location, ownership, size, teaching status), geographic area (e.g., hospital region), and the nature of ED visits (e.g., common reasons for ED visits, including injuries).
STRENGTHS: | The NEDS is the largest all-payer emergency department database in the United States. Data are weighted to be nationally representative of non-federal hospital-owned emergency departments in the United States. Trend data are available for over 15 years. The large sample size enables analyses across hospital types and the study of relatively uncommon disorders and procedures.
LIMITATIONS: | Not all states participate, and not all participating states collect data on race-ethnicity. There may be more than one report per person, because the report reflects a visit rather than an individual. Because only emergency department visits to non-federal hospital-owned facilities are included, emergency department visit rates based on the U.S. population are underestimates.
AVAILABILITY OF DATA: | Summary statistics are published by the Agency for Healthcare Research and Quality (http://www.hcup-us.ahrq.gov/reports.jsp). An online database, HCUP-Net (https://hcup-us.ahrq.gov/dataquerytools.jsp) allows users to easily generate certain statistics. Selected datasets can be purchased for analysis.

HEALTHCARE COST AND UTILIZATION PROJECT-NATIONAL (NATIONWIDE) INPATIENT SAMPLE (HCUP NIS)

SPONSORS: | Agency for Healthcare Research and Quality https://www.hcup-us.ahrq.gov/nisoverview.jsp#whats
DESIGN: | The Healthcare Cost and Utilization Project National (Nationwide) Inpatient Sample (HCUP NIS) consists of a nationally representative sample of discharges from all participating non-federal hospitals collected annually. The NIS is drawn from all states participating in HCUP, representing more than 97 percent of the U.S. population. The NIS approximates a 20-percent stratified sample of discharges from U.S. community hospitals, excluding rehabilitation and long-term acute care hospitals. NIS data are weighted to represent the annual discharges from non-federal hospitals in the United States. The NIS contains information on all hospital stays, regardless of expected payer of the hospital stay. The NIS is sampled from the State Inpatient Databases (SID (https://www.hcup-us.ahrq.gov/sidoverview.jsp)), which include all inpatient data that are currently contributed to HCUP. The number of States participating in the NIS has grown from 8 in the first year, representing 31 percent of all hospital discharges in the United States, to 47 plus the District of Columbia, at present, representing 85 to 90 percent of all hospital discharges in the United States. Beginning with the year 2012 data, the NIS was redesigned to improve national estimates. The self-weighting design of the new NIS reduces the margin of error for estimates and delivers more stable and precise estimates than the previous NIS design. To highlight the design change, beginning with 2012 data, AHRQ renamed the NIS from the "Nationwide Inpatient Sample" to the "National Inpatient Sample." The redesign incorporates three major types of changes: Revisions to the sample design - the NIS is now a sample of discharge records from all HCUP-participating hospitals, rather than a sample of hospitals from which all discharges were retained. Revisions to how hospitals are defined - the NIS now uses the definitions of hospitals and discharges supplied by the statewide data organizations that contribute to HCUP, rather than the definitions used by the AHA Annual Survey. Revisions to enhance confidentiality - the NIS now eliminates state and hospital identifiers and other data elements that are not uniformly available across states.
TIMEFRAME: | Data have been collected annually since 1988.
SAMPLE SIZE: | It contains data from around 7 million hospital stays each year (unweighted) and estimates around 35 million hospitalizations nationally (weighted).
CONTENT RELEVANT TO DIGESTIVE DISEASES: | Data for each hospital stay include patient demographics (e.g., sex, age, race, median income for ZIP Code), discharge status, length of stay, total charges, expected payment source, up to 15 diagnoses and 7 surgical procedures coded using ICD codes, and hospital characteristics (e.g., ownership, size, teaching status).
STRENGTHS: | The NIS is the largest all-payer inpatient health care database in the United States. Data are weighted to be nationally representative of non-federal hospitals in the United States. Trend data are available for almost 35 years. The large sample size enables analyses of rare conditions, uncommon treatments, and special patient populations.
LIMITATIONS: | Not all states participate, and not all participating states collect data on race-ethnicity. The charge information is for the facility only; no information on physician fees is available. Data on medications are not supplied, although medication costs are included in the charge total. There may be more than one report per person, because the report reflects a hospitalization rather than an individual. Because hospitalizations in federal facilities are not included, hospital stay rates based on the U.S. population are underestimates.
AVAILABILITY OF DATA: | Summary statistics are published by the Agency for Healthcare Research and Quality (http://www.hcup-us.ahrq.gov/reports.jsp). An online database, HCUP-Net (https://hcup-us.ahrq.gov/dataquerytools.jsp) allows users to easily generate certain statistics. Selected datasets can be purchased for analysis.

HEALTHCARE COST AND UTILIZATION PROJECT-NATIONWIDE AMBULATORY SURGERY SAMPLE (HCUP NASS)

SPONSORS: | Agency for Healthcare Research and Quality https://hcup-us.ahrq.gov/nassoverview.jsp
DESIGN: | The Healthcare Cost and Utilization Project Nationwide Ambulatory Surgery Sample (HCUP NASS) consists of a nationally representative sample of major ambulatory surgery encounters performed in hospital-owned facilities. Major ambulatory surgeries are defined as selected major therapeutic procedures that require the use of an operating room, penetrate or break the skin, and involve regional anesthesia, general anesthesia, or sedation to control pain. Procedures intended primarily for diagnostic purposes are excluded. To be included in the NASS, ambulatory surgeries are also required to have a relatively high annual volume or aggregate total facility charge. Examples include ambulatory surgeries such as cholecystectomy, appendectomy, gastric bypass, and hernia repair. The NASS incudes data from 2,799 hospital-owned facilities located in 33 States and the District of Columbia, approximating a 65-percent stratified sample of U.S. hospital-owned facilities performing selected ambulatory surgeries. The NASS is sampled from the State Ambulatory Surgery and Services Databases (SASD) (https://hcup-us.ahrq.gov/sasdoverview.jsp).
TIMEFRAME: | Data have been collected annually since 2016.
SAMPLE SIZE: | It contains approximately 9.1 million ambulatory surgery encounters each year and approximately 12.1 million ambulatory surgery procedures (unweighted) and estimates approximately 12.4 million ambulatory surgery encounters and 16.4 million ambulatory surgery procedures (weighted).
CONTENT RELEVANT TO DIGESTIVE DISEASES: | Data for each ambulatory surgery encounter include patient demographics (e.g., sex, age, urban-rural designation of residence, national quartile of median household income for patient's ZIP Code), up to 30 clinical diagnostic ICD codes, surgical procedure CPT codes, disposition of patients, total charges, expected payment source, and hospital characteristics (e.g., region, ownership, teaching status).
STRENGTHS: | The NASS is the only all-payer ambulatory surgery database in the United States. Data are weighted to be nationally representative of non-federal hospital-owned ambulatory surgery facilities in the United States.
LIMITATIONS: | Not all states participate. Not all participating states collect data on race-ethnicity. There may be more than one report per person, because the report reflects an ambulatory surgery encounter rather than an individual. Because only ambulatory surgery encounters in non-federal hospital-owned facilities are included, ambulatory surgery encounter rates based on the U.S. population are underestimates.
AVAILABILITY OF DATA: | Summary statistics are published by the Agency for Healthcare Research and Quality (http://www.hcup-us.ahrq.gov/reports.jsp). An online database, HCUP-Net (https://hcup-us.ahrq.gov/dataquerytools.jsp) allows users to easily generate certain statistics. Selected datasets can be purchased for analysis.

VITAL STATISTICS OF THE UNITED STATES: MULTIPLE CAUSE-OF-DEATH

SPONSORS: | National Center for Health Statistics Centers for Disease Control and Prevention http://www.cdc.gov/nchs/deaths.htm
DESIGN: | Multiple cause-of-death mortality data from the National Vital Statistics System include all deaths occurring within the United States collected annually. Information is abstracted from death certificates filed in state and the District of Columbia vital statistics offices. An underlying cause and up to 20 contributing causes of death were derived from death certificates and coded according to the ICD. The study design is described in: National Center for Health Statistics, Data systems of the National Center for Health Statistics. Hyattsville, Maryland: Public Health Service, 1981; DHHS Publication No. (PHS) 82-1318. (Vital and Health Statistics: Series 1, No. 16).
TIMEFRAME: | Data have been collected annually since 1968.
SAMPLE SIZE: | The sample is a 100 percent count of deaths occurring in the United States.
CONTENT RELEVANT TO DIGESTIVE DISEASES: | Demographic data (e.g., age, sex, race, residence) and underlying and contributing causes of death are included.
STRENGTHS: | All deaths occurring in the United States are included. Trend data are available for 55 years. For digestive diseases with high mortality rates, such as cirrhosis, death records are the most comprehensive data source. Mortality statistics may be the only reliable data source for uncommon fatal conditions. Annual age-adjusted mortality rates are useful for examining trends over time, assuming case-fatality rates do not change significantly. Mortality rates for diseases that are usually fatal are often used as estimates of incidence rates when the latter are not available.
LIMITATIONS: | Quality is dependent on the accuracy of death certificate diagnoses which may vary according to condition. Chronic diseases that contribute to mortality are frequently underreported.
AVAILABILITY OF DATA: | Published data are found in: National Center for Health Statistics Vital Statistics of the United States (http://www.cdc.gov/nchs/products/pubs/pubd/vsus/vsus.htm), National Vital Statistics Reports (http://www.cdc.gov/nchs/products/nvsr.htm), and Vital and Health Statistics, Series 20 (https://www.cdc.gov/nchs/products/series/series20.htm). Data are publicly available on the National Bureau of Economic Research website (http://www.nber.org/data/multicause.html) in an easy-to-use form with input statements, in addition to the CDC website (https://www.cdc.gov/nchs/data_access/vitalstatsonline.htm).

UNITED STATES POPULATION ESTIMATES

SPONSOR: | National Center for Health Statistics Centers for Disease Control and Prevention https://www.cdc.gov/nchs/nvss/bridged_race.htm
DESIGN: | Annual population data were derived from the national population estimates program of the U.S. Census Bureau and the CDC. The estimates are mid-year (July 1) population counts by age, sex, race, and Hispanic origin. The counts are used with all national samples as the denominator for all estimates of rates. The year 2000 estimates are also used for age-adjusting. These estimates are not used for cancer statistics from the Surveillance, Epidemiology, and End Results (SEER) program, which has its own population counts.
TIMEFRAME: | Estimates for all years used in this report.
SAMPLE SIZE: | The U.S. population is the sample.
CONTENT RELEVANT TO DlGESTIVE DISEASES: | Denominators are provided for calculating rate per 100,000 persons by age, race-ethnicity, and sex.

SURVEILLANCE, EPIDEMIOLOGY, AND END RESULTS (SEER) PROGRAM

SPONSORS: | National Cancer Institute http://seer.cancer.gov/
DESIGN: | A total of 17 population-based registries in the United States provide data on all residents diagnosed with cancer and follow-up information on all previously diagnosed patients. Data are compiled twice a year. Cancer mortality data are obtained from vital statistics for the entire United States.
TIMEFRAME: | Data have been collected annually since 1975.
SAMPLE SIZE: | Surveillance, Epidemiology, and End Results (SEER) program data are 100 percent counts from the Alaska Native Tumor Registry; Connecticut; Atlanta, Georgia; Greater Georgia; Rural Georgia; San Francisco/Oakland, California; San Jose-Monterey, California; Greater California; Hawaii; Iowa; Kentucky; Los Angeles, California; Louisiana; New Mexico; New Jersey; Seattle/Puget Sound, Washington; and Utah.
CONTENT RELEVANT TO DIGESTIVE DISEASES: | Data on cancer incidence and mortality, including current and projected trends, are collected for selected sites such as esophagus, stomach, colon, rectum, liver, and pancreas. Demographic data include age, sex, and race.
STRENGTHS: | SEER data are verified for quality and completeness and are estimated to be 99 percent complete from the registry sites. Data are weighted to provide national estimates. Trend data are available for over 45 years.
LIMITATIONS: | SEER data represent only 17 areas of the country. Although the data are weighted to provide national estimates, these data are not statistically representative of the United States.
AVAILABILITY OF DATA: | Data are published by the National Cancer Institute (http://seer.cancer.gov/publications/) and certain statistics can easily be generated online (http://seer.cancer.gov/statistics/). Selected datasets are available for analysis.

OPTUM CLINFORMATICS® DATA MART (CDM)

SPONSOR: | Optum https://www.optum.com/content/dam/optum/resources/productSheets/ Clinformatics_for_Data_Mart.pdf (https://www.optum.com/content/dam/optum/resources/productSheets/Clinformatics_for_Data_Mart.pdf)
DESIGN: | The Clinformatics® Data Mart (CDM) is comprised of administrative health claims for members of a large national managed care company affiliated with Optum and includes private health plan and Medicare Advantage members from all 50 states. Administrative claims submitted by providers and pharmacies are verified, adjudicated, and de-identified prior to inclusion in CDM. Data are included for only those covered individuals with both medical and prescription drug coverage, to enable users to evaluate the claims related to the complete health care experience. Additionally, the CDM includes results for outpatient lab tests processed by large national lab vendors under contract with the managed care organization. The CDM also includes data related to member inpatient confinements and member eligibility.
TIMEFRAME: | Data have been collected monthly since 2001.
SAMPLE SIZE: | The database includes approximately 17–19 million annual covered individuals for over 68 million unique members from January 2007 through December 2020.
CONTENT RELEVANT TO DIGESTIVE DISEASES: | Demographics including age, sex, race, and region; date of death; and data for each medical or confinement claim include patient admission status, total costs and charges, diagnoses and surgical procedures coded using ICD and CPT codes.
STRENGTHS: | Data are on a member-level, allowing members to be tracked across multiple plans and enrollment periods. Month and year of death are based on social security number plus one additional piece of PII.
LIMITATIONS: | CDM contains lab results from certain laboratory chains with contractual relationships with the major insurance company sourcing CDM. There are no incentives on the part of the members or the providers to use these lab vendors. Therefore, the lab result data should be considered incomplete. Not all members have lab results, and for members with lab results in the CDM, not all labs may be represented. Diagnoses are not recorded with pharmacy claims. In 2011, some states stopped contributing dates of death to the Social Security office for privacy concerns, so state reported information is no longer used. This caused a 30% drop in records. Therefore, it is important to avoid comparing data from before and after this time.
AVAILABILITY OF DATA: | Selected datasets can be purchased for analysis. Either date-of-death or socioeconomic status versions are available.

CENTERS FOR MEDICARE AND MEDICAID SERVICES (CMS) MEDICARE 5% SAMPLE

SPONSOR: | Centers for Medicare and Medicaid Services https://www2.ccwdata.org/web/guest/home/
DESIGN: | The Centers for Medicare and Medicaid Services creates the Medicare 5% sample files to be representative of the entire population of Medicare beneficiaries, and it is housed in the CMS Chronic Conditions Data Warehouse. Data are linked by a unique, unidentifiable beneficiary key that can be used to follow beneficiaries across care settings and time. The Medicare datasets contain fee-for-service and Medicare Advantage institutional and non-institutional claims and enrollment/eligibility information (Part A, Part B, and Medicare Advantage). Assessment data and Part D Prescription Drug Event data which include plan characteristics, pharmacy characteristics, and prescriber characteristics are also available.
TIMEFRAME: | Medicare fee-for-service files are available from 1999 onward, Medicare Advantage files are available from 2015 onward, Part D Prescription Drug Event data files are available from 2006 onward, and NDI cause of death information is available from 1999 onward.
SAMPLE SIZE: | A 5% sample representative of all Medicare beneficiaries.
CONTENT RELEVANT TO DlGESTIVE DISEASES: | Primary and other diagnoses (up to 25 in some datasets) are coded using the ICD. Procedures are coded using ICD and CPT codes. Utilization includes number of claims, number of visits, patient admission type/date/length, and associated charges and costs. Demographic information includes sex, race, age, geographic location, and insurance type. Death information includes date of death and cause of death diagnosis.
STRENGTHS: | Data were weighted to be nationally representative of all Medicare beneficiaries. Medicare covers approximately 96 percent of all U.S. citizens aged 65 years and over permitting generalization to the U.S. older adult population (https://www.resdac.org/getting-started-cms-data#who-is-in-the-data). Beneficiaries can be followed across multiple care settings and years.
LIMITATIONS: | Medicare Advantage claims were not available prior to 2015. Linking all entries for one specific event can be complicated, as separate claims are generated for institutional (Part A) and physician/supplier (Part B) services. Information is not available on stage/severity or histology of diseases. The Part D event file contains no diagnosis codes. Different care settings use different procedure codes (ICD codes for inpatient care and CPT/HCPCS codes for outpatient care.) Exact timing of events can be difficult to calculate.
AVAILABILITY OF DATA: | Data can be accessed through the CCW Virtual Research Data Center (VRDC) (https://www.resdac.org/). Costs vary depending on beneficiary cohort size, years of data and files requested.

CENTERS FOR MEDICARE AND MEDICAID SERVICES (CMS) MEDICAID FILES

SPONSOR: | Centers for Medicare and Medicaid Services https://www2.ccwdata.org/web/guest/home/
DESIGN: | The CMS Medicaid files include the entire population of Medicaid beneficiaries and are housed in the CMS Chronic Conditions Data Warehouse. Data are linked by a unique, unidentifiable beneficiary key that can be used to follow beneficiaries across care settings and time.
TIMEFRAME: | Medicaid MAX files are available from 1999-2015 and Medicaid TAF files are available from 2014 onward. NDI cause of death information is available from 1999 onward.
SAMPLE SIZE: | Files include all Medicaid beneficiaries.
CONTENT RELEVANT TO DlGESTIVE DISEASES: | Primary and other diagnoses (up to 12 in some datasets) are coded using the ICD. Procedures are coded using ICD and CPT codes. Utilization includes number of claims, number of visits, patient admission type/date/length, and associated charges and costs. Demographic information includes sex, race-ethnicity, age, and geographic location. Death information includes date of death and cause of death diagnosis.
STRENGTHS: | Representative of all Medicaid beneficiaries. These datasets allow beneficiaries to be followed across multiple care settings and years. Medicaid includes information on Asians / Hawaiians / Pacific Islanders and American Indians / Alaska Natives, groups for which data are less commonly available.
LIMITATIONS: | The income level for Medicaid eligibility varies among states. Data collection methods and program rules vary significantly from state to state, leading to inconsistencies in the data. Linking all entries for one specific event can be complicated, as separate claims are generated for institutional and physician/supplier services. Information is not available on stage / severity or histology of diseases. The TAF Pharmacy file contains no diagnosis codes. Different care settings use different procedure codes (ICD codes for inpatient care and CPT/HCPCS codes for outpatient care.) Exact timing of events can be difficult to calculate.
AVAILABILITY OF DATA: | Data can be accessed through the CCW Virtual Research Data Center (VRDC) (https://www.resdac.org/). Costs vary depending on beneficiary cohort size, years of data and files requested.

## Part 2. Methodology for Tables and Figures

### I Disease Definitions

Digestive diseases were coded based on either the International Classification of Diseases (ICD)-9 CM (Clinical Modification) (https://archive.cdc.gov/www_cdc_gov/nchs/icd/icd9cm.htm) for events prior to the 4^th^ quarter of 2015 or ICD-10-CM (https://www.cdc.gov/nchs/icd/icd-10-cm/index.html) for events beginning in the 4^th^ quarter of 2015 for morbidity and ICD-10 (https://www.cdc.gov/nchs/icd/icd-10/?CDC_AAref_Val=https://www.cdc.gov/nchs/icd/icd10.htm) for mortality. See Appendix 1 for the complete list of digestive disease codes used. ‘All-listed diagnoses’ were used in these articles and included both the first-listed (primary) diagnosis and all remaining (secondary) diagnoses. Diagnoses were counted only once, irrespective of the number of actual diagnoses. For example, in the chapter on all digestive diseases, only one digestive disease diagnosis was counted, even though more than one could have been listed on a medical record or death certificate.

While the coding for digestive disease morbidity is generally consistent between ICD-9-CM and ICD-10-CM, the World Health Organization (WHO), which produces the ICD code definitions, advises that series are not necessarily comparable across versions of the ICD code book. This change was portrayed as a vertical line at approximately October 1, 2015 on the morbidity figures. The ‘Other Digestive Disease’ category (not a separate disease but included in All Digestive Diseases) shows the greatest difference between ICD-9-CM and ICD-10-CM.

### II National Event-Level Data Sources

#### A Demographic Categories for National Event-Level Data

For the purpose of calculating rates for the U.S. population, annual population data were derived from the national population estimates program of the U.S. Census Bureau and the Centers for Disease Control and Prevention (CDC) (http://wonder.cdc.gov/population.html) for national estimates from survey data. Population counts were specific for each of the demographic groups shown in the tables and figures. (Population estimates for claims data (Medicare, Medicaid, and Optum) are specific to the claims and are based on the enrollment in the respective programs.)

For NAMCS data, race was coded as ‘White’ or ‘Black’; or ‘Two or more races / Other’, if another category was specified. Missing race data were not considered ‘Other’. Hispanic origin was coded as ‘Hispanic’ or ‘Not Hispanic’. For HCUP NIS and mortality data, race-ethnicity was coded as ‘White’, ‘Black’, ‘Hispanic’, ‘Asian / Native Hawaiian / Pacific Islander’, ‘American Indian / Alaska Native’, or ‘Two or more races / Other’.

The HCUP NIS data combine Hispanic origin with race, so it was impossible to know whether Hispanics were white or black. In order not to undercount the totals, we assumed all Hispanics were white. As a result, hospital stays for whites were slightly overstated and for blacks slightly understated. HCUP NIS data came from the individual states, and a varying number of states did not report race, depending on the year. To adjust for this limitation, we created a separate weight for race, based on the existing weight times the inverse of the proportion of each race in the states that did report race to the total for all states in that year of the NIS. Note that these are counts of persons, based on the mid-year population estimates, and not the proportion of hospital stays. We did not report separate counts for ‘Other Race’, because the definition of ‘Other Race’ in the HCUP NIS and the population counts may not be the same. A similar weight was created for Hispanic origin.

#### B Age-Adjustment for National Event-Level Data

Age-adjustment through direct standardization allowed for comparisons across race, sex, and time that were not influenced by differences in age distribution for the groups being compared. Year-specific population data in 18 age groups, plus the National Center for Health Statistics (NCHS) standard year 2000 population, were used for age-adjusting (http://www.cdc.gov/nchs/data/nvsr/nvsr47/nvs47_03.pdf). Age-specific rates were calculated for each of the 18 age groups (age 0–4, 5-year age groups through age 84, and age 85 and older), and the results were multiplied by the year 2000 standard population proportion in each of the age groups. These results were then summed to arrive at the age-adjusted population rate estimate. Further details can be found in Anderson and Rosenberg.(3)

#### C Tables

##### 1.Morbidity Estimates

###### a Ambulatory Care Visits

Estimates in the tables for ambulatory care visits in 2018-2019 are based on the 2-year average. Multiple years were combined to have sufficient observations to meet the minimum threshold for reporting and for more stable estimates. The 2 years of data were averaged by dividing the sampling weight by 2, in accordance with the general instructions from NCHS.

Each outpatient record could have multiple diagnoses listed. The primary diagnosis was the first diagnosis listed in the record. All remaining diagnoses were secondary diagnoses. A visit was considered to have been for a specific digestive disease if any of the diagnoses listed on the record fell into the subject category. Therefore, any individual record could be counted for more than one digestive disease. However, a given record was not counted more than once for a specific disease. For example, a record having the ICD-10-CM diagnosis codes of ‘A00’ and ‘A01’ was only counted once in the category of Gastrointestinal Infections. The weighted count of visits with all-listed diagnoses of each of the digestive diseases was the count (in thousands) listed in the table under ‘Ambulatory Care Visits’, ‘Number in Thousands’. The ‘Rate per 100,000’ was the count of visits, not the number of individuals with a visit, divided by the number of persons in the population (in 100,000s) in the demographic group.

###### b Emergency Department Visits

Data in the tables came from the HCUP NEDS files of emergency department visits from participating states. Sampling weights inflated the visits to the U.S. total. The ‘Number in Thousands’ and ‘Rate per 100,000’ for emergency department visits were calculated in a similar manner as for ambulatory care visits.

###### c Hospital Stays

Hospital stays were based on inpatient stays of at least 1 night. Emergency room visits that did not result in admission to the hospital with an overnight stay were not counted. Data in the tables came from the HCUP NIS files of hospital stays from participating states. Sampling weights inflated the stays to the U.S. total, based on information from the American Hospital Association. The ‘Number in Thousands’ and ‘Rate per 100,000’ for hospital stays were calculated in a similar manner to ambulatory care and emergency department visits.

##### 2 Mortality

Counts of deaths from digestive diseases were derived from the Multiple Cause-of-Death data files from the Division of Vital Statistics, CDC. These data are a complete accounting of all deaths in the United States (although not necessarily for all U.S. citizens). Cause of death is organized on a record axis, with a specific underlying cause of death and contributing causes for each decedent.

The underlying cause of death was determined from the list of all causes on the death certificate by professional coders. Underlying cause is analogous to a first-listed diagnosis for morbidity. The record axis of the death certificate can list up to 20 contributing causes in addition to the underlying cause. A record of any of the unique digestive diseases was noted for each of the 21 possible causes, and any duplicate digestive diseases were eliminated. A death was attributed to one of the digestive diseases if any of the unduplicated digestive diseases were recorded. Therefore, a death could appear under more than one of the digestive diseases in the tables.

‘Number of Deaths’ (in 100,000s) was the count of all deaths that had the specified digestive disease listed in any position on the record axis. A death could appear under more than one disease if any of the diagnoses were listed; however, no death appeared more than once for a given disease. The ‘Rate per 100,000’ column was determined by dividing the number of deaths with underlying or other cause by the population (in 100,000s) in the demographic group. The race- and sex-specific and total rate estimates were age-adjusted, while the age-specific rates were not age-adjusted.

‘Years of Potential Life Lost’ assumed life expectancy of 75 years had individuals not died before that age. Because age at death is reported in full years, we added 0.5 years to each age at death. Thus, for the purpose of calculating years of life lost, a person whose age at death was listed as 65 was counted as having been 65.5 years old. The age 65.5 represented the average age of all people who died at age 65, and each contributed 9.5 years of potential life lost (75-65.5 = 9.5). The tables show the total number of years of life lost to age 75 in thousands. ‘Years of Potential Life Lost’ was calculated for underlying cause of death and was irrelevant for underlying or other cause.

##### 3 Cancer Incidence and 3-Year Survival

Cancer incidence and 3-year survival rates were derived from SEER registry data. The registries do not cover the entire United States and do not necessarily represent the entire population. Instead, each registry covers a specific set of counties, across diverse sections of the country. Population counts used for rates and age-adjustment were also restricted to the counties covered by the registry. Cancer incidence was estimated for the entire country from the rates for 17 registries in 2022. The estimated number of new cases for the United States was calculated by multiplying the incidence rate for the 17 registries by the 2022 U.S. population. Age-adjusted incidence rates were based only on the 17 registry areas and were calculated from the age-specific rates within the demographic group multiplied by the U.S. standard 2000 population as described above under ‘Age-Adjustment’. Only estimates based on unweighted counts of 17 or more cases were shown, following the reporting standard set by NCI.

Three-year survival was the proportion of those diagnosed in a given year who were still known to be alive 3 years later. Three-year survival was computed using diagnoses in 2019 because it was impossible to know the 3-year status of patients diagnosed after that year. Absolute survival is shown in tables, whereas SEER typically publishes relative survival. Relative survival accounts for the expected survival of the population as a whole and is higher than absolute survival, especially for cancers that concentrate in groups with high underlying mortality, such as the elderly.

#### D Figures

##### 1 Morbidity Estimates

The figures show trends in rates of ambulatory care visits from 2006 through 2018–2019 and of emergency department visits and hospital stays from 2006 through 2022 using all-listed diagnoses. Because of the smaller sample size for the ambulatory care surveys, estimates derived from NAMCS files were 3-year average, except for the 2018–2019 estimates, which were averages of those two years. This approach provided more stable estimates across time. All rates were age-adjusted. The vertical line at 2015 4^th^ quarter represented the change from ICD-9-CM to ICD-10-CM.

##### 2 Mortality

The figures show trends in mortality rate estimates for the period 2006 through 2023 using the multiple cause-of-death data for each year. Because these were observed counts for the United States and not samples, they were not considered estimates. The age-adjusted mortality rates are shown for underlying or other cause rates for the total population per year.

##### 3 Cancer Incidence and 3-Year Survival

For digestive cancers, the figures for age-adjusted cancer incidence and 3-year survival were derived from data obtained by 17 registries that SEER used through the entire period of 2006–2022.

### III Person-Level Data Sources

Enrollees were considered digestive disease patients if they had one or more claims with an ICD-9-CM or ICD-10-CM diagnostic code indicative of a digestive disease in the primary or any secondary diagnostic code field (i.e., all-listed diagnosis) in the medical claim files. The number and percentage of enrollees who qualified as digestive disease patients in a given year were calculated. This percentage is referred to as the ‘claims-based prevalence’. Numbers and rates of ambulatory care visits, emergency department visits, and hospital stays were based on events, not persons, for comparability with national estimates. Estimates were reported overall and stratified by age, sex, race-ethnicity, and region.

#### A Optum Clinformatics® Data Mart (CDM)

The study population / denominator included all privately insured enrollees who had a single consistent birth year recorded in CDM, resided in the United States, and were enrolled at any time during a given calendar year.

Optum© CDM member eligibility files containing birth year, demographics, and eligibility period were linked to inpatient confinement (acute care hospital or skilled nursing facility stay), medical (health care professional services), medical diagnosis, and pharmacy claims files. Hospital stays were defined as having an inpatient hospital place of service. Ambulatory care visits were evaluation and management visits with an office, outpatient hospital, or ambulatory surgical center place of service. Evaluation & management visits were additionally characterized by a non-facility location with a type of service including office visits, surgery, emergency room, consultations, or home health / hospice visits, and excluding non-encounter services; capitated primary, specialist, or professional encounters, fee-for-services charged to Cap Organization; and fee-for-service for OXFORD / Parallax / NICE only. Demographic variables included age (0-11, 12-24, 25-44, 45-54, 55-64, 65-74, or 75+), sex (male or female), race-ethnicity (non-Hispanic White, non-Hispanic Black, Hispanic, Asian, or unknown), and geographical region (Northeast, Midwest, South, or West).

Rates were age-adjusted using 18 age groups (age 0–4, 5-year age groups through age 84, and age 85 and older) and the 2020 decennial census data.

#### B Centers for Medicare and Medicaid Services (CMS) Medicare 5% Sample

The study population / denominator included beneficiaries who were 65 years or older as of January 1^st^ of a given year, resided in the 50 U.S states or District of Columbia, and were enrolled at any time during the year in fee-for-service Part A or Part B Medicare benefits or in the Medicare Advantage program (Part C / Health Maintenance Organization benefits). Enrollment in Part C has doubled in terms of percentage of the total Medicare population over time.

The denominator file which is at an individual level and contains demographic and enrollment data was linked by the beneficiary unique identifier to institutional (hospital inpatient stays, hospital outpatient services, skilled nursing facilities, home health agencies and hospice care organizations) or non-institutional (also called Part B; health care professionals, supplies, and services) medical claims files. Both institutional and non-institutional claims files have a base file that contains information at a claim level including the corresponding diagnoses. A revenue detail file exists for each type of institutional claim file and a line-level file for the non-institutional claim file. These line / revenue level files contain line-item details of charges and information such as medical procedure Healthcare Common Procedure Coding System codes (HCPCS) or place of service and type of service. Both types of line level files can be linked back to the appropriate base file using beneficiary and claim identifiers, but institutional claims for a given event (such as inpatient stay) are independent of supplier claims and may have different diagnosis codes as a result.

All claims in the hospital inpatients stays institutional dataset were used to identify a person as having an inpatient hospitalization. People with emergency department visits were identified from the institutional hospital inpatients stays, institutional hospital outpatient services and the non-institutional Part B claims file. From the institutional files a claim was from an emergency department visit if the ‘revenue center’ code was 0450-0459 or 0981 as these codes relate to emergency room use or professional fees charged for the emergency room. In the non-institutional file, a claim was from an emergency department visit if the service place indicated ‘emergency room’ and service type indicated ‘medical care’, ‘surgery’ or ‘consultation’. People with at least one claim were included in the analysis.

People with ambulatory care visits were identified when an evaluation and management (E & M) visit occurred at an office, outpatient hospital, or other place of service. These were identified from institutional hospital outpatient services, and the non-institutional Part B claims file. A claim was classified as from an ambulatory E & M visit from the institutional hospital outpatient services file using either of two criteria: if the HCPCS code indicated an office or other outpatient visit for evaluation & management (92002 – 92004,92012 – 92014,99201 – 99205, 99211 – 99215,99241 – 99245,99304 – 99310, 99315 – 99316, 99318,99324 – 99328, 99334 – 99337, 99341 – 99345, 99347 – 99350, 99381 – 99387, 99391 – 99397, 99401 – 99404, 99411 – 99412, 99420,99429, 99461, G0463, T1015); or if the revenue code indicated a clinic visit (0510-0529, 0982-0983). From the non-institutional Part B claims file a claim was considered to result from an ambulatory E & M visit if the Service Place did not indicate ‘pharmacy’, ‘ambulance’, ‘mass immunization center’, ‘independent laboratory’, or ‘inpatient’ and Service Type indicated ‘medical care’, ‘surgery’ or ‘consultation.’ Both emergency department visit, and ambulatory care visit events were matched on service date across data files (e.g., outpatient / Part B). This was because one event could have different claims in different files for the same visit (a facility charge and a service provider charge).

For claims-based prevalence estimation, people qualified as digestive disease patients from any of the medical claims. All people identified from any of the following claim types: inpatient stays; hospital outpatient services; Part B services; skilled nursing facilities; home health agencies; hospice care organizations; and durable medical equipment were used to identify a person having a digestive disease event. People were included as a prevalent case who had at least one event in any of the datasets with a digestive disease in any diagnostic code field. Although it varies by digestive disease, anywhere from 7% to 69% of prevalent cases are based on a single ambulatory claim. This is lowest for cancers, but rather high for hemorrhoids, functional disorders, and diverticular disease, suggesting that many cases may not be chronic, or may be ‘rule outs’.

Mortality was identified using the National Death Index (NDI) segment file. Enrollees were considered digestive disease patients if they had an ICD-10 cause of death code indicative of a digestive disease in any of the entity axis cause of death fields depending on the table (underlying / other cause of death).

Demographic variables included age (65-69, 70-74, 75-79, 80-84 or 85+), sex (male or female), race (White, Black, Other), and geographical region (Northeast, Midwest, South, or West). Estimates from the 5% sample were multiplied by 20 to represent national estimates. CMS restricts reporting to measures having at least 5 unweighted cases. Thus, any measure in a table under 100 is suppressed.

#### C CMS Medicaid Files

The study population / denominator included beneficiaries who were 19 to 64 years as of January 1^st^ of a given year, resided in the 50 U.S states or District of Columbia, and were enrolled in Medicaid benefits at any time during the year. Medicaid eligibility is based on income below a certain level that varies among states, so Medicaid beneficiaries represent a low-income population.

The denominator file which is at an individual level and contains demographic and enrollment data was linked by the beneficiary unique identifier to institutional or non-institutional medical claims files.

Demographic variables included age (19–34, 35-44, 45-54, or 55-64), sex (male or female), race-ethnicity (non-Hispanic White, non-Hispanic Black, Hispanic, Asian, American Indian/Alaska native, Hawaiian/Pacific Islander, or Multiracial / unknown), and geographical region (Northeast, Midwest, South, or West).

Rates were age-adjusted using four age groups (19–34, 35-44, 45-54, or 55-64) and the 2020 decennial census data.

## References

1 Ruhl CE, Sayer B. Appendix 2. In: Everhart JE, editor. The burden of digestive diseases in the United States. US Department of Health and Human Services, Public Health Service, National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases. Washington, DC: US Government Printing Office, 2008; NIH Publication No. 09-6443 pp.153-165.
2 Sayer B. Appendix 3. In: Everhart JE, editor. The burden of digestive diseases in the United States. US Department of Health and Human Services, Public Health Service, National Institutes of Health, National Institute of Diabetes and Digestive and Kidney Diseases. Washington, DC: US Government Printing Office, 2008; NIH Publication No. 09-6443 pp.167-171.
3 Anderson RN, Rosenberg HM. Age standardization of death rates: implementation of the year 2000 standard. 3:1-20. October 7, 1998. National Vital Statistics Reports. Hyattsville Maryland: National Center for Health Statistics.