# 13 Selected baculovirus genes without orthologs in the AcMNPV genome: Conservation and function

Below is a non-inclusive list of baculovirus genes that are not present in the AcMNPV genome, but that either have homology with well-characterized genes from other organisms, or that have been investigated in baculoviruses. Following this list is a summary of investigations on each gene.

- DNA ligase
- dUTPase
- Enhancin
- Eukaryotic translation initiation factor 5
- Helicase-2
- HOAR
- Iap-3
- Metalloproteinase
- Nicotinamide riboside kinase 1
- PARG
- PARP
- PTP-2
- Photolyase
- Ribonucleotide reductase Large subunit
- Ribonucleotide reductase Small Subunit
- Serpin
- Thymidylate kinase
- Trypsin-like
- V-TREX

DNA Ligase. A DNA ligase would be involved in the ligation of Okazaki fragments during lagging strand synthesis. Homologs of DNA ligase are present in all sequenced granulovirus genomes and two NPV genomes (LdMNPV and MacoNPV-B). The GV ligases are similar to ligase I, whereas the LdMNPV is similar to ligase III (1). Vaccinia also encodes an ortholog of ligase III (2). The DNA ligase of LdMNPV was characterized and found to be capable of ligating double-stranded synthetic DNA substrates containing a single nick (3). A striking feature of the baculovirus ligase homologs is that they are always (except MacoNPV-B) accompanied with a helicase homolog that is not found in any of the genomes lacking ligase. This helicase is related to the PIF1 family (3) (note: this is not a per os infectivity factor). Members of this family have a preference for RNA-DNA hybrids and could be involved in the maturation of Okazaki fragments (4). This may involve displacement of the RNA primer, producing an RNA flap that would then be cleaved by a flap endonuclease (FEN) (5) or digested by a 5' to 3' exonuclease. DNA polymerase would then fill in the gap by extending the Okazaki fragment, and the ligase could join the fragments.

dUTPase. Deoxyuridine triphosphate (dUTP) can be mutagenic if incorporated into DNA. The enzyme dUTPase dephosphorylates dUTP to dUMP, which is a substrate for thymidine biosynthesis. Homologs of dUTPase are present in 10 NPV (all Group II except for OpMNPV) and two GV genomes (6). Baculoviruses may have incorporated this gene to either supplement or substitute for the host gene. The viruses that encode a dutpase homolog also normally encode both subunits of ribonucleotide reductase (RR) (see below). The presence of RR may have selected for the incorporation of dutpase in order to mitigate the production of the dUTP mutagen by ribonucleotide reductase. In one study of an NPV, dUTPase first appeared in cell nuclei but late in the infection it appeared to be excluded from the nucleu but was diffusely located in the cytoplasm (7).

Enhancin. Metalloproteinases are endopeptidases that contain divalent cations as integral components of their structure (8). Enhancins are members of this proteinase group and are encoded by a few lepidopteran NPVs (e.g., Ld-, Cf-, and MacoNPV) and GVs (e.g., Ag-, As-, Tn-, XcGV). In one study of TnGV, enhancin was estimated to comprise up to 5% of the mass of occlusion bodies (9). In LdMNPV, enhancin was found to be associated with ODV (10). Enhancin genes are often present in multiple copies, e.g., the XecnGV genome has four copies (11). In LdMNPV, which encodes two enhancins, deletion of either results in a 2- to 3-fold reduction in potency, whereas deletion of both caused a 12-fold reduction (12). Enhancin is thought to facilitate baculovirus infection by digesting the peritrophic membrane (PM). The PM forms a barrier in insect guts that prevents the ready access of pathogens to the epithelial cells. The PM is rich in chitin and insect intestinal mucin, and enhancins appear to target the degradation of intestinal mucin, thereby facilitating access of virions to the underlying cells (13) (14). Enhancins show sequence homology with high levels of significance (e.g., E = 3e-29) to predicted proteins of some pathogenic bacteria, e.g., Clostridium botulinum, and a variety of Bacillus (e.g., B. anthracis) and Yersinia (e.g., Y. pestis) species. To investigate their function, enhancins from B. cereus, Y. pseudotuberculosis, or TnGV were cloned into a construct of AcMNPV that yielded occluded viruses. Although the LD50 of these constructs was found to be about half of wt, only the construct expressing the TnGV enhancin caused a reduction in survival time. In addition, the bacterial enhancins failed to degrade insect intestinal mucin. It was suggested that the bacterial enhancins may have evolved an activity distinct from their viral homologs (15).

Eukaryotic translation initiation factor 5. Orthologs of eukaryotic translation initiation factor 5 have been found in two baculoviruses including Choristoneura rosaceana NPV (ChroNPV) and Choristoneura occidentalis GV (ChocGV). They are closely related (72% sequence identity) and are members of a lepidopteran lineage indicating that the gene was likely captured from a host insect and subsequently one virus obtained it from the other during a co-infection (16) (17).

Helicase-2. A second helicase homolog has been found in 10 GV and two NPV genomes (6). The homology to one of the NPVs, from Spodoptera littoralis (SpliNPV)-ORF 40, is minimal. The hel-2 gene from LdMNPV (18) is related to a yeast helicase that is important in recombination and repair of mitochondrial DNA. It had no effect on DNA replication in a transient replication assay and could not substitute for helicase-p143 (3). With one exception, Mamestra configurata NPV (MacoNPV-B) (and the limited homology of SpliNPV-ORF40 described above), the hel-2 and DNA ligase genes (see above) are found in the same genomes (predominantly GVs), suggesting that they may participate in the same metabolic pathway in these viruses (see Chapter 5). In one GV genome, the hel-2 gene was fused to the alkaline exonuclease gene (19), suggesting that the two genes may encode proteins involved in the same process such as the removal of Okazaki fragments during lagging strand synthesis. A closely related ortholog of hel-2 is also present in ascoviruses.

HOAR. According to Prof. David Tribe the name is derived as follows: ‘H refers to Heliothis, O open reading frame and Hoar sounds like the given second name of the student Hoa (TH Le) who determined the sequence.’ HOAR is predicted to contain a RING-finger domain and the gene appears to be somewhat unstable and shows a high degree of variation in a repeated region (20). Based on Hhpred it has a 96% probability of being a ubiquitin ligase. It is found in many group II alphabaculoviruses

Iap-3. Inhibitor of apoptosis-3. Although 5 lineages of iap genes have been identified in baculoviruses, the iap-3 lineage is the most well-characterized and is a powerful inhibitor of apoptosis in certain cell lines. It is not found in the AcMNPV genome, although related iap genes are present. This lack of iap-3 is likely compensated by the presence of p35, another apoptotic inhibitor. Members of the iap-3 lineage are found in Group I, II, GVs and hymenopteran NPVs. Iap-3 genes are closely related to iap genes of insects. OpMNPV IAP-3 is 57% identical to IAP from B. mori, indicating that the iap gene was likely captured by viruses on one or more occasions. In addition, iap from S. frugiperda has similar properties to IAP-3 in terms of its structure and function (21). For additional information, see Chapter 7.

Metalloproteinase. As described above, metalloproteinases are endopeptidases that contain divalent cations. Baculoviruses encode three distinct metalloproteinases, cathepsin, enhancin, and a stromelysin1-like metalloproteinase. Although cathepsin homologs are found most lepidopteran group I and II NPVs, they are only found in four GV genomes and are not present in the hymenopteran and dipteran viruses. However, there are other enzymes encoded in GVs that might compensate for the lack of cathepsin. One such enzyme is a metalloproteinase that has homologs in all sequenced GV genomes, but is not present in NPV genomes. They have about 30% amino acid sequence identity to a catalytic domain in a stromelysin1 metalloproteinase of humans and sea urchins. The GV enzyme lacks a signal peptide and a cysteine switch that maintains the other enzymes in an inactive form. The stromelysin1-like metalloproteinase from XcGV was characterized and found be capable of digesting proteins and was inhibited by metalloproteinase inhibitors (22). It is possible that the universal presence of metalloproteinase homologs in the GV genomes is involved in assisting in their viral transmission by facilitating the disintegration of cells after the GV replicative cycle is complete.

Nicotinamide riboside kinase 1 (NRK1). Orthologs of NRK1 are found in most group II NPVs and in at least 5 GVs. It plays a role in nicotinamide adenine dinucleotide (NAD+) synthesis. It phosphorylates nicotinamide riboside yielding nicotinate mononucleotide (23). Since PARG reverses the ADP-ribosylation of proteins by PARP and NRK1 is part of the nicotinamide adenine dinucleotide pathway, it is possible that the presence of PARG and NRK1 in many group II baculoviruses is indicative of their ability to manipulate these processes.

PARG. All sequenced Group II genomes encode homologs of Poly (ADP-ribose) glycohydrolase (PARG) (24, 25). PARG is the primary enzyme responsible for the catabolism of poly(ADP-ribose) in vivo (see PARP below). It catalyzes the hydrolysis of glycosidic (1’–2’) linkages in poly(ADP-ribose) to produce ADP-ribose (26). Therefore, whereas PARP stimulates a variety of processes (see below), PARG reverses the products of PARP. In HaSNPV, PARG (Ha100) was ODV associated (25). A deletion mutant of HaSNPV was similar to wt except the lethal time was longer and the LC50 was higher than wt (27).

PARP. A homolog of poly (ADP-ribose) polymerases (PARP) has only been reported in a single baculovirus genome, Anticarsia gemmatalis (AgMNPV), Ag31 (28) (29). PARP is an enzyme found in nuclei. It is activated by DNA strand breaks and signals enzymatic pathways involved in DNA repair. Upon detecting a single strand break, it binds to the DNA and uses NAD+ as a substrate to synthesize polymers of ADP-ribose on acceptor proteins that in turn act as signals for recruiting enzymes involved in DNA repair. It is also involved in telomere elongation, chromatin structure, and the transcription of a variety of genes involved in immunity, stress resistance, hormone responses, and the possible silencing of retroelements (30) (31). It may also be involved in the regulation of a mitochondrial protein that induces apoptosis (32). PARP is a caspase-3 substrate and its cleavage is used as a measure of apoptosis.

Protein tyrosine phosphatase-2. All group Group I alphabaculoviruses encode an ortholog of protein tyrosine phosphatase. The Group I viruses are divided into two major lineages and most of the viruses in one of these lineages encode another ptp gene called ptp-2. In addition, most Group II baculoviruses and at least two betabaculoviruses (GVs) also encode orthologs to ptp-2 (33). In OpMNPV, ptp-1 (op10) shows 60% aa sequence identity to AcMNPV PTP-1, but only ~20% identity to Op9 (PTP-2). PTP-2 is more closely related to a vaccinia and a human PTP with sequence identity of ~27% (34). The role of PTP-2 has not been investigated although the active site in OpMNPV PTP-1 was predicted to be inactive because the catalytic site had a W rather than a C in a critical amino acid (34).

Photolyase. Homologs of photolyase genes have been found in the genomes of Group II baculovirus that are members of a lineage that infects insects of the subfamily Plusiinae of the family Noctuidae (35-37). Orthologs are also found in some poxiviruses (38) including entomopox viruses (39). They have also been observed to be associated with mitotic structures (40). Photolyases are involved in the repair of DNA damage caused by ultraviolet light. Chrysodeixis chalcites NPV (ChchNPV) encodes two photolyase genes that are predicted to encode proteins with 45% amino acid sequence identity. When both were tested, only one copy showed photoreactivating activity (41). Transfection of egfp fusions of photolyase genes into T. ni cells resulted in fluorescence localized to chromosomes and spindles and other structures associated with mitosis. Baculovirus infection of the transfected cells caused fluorescence to localize to the virogenic stroma (40). It was observed that one of the ChchNPV binds a CLOCK protein and represses CLOCK/BMAL1- transcription affected the oscillation of embryonic mouse fibroblasts indicating that it may be involved in circadian clock regulation (42). The incorporation of an algal virus photolyase gene as a means to cause resistance to UV inactivation of AcMNPV has been described. However, although BV survival was increased after exposure to UV light, occluded virion survival was not affected (43).

Ribonucleotide reductase. Ribonucleotide reductase is a heterodimer composed of large and small subunits (RR1 and RR2, respectively). It is involved in the catalysis of ribonucleotides to deoxyribonucleotides as a pathway for providing nucleotides for DNA synthesis. Well-documented RR1 and RR2 genes have been reported in the genomes of three GVs, 10 distinct Group II NPVs, and a single Group I NPV (OpMNPV) (6). Two different RR2 genes have been reported for LdMNPV (18). Based on the phylogeny of baculovirus RR1 genes, it has been postulated that two different capture events resulted in baculoviruses obtaining this gene (1). One source was from a bacterium for the OpMNPV and LdMNPV RR1 gene lineage, whereas the other lineage (e.g., Spodoptera exigua MNPV (SeMNPV)) appears to have been derived from eukaryotes, most likely insects. The two RR2 genes from LdMNPV appear to be derived independently, one from each different source, rather than via gene duplication. No enzymology has been described for baculovirus RR, and it is not known whether they have enzymatic activity or how they integrate with or substitute for the homologous host enzymes.

Serpin. A sequence related to lepidopteran serpins was found in the genome of a baculovirus of Hemileuca sp., a member of the Saturniidae. It shows about 34% amino acid sequence identity to serpins from Manduca sexta and Bombyx mori suggesting that it was captured from a host insect (44). Serpins, ([underlined: ser]ine [underlined: p]rotease [underlined: in]hibitors), were named because of their ability to inhibit chymotrypsin-like serine proteases. No other baculoviruses have been reported to encode this gene.

Thymidylate kinase. A gene encoding an ortholog of Thymidylate kinase was observed in the genome of a GV pathogenic for Epinotia aporema (19). Thymidylate kinase is involved in adding a phosphate to thymidine 5’ monophosphate and converting it to thymidine 5’ diphosphate. It is important for the production of dTTP for DNA synthesis.

Trypsin-like. Although hymenopteran lack homologs of chitinase and cathepsin, they all encode a trypsin-like protein (e.g., Nese7) (45) that shows high levels of aa sequence identity (e.g., 50%) to insect trypsin-like homologs. It is possible that the presence of this enzyme compensates for the absence of chitinase and cathepsin and facilitates the release of virus from infected gut cells into the environment and to provide inoculum for the re-infection of other gut cells.

V-TREX (Viral three-prime repair exonuclease). A gene with homology to 3' to 5' exonucleases from other systems has been identified in three Group I NPVs, AgMNPV, CfMNPV and AnpeNPV. The enzyme from both AgMNPV and CfMNPV demonstrated to 3' to 5' exonucleolytic activity. It is thought that they may be involved in DNA repair (46, 47).

## References

1 Hughes, A.L. and R. Friedman, Genome-Wide Survey for Genes Horizontally Transferred from Cellular Organisms to Baculoviruses. Mol Biol Evol., 2003. 20: p. 979-8.
2 Paran, N., F.S. De Silva, T.G. Senkevich, and B. Moss, Cellular DNA ligase I is recruited to cytoplasmic vaccinia virus factories and masks the role of the vaccinia ligase in viral DNA replication. Cell Host Microbe, 2009. 6(6): p. 563-9.
3 Pearson, M.N. and G.F. Rohrmann, Characterization of a baculovirus-encoded ATP-dependent DNA ligase. J. Virol., 1998. 72: p. 9142-9149.
4 Boule, J.B. and V.A. Zakian, The yeast Pif1p DNA helicase preferentially unwinds RNA DNA substrates. Nucleic Acids Res, 2007. 35(17): p. 5809-18.
5 Lieber, M.R., The FEN-1 family of structure-specific nucleases in eukaryotic DNA replication, recombination and repair. Bioessays, 1997: p. 233-40.
6 Esteban, D.J., M. Da Silva, and C. Upton, New bioinformatics tools for viral genome analyses at Viral Bioinformatics - Canada. Pharmacogenomics, 2005. 6: p. 271-80.
7 Lin, T., R. Chang, C. Wei, and G. Lang, Characterization of the deoxyuridine triphosphatase gene of Ophiusa disjungens nucleopolyhedrovirus. Acta Virol, 2012. 56(3): p. 241-6.
8 Lepore, L.S., P.R. Roelvink, and R.R. Granados, Enhancin, the granulosis virus protein that facilitates nucleopolyhedrovirus (NPV) infections, is a metalloprotease. J Invertebr Pathol, 1996. 68(2): p. 131-40.
9 Hashimoto, Y., B.G. Cosaro, and R.R. Granados, Location and nucleotide sequence of the gene encoding the viral enhancing factor of the Trichoplusia ni granulosis virus. J. Gen. Virol., 1991. 72: p. 2645-2651.
10 Slavicek, J.M. and H.J. Popham, The Lymantria dispar nucleopolyhedrovirus enhancins are components of occlusion-derived virus. J Virol, 2005. 79(16): p. 10578-88.
11 Hayakawa, T., R. Ko, K. Okano, S. Seong, C. Goto, and S. Maeda, Sequence analysis of the Xestia c-nigrum granulovirus genome. Virology, 1999. 262: p. 277-297.
12 Popham, H.J., D.S. Bischoff, and J.M. Slavicek, Both Lymantria dispar nucleopolyhedrovirus enhancin genes contribute to viral potency. J Virol, 2001. 75(18): p. 8639-48.
13 Wang, P. and R.R. Granados, An intestinal mucin is the target substrate for a baculovirus enhancin. Proc Natl Acad Sci U S A, 1997. 94(13): p. 6977-82.
14 Toprak, U., S. Harris, D. Baldwin, D. Theilmann, C. Gillott, D.D. Hegedus, and M.A. Erlandson, Role of enhancin in Mamestra configurata nucleopolyhedrovirus virulence: selective degradation of host peritrophic matrix proteins. J Gen Virol, 2012. 93(Pt 4): p. 744-53.
15 Galloway, C.S., P. Wang, D. Winstanley, and I.M. Jones, Comparison of the bacterial Enhancin-like proteins from Yersinia and Bacillus spp. with a baculovirus Enhancin. J Invertebr Pathol, 2005. 90(2): p. 134-7.
16 Escasa, S.R., H.A. Lauzon, A.C. Mathur, P.J. Krell, and B.M. Arif, Sequence analysis of the Choristoneura occidentalis granulovirus genome. J Gen Virol, 2006. 87(Pt 7): p. 1917-33.
17 Thumbi, D.K., C. Beliveau, M. Cusson, R. Lapointe, and C.J. Lucarotti, Comparative Genome Sequence Analysis of Choristoneura occidentalis Freeman and C. rosaceana Harris (Lepidoptera: Tortricidae) Alphabaculoviruses. PLoS One, 2013. 8(7): p. e68968.
18 Kuzio, J., M.N. Pearson, S.H. Harwood, C.J. Funk, J.T. Evans, J. Slavicek, and G.F. Rohrmann, Sequence and analysis of the genome of a baculovirus pathogenic for Lymantria dispar. Virology, 1999. 253: p. 17-34.
19 Ferrelli, M.L., R. Salvador, M.E. Biedma, M.F. Berretta, et al., Genome of Epinotia aporema granulovirus (EpapGV), a polyorganotropic fast killing betabaculovirus with a novel thymidylate kinase gene. BMC Genomics, 2012. 13: p. 548.
20 Le, T.H., T. Wu, A. Robertson, D. Bulach, P. Cowan, K. Goodge, and D. Tribe, Genetically variable triplet repeats in a RING-finger ORF of Helicoverpa species baculoviruses. Virus Res, 1997. 49(1): p. 67-77.
21 Cerio, R.J., R. Vandergaast, and P.D. Friesen, Host Insect Inhibitor-of-Apoptosis SfIAP Functionally Substitutes for Baculovirus IAP but is Differentially Regulated by its N-terminal Leader. J Virol, 2010. 84: p. 11448-60.
22 Ko, R., K. Okano, and S. Maeda, Structural and functional analysis of the Xestia c-nigrum granulovirus matrix metalloproteinase. J Virol, 2000. 74(23): p. 11240-6.
23 Magni, G., A. Amici, M. Emanuelli, G. Orsomando, N. Raffaelli, and S. Ruggieri, Enzymology of NAD+ homeostasis in man. Cell Mol Life Sci, 2004. 61(1): p. 19-34.
24 Chen, X., W. IJkel, R. Tarchini, X. Sun, et al., The sequence of the Helicoverpa armigera single nucleocapsid nucleopolyhedrovirus genome. J Gen Virol, 2001. 82: p. 241-257.
25 Deng, F., R. Wang, M. Fang, Y. Jiang, et al., Proteomics analysis of Helicoverpa armigera single nucleocapsid nucleopolyhedrovirus identified two new occlusion-derived virus-associated proteins, HA44 and HA100. J Virol, 2007. 81(17): p. 9377-85.
26 Miwa, M., M. Tanaka, T. Matsushima, and T. Sugimura, Purification and properties of glycohydrolase from calf thymus splitting ribose-ribose linkages of poly(adenosine diphosphate ribose). J Biol Chem, 1974. 249(11): p. 3475-82.
27 Luo, S., Y. Zhang, X. Xu, M. Westenberg, et al., Helicoverpa armigera nucleopolyhedrovirus occlusion-derived virus-associated protein, HA100, affects oral infectivity in vivo but not virus replication in vitro. J Gen Virol, 2011. 92(Pt 6): p. 1324-31.
28 Oliveira, J.V., J.L. Wolff, A. Garcia-Maruniak, B.M. Ribeiro, et al., Genome of the most widely used viral biopesticide: Anticarsia gemmatalis multiple nucleopolyhedrovirus. J Gen Virol, 2006. 87(Pt 11): p. 3233-50.
29 de Castro Oliveira, J.V., F.L. de Melo, C.M. Romano, A. Iamarino, et al., Structural and phylogenetic relationship of ORF 31 from the Anticarsia gemmatalis MNPV to poly (ADP-ribose) polymerases (PARP). Virus Genes, 2008. 37: p. 177-84.
30 Tulin, A., N.M. Naumova, A.K. Menon, and A.C. Spradling, Drosophila poly(ADP-ribose) glycohydrolase mediates chromatin structure and SIR2-dependent silencing. Genetics, 2006. 172(1): p. 363-71.
31 Jagtap, P. and C. Szabo, Poly(ADP-ribose) polymerase and the therapeutic effects of its inhibitors. Nat Rev Drug Discov, 2005. 4(5): p. 421-40.
32 Yu, S.W., H. Wang, M.F. Poitras, C. Coombs, et al., Mediation of poly(ADP-ribose) polymerase-1-dependent cell death by apoptosis-inducing factor. Science, 2002. 297(5579): p. 259-63.
33 van Houte, S., V.I. Ros, T.G. Mastenbroek, N.J. Vendrig, K. Hoover, J. Spitzen, and M.M. van Oers, Protein Tyrosine Phosphatase-Induced Hyperactivity Is a Conserved Strategy of a Subset of BaculoViruses to Manipulate Lepidopteran Host Behavior. PLoS One, 2012. 7(10): p. e46933.
34 Ahrens, C.H., R. Russell, C.J. Funk, J.T. Evans, S.H. Harwood, and G.F. Rohrmann, The sequence of the Orgyia pseudotsugata multinucleocapsid nuclear polyhedrosis virus genome. Virology, 1997. 229: p. 381-399.
35 van Oers, M.M., E.A. Herniou, M. Usmany, G.J. Messelink, and J.M. Vlak, Identification and characterization of a DNA photolyase-containing baculovirus from Chrysodeixis chalcites. Virology, 2004. 330: p. 460-470.
36 Willis, L.G., R. Siepp, T.M. Stewart, M.A. Erlandson, and D.A. Theilmann, Sequence analysis of the complete genome of Trichoplusia ni single nucleopolyhedrovirus and the identification of a baculoviral photolyase gene. Virology, 2005. 338: p. 209-26.
37 Xu, F., J.M. Vlak, and M.M. van Oers, Conservation of DNA photolyase genes in group II nucleopolyhedroviruses infecting plusiine insects. Virus Res, 2008. 136: p. 58-64.
38 Bennett, C.J., M. Webb, D.O. Willer, and D.H. Evans, Genetic and phylogenetic characterization of the type II cyclobutane pyrimidine dimer photolyases encoded by Leporipoxviruses. Virology, 2003. 315(1): p. 10-9.
39 Afonso, C.L., E.R. Tulman, Z. Lu, E. Oma, G.F. Kutish, and D.L. Rock, The genome of Melanoplus sanguinipes entomopoxvirus. J Virol, 1999. 73(1): p. 533-52.
40 Xu, F., J.M. Vlak, A.P. Eker, and M.M. van Oers, DNA photolyases of Chrysodeixis chalcites nucleopolyhedrovirus are targeted to the nucleus and interact with chromosomes and mitotic spindle structures. J Gen Virol, 2010. 91: p. 907-14.
41 van Oers, M.M., M.H. Lampen, M.I. Bajek, J.M. Vlak, and A.P. Eker, Active DNA photolyase encoded by a baculovirus from the insect Chrysodeixis chalcites. DNA Repair (Amst), 2008. 7: p. 1309-18.
42 Biernat, M.A., A.P. Eker, M.M. van Oers, J.M. Vlak, G.T. van der Horst, and I. Chaves, A baculovirus photolyase with DNA repair activity and circadian clock regulatory function. J Biol Rhythms, 2012. 27(1): p. 3-11.
43 Petrik, D.T., A. Iseli, B.A. Montelone, J.L. Van Etten, and R.J. Clem, Improving baculovirus resistance to UV inactivation: increased virulence resulting from expression of a DNA repair enzyme. J. Invertebr. Pathol., 2003. 82: p. 50-56.
44 Rohrmann, G.F., M.A. Erlandson, and D.A. Theilmann, The genome of a baculovirus isolated from Hemileuca sp. encodes a serpin ortholog. Virus Genes, 2013.
45 Garcia-Maruniak, A., J.E. Maruniak, P.M. Zanotto, A.E. Doumbouya, J.C. Liu, T.M. Merritt, and J.S. Lanoie, Sequence analysis of the genome of the Neodiprion sertifer nucleopolyhedrovirus. J Virol, 2004. 78(13): p. 7036-51.
46 Slack, J.M. and M. Shapiro, Anticarsia gemmatalis multicapsid nucleopolyhedrovirus v-trex gene encodes a functional 3' to 5' exonuclease. J Gen Virol, 2004. 85(Pt 10): p. 2863-71.
47 Yang, D.H., J.G. de Jong, A. Makhmoudova, B.M. Arif, and P.J. Krell, Choristoneura fumiferana nucleopolyhedrovirus encodes a functional 3'-5' exonuclease. J Gen Virol, 2004. 85(Pt 12): p. 3569-73.