# 12 The AcMNPV genome: Gene content, conservation, and function

The Autographa californica nucleopolyhedrovirus (AcMNPV) was originally described in the early 1970s (1) and research on its genetics began later in that decade. This was stimulated by the facility with which the virus replicated in cells from Spodoptera frugiperda (2) and Trichoplusia ni (3). Subsequently, this led to the development of technology for the deletion of genes (4, 5), and allowed for targeted studies on the function of specific genes, particularly if the deletion or mutation of the target gene was not lethal to the virus. The publication of the genome sequence of AcMNPV (6) was a landmark in the investigation of this virus because it put all previous and future investigations into context. It also revealed genes that are shared with other organisms, and provided the basis for understanding baculovirus diversity. Subsequently, the development of the bacmid system, which allowed for the production of recombinants via transposition of recombinant plasmids into the AcMNPV genome incorporated into a bacterial artificial chromosome, allowed for manipulation of the whole AcMNPV genome in bacteria (7). The adaptation of this technology to making targeted deletions provided a method for constructing baculovirus gene knockouts in bacteria that could then be investigated via transfection into insect cell lines (8). The modification of this technology using a lambda red recombinant system (9) allowed for the more efficient production of knockouts (10). This has resulted in a proliferation of studies on AcMNPV essential genes that were previously difficult to investigate because knockouts were lethal and they could not be readily generated without the production of complementary cell lines. With bacmid knockouts, the function of the target gene can be inferred from the examination of cells transfected with DNA of the mutant. The adaptation of similar bacmid systems for other baculovirus genomes has allowed for parallel studies on these viruses. Concomitant with the development of techniques for investigating gene function has been a proliferation of complete genome sequence data for many baculoviruses. Because of the widespread use of AcMNPV, not only for fundamental investigations on gene function, but also because of its use as an expression vector, I have attempted to annotate the AcMNPV genome in terms of understanding the function of each of the genes.

## Adjustments to the AcMNPV genome sequence: There are approximately 150 orfs

Several regions of the genome of the AcMNPV C-6 strain have been resequenced by one or more laboratories. This, in combination with genome sequences of variants of AcMNPV that have become available, has revealed revisions that should be incorporated into the sequence. The following summarizes the physical corrections to the AcMNPV genome that have been described. The original orfs Ac20/21, 58/59, 106/107 and 112/113 (6) should be combined into single orfs. Ac20/21 was resequenced when it was implicated in actin rearrangement (11), and all four of these regions were resequenced as a comparison of the AcMNPV and RoMNPV genomes (12). In addition, resequencing also indicated that Ac17, 52, 131, and 143 are longer than originally reported (12). The total number of orfs reported for AcMNPV was originally calculated to be 154; this adjustment reduces it by 4. However, the discovery of lef-10 (Ac53a), which was missed in the original annotation because of its significant overlap with the 5' region of an adjacent gene (Ac54) (13), adds an additional orf. Therefore, there appear to be 151 orfs present in the genome based on the original criteria of an orf comprising 50 amino acids. However, Ac85 (53 aa) is only found in two other NPVs that are variants of AcMNPV (PlxyNPV) (14) and RoMNPV (12). Two orfs, Ac97 (56 aa) and Ac140 (60 aa), are only present in AcMNPV. Of these three orfs, only Ac97 was predicted to be preceded by transcriptional regulatory sequences (6). Although these three orfs may not be valid, others may be present that have not yet been detected. Therefore, it would appear that there are 'about' 150 orfs in the AcMNPV genome.

In this review, I have attempted to include pertinent information on the function of all the orfs present in the AcMNPV genome. This is not an exhaustive review, but an attempt to infer function from either actual experimentation on the AcMNPV gene or to homology from related viruses. A significant proportion of the data included comes from the Bombyx mori NPV (BmNPV). It is closely related to AcMNPV and is the second most studied NPV and a complete study based on the generation of BmNPV bacmid knockouts of all its open reading frames has been described (15).

Table 1 lists all the genes that have been named in the AcMNPV genome followed by the orf number. It cannot be emphasized enough how important it is to incorporate both orf numbers and the AcMNPV homolog (if present) into any description of a baculovirus gene no matter which baculovirus it is from. Without this reference, it is difficult, if not impossible, to put reports into any sort of perspective. Following the index is a review of what I could find regarding all the genes in the AcMNPV genome. This is not a complete review of these genes but focuses particularly on AcMNPV. When a report of the homolog from another virus is relevant, that material is also included.

Table 1.

Index to named AcMNPV genes/gene products

ARIF1 (Actin rearranging factor1) | Ac20/21
Alkaline nuclease | Ac133
BRO (Baculovirus repeated orf) | Ac2
BV/ODV-E26 | Ac16
BV/ODV-C42 | Ac101
Calyx, polyhedron envelope | Ac131
Cathepsin | Ac127
ChaB homolog | Ac59
ChaB homolog | Ac60
Cg30 | Ac88
C42 | Ac102
Chitinase | Ac126
Conotoxin like (Ctl) | Ac3
Desmoplakin-like | Ac66
DBP (DNA binding protein) | Ac25
DnaJ domain protein | Ac51
DNA polymerase | Ac65
EGT | Ac15
ETL (PCNA) | Ac49
ETM | Ac48
ETS | Ac47
Exon-0 | Ac141
F (fusion protein homolog) | Ac23
FGF (fibroblast growth factor) | Ac32
FP (few polyhedra) | Ac61
Fusolin (gp37) | Ac64
GP16 | Ac130
GP37 | Ac64
GP41 | Ac80
GP64 | Ac128
Gta (global transactivator) | Ac42
Hcf-1 (host cell factor 1) | Ac70
Helicase, p143 | Ac95
He65 | Ac105
Homologous regions | Hrs (see end of chapter)
Iap-1 | Ac27
Iap-2 | Ac71
Ie1 | Ac147
Ie0 | Ac147-0
Ie2 | Ac151
J domain | Ac51
Lef1 | Ac14
Lef2 | Ac6
Lef3 | Ac67
Lef4 | Ac90
Lef5 | Ac99
Lef6 | Ac28
Lef7 | Ac125
Lef8 | Ac50
Lef9 | Ac62
Lef10 | Ac53a
Lef11 | Ac37
Lef12 | Ac41
Me53 | Ac139
MTase (methyl transferase) | Ac69
Nudix | Ac38
ODV-E18 | Ac143
ODV-E25, p25, 25k | Ac94
ODV-EC27 | Ac144
ODV-E56 | Ac148
ODV-E66 | Ac46
P6.9 | Ac100
P10 | Ac137
P11 | Ac145
P12 | Ac102
P15 | Ac87
P18 | Ac93
P24 | Ac129
P26 | Ac136
P33 (sulfhydryl oxidase) | Ac92
P35 | Ac135
P40 | Ac102
P43 | Ac39
P45, p48 | Ac103
P47 | Ac40
P49 | Ac142
P74, pif | Ac138
P94 | Ac134
P143 (helicase) | Ac95
PCNA | Ac49
Pe38 | Ac153
PEP polyhedron envelope protein | Ac131
Pif-1 | Ac119
Pif-2 | Ac22
Pif-3 | Ac115
Pif-4 | Ac96
Pif-5 | Ac148
Pif-6 | Ac68
PK1 (Protein kinase 1) | Ac10
PK2 (Protein kinase 2) | Ac123
PKIP (Protein kinase interacting factor) | Ac24
PNK polynucleotide kinase | Ac33
PNK/PNL polynucleotide kinase/ligase | Ac86
Polyhedrin | Ac8
Pp31;39K | Ac36
Pp34, polyhedron envelope | Ac131
Pp78/83;orf1629 | Ac9
Protein tyrosine phosphatase (ptp) | Ac1
SOD superoxide dismutase | Ac31
Sulfhydryl oxidiase, sox | Ac92
TLP telokin-like | Ac82
TRAX-like | Ac47
Ubiquitin | Ac35
VLF-1 very late factor 1 | Ac77
Vp39, capsid | Ac89
Vp80, vp87 | Ac104
Vp91 | Ac83
Vp1054 | Ac54
19K | Ac96
38K | Ac98
49K | Ac142

## Annotation of the AcMNPV genome

Below is an annotation of the orfs in the AcMNPV genome based on their orf number from (6). An asterisk (*) indicates a core gene with homologs found in all sequenced baculovirus genomes. The orf size in amino acids, followed by the molecular mass in kDa is indicated after each orf as reported by (6, 12). The same information is also included for the BmNPV (16) and Heliocoverpa armigera (HaSNPV) (17) orthologs of these genes. Both AcMNPV and BmNPV are Group I alphabaculoviruses whereas HaSNPV is a group II alphabaculovirus and lacks some of the genes found in AcMNPV and BmNPV but also has some additional genes. The distribution of the genes is from analyses completed in early 2008; therefore, the viral distribution reflects the genomes available at that time. The survey of information regarding each gene was updated in late 2013.

### Ac1 (168aa:19.3kDa), (Bm130:168aa:19.3kDa), (protein tyrosine phosphatase (ptp); baculovirus phophatase (bvp)).

Ac1 homologs are present in the genomes of all lepidopteran Group I NPVs, but not those of other baculoviruses. Closely related orfs are found in a variety of invertebrates, e.g., Drosophila (E = 7e-30) and vertebrates, e.g., human (E = 2e-27). It is expressed from a late promoter (18). It was originally identified because of its relatedness to protein tyrosine phosphatases and its ability to dephosphorylate proteins at ser, thr and tyr residues (19). However, it was later found that Ac1 is an RNA 5'-triphosphatase and hydrolyzes the gamma phosphate of triphosphate-terminated poly(A) and also hydrolyzes ATP to ADP and GTP to GDP (20, 21). The crystal structure has been determined (22). Ac1 is predicted to have one of the same enzymatic activities of LEF-4 (Ac90) that is involved in preparing RNA for cap formation. Although deletion is not lethal, mutants are partially defective in occluded virus production in Sf-21, but not Tn-368 cells (23). During the final larval stages many Lepidoptera disperse (wander) probably as an evolutionary mechanism to spread the population, reduce predation, and find an optimal location for pupation. Baculovirus infection appears to be capable of enhancing this behavior possibly as a mechanism of spreading the virus. It was found that BmNPV deleted for the tyrosine phosphatase gene failed to undergo this enhanced wandering behavior (24). It is not clear whether the enzymatic activity of this protein is related to this observation. One report indicated that it was not required for BmNPV infected B. mori larvae (25), whereas the other suggested that it was required for the in AcMNPV infected S. exigua larvae (26). Although not reported to be associated with ODV by proteomic analysis, it was found in BV preparations (27).

### Ac2 (328aa:38.8kDa), (Bm131:349aa:40.1kDa, Bm22:317aa:35.4kDa, Bm80:239:27.5kDa, Bm81:318aa:35.9kDa, Bm132:241aa:27.8kDa), (Ha59:244aa:28.2,Ha60:527aa:59.7kDa,Ha105:501aa:58.3kDa) (Baculovirus repeated orf—BRO).

Derivation: In American inner-city dialect 'bro' means 'brother', but not necessarily a close relationship.

Homologs of Ac2 have a widespread distribution in lepidopteran NPVs and GVs and are also found in the dipteran, but not hymenopteran NPV genomes. Related orfs are also found in double-stranded DNA phage, prokaryotic class II transposons, and a variety of DNA viruses pathogenic for insects, including entomopox viruses, iridoviruses and ascoviruses (28). Twenty-three copies of bro genes have been reported in a Heliothis virescens ascovirus genome sequence (29). Although there is only one copy of the bro gene in AcMNPV, the number can vary in different baculoviruses from none in the closely related Rachiplusia ou MNPV — its orfs are 96% identical in sequence to AcMNPV (12), two in the more closely related PlxyNPV (14) (orfs are 98.5% identical to AcMNPV), to up to 16 copies in LdMNPV (30). AcMNPV Ac 2 deletion mutants are viable, but some differences in polyhedron production in infected cells were noted (28). One of the major differences in gene content between BmNPV and AcMNPV is the presence of 3-5 copies of bro genes in BmNPV vs. a single copy in AcMNPV (16). The BmNPV bro genes are present in three locations with duplicate genes in two of the locations. In contrast, another BmNPV strain only shows 3 copies of the gene, one at each of the three locations (31, 32). This suggests that duplication/loss of these genes might be common. In the strain with five genes, individual mutants of four of the genes were isolated in BmNPV, but a mutant of one gene (bro-d) could not be isolated. Also, a double mutant of bro-a and bro-c could not be produced, suggesting that they complement an essential function and that bro-d has a unique essential function (33). BmNPV BRO proteins have DNA binding activity (34), and all the BmNPV bro genes appeared to be expressed as early genes and are distributed in both the nucleus and cytoplasm (33). One of the bro gene products was found to interact with laminin, a glycoprotein that is a major constituent of the basal lamina and is involved in cell attachment (35).

### Ac3 (53aa:5.6kDa) (Conotoxin-like (ctl) genes).

Conotoxins are small disulfide-rich ion channel antagonists isolated from snails (genus Conus) (36). Homologs of ctl are found in about half of the sequenced Group I and Group II lepidopteran NPV genomes and two GVs (Xcni- and HaGV). Although in AcMNPV a single ctl gene is present, several other viruses, e.g., OpMNPV and LdMNPV, encode two ctl genes of different lineages (ctl-1 and ctl-2). Homologs are found in the Amsacta moori entomopoxvirus (E = 0.006), a few mosquito species, a funnel web spider, a wasp, and a bacterium. The EPV (A. moori gene falls within the baculovirus ctl-2 lineage. In a study examining the AcMNPV ctl (ctl-1) gene, no differences in mortality, motility, or weight gain were observed when either neonate or late instar Spodoptera frugiperda larvae were infected with an AcMNPV mutant deleted for ctl-1, compared with infection with wt virus (37).

### Ac4 (151aa:17.6kDa), (Bm133:151aa:17.7kDa).

Homologs of Ac4 are found in all Group I, three group II, and two GV genomes, but not in other lineages. Ac4/Bm133 is likely to be nonessential because when it was deleted the virus appeared normal (15, 38, 39).

### Ac 5 (109aa:12.4kDa), (Bm134:109aa:12.4kDa).

Homologs of Ac5 are found in the genomes all Group I (except AnpeNPV) NPV genomes. It is associated with the AcMNPV PIF complex (40). Ac5/Bm134 is likely to be nonessential because when Bm134 was deleted, the virus appeared normal (15, 24).

### *Ac6 (210aa:23.9kDa), (Bm135:210aa:23.8kDa) (Ha117:241aa:27.8kDa)(Lef-2).

LEF-2 is a DNA primase accessory factor and is encoded by all baculovirus genomes. It interacts with LEF-1 (41), the baculovirus DNA primase. It has homology to the large subunit of DNA primase in several archaea. It is required for transient DNA replication (42, 43). Based on limited amounts of DNA synthesis by a lef-2 bacmid knockout in transfected cells, it was suggested that Lef-2 is not required for the initiation of DNA replication. This was in contrast to a bacmid with the helicase gene deleted that showed no synthesis (44). However, the transfected DNA is likely nicked and therefore the ends of the nicks could act as primers, resulting in limited amounts of leading strand DNA synthesis in the absence of an active primase complex. Elution profiles of LEF-1 and LEF-2 from ssDNA cellulose and DEAE resin, suggested that LEF-2 may bind to both DNA and LEF-1 (45). LEF-2 mutants have been characterized that appear to affect very late transcription, indicating that it may have roles in both replication and transcription (46). In addition, BmNPV LEF-2 was shown to activate late transcription (47). It is an essential gene as AcMNPV or BmNPV bacmids deleted for lef-2 were unable to produce infectious virus (15, 44).

### Ac7 (201aa:23.6kDa) (Orf 603).

This gene is only found in three baculovirus genomes in addition to AcMNPV, including ClbiNPV, PlxyNPV and RoMNPV. Deletion from AcMNPV did not affect replication in cell culture or in T. ni larvae (48).

### Ac8 (245aa:28.6kDa), (Bm1:245aa:28.8kDa) (Ha1:245aa: 26.7kDa) (polyhedrin, occlusion body protein).

Homologs of polyhedrin are found in all baculovirus genomes, except for that of the dipteran virus (CuniNPV). Surprisingly, CuniNPV has an occlusion body protein unrelated and about three times as large as polyhedrin of other baculoviruses (49, 50). Because of unexpected patterns of phylogeny of AcMNPV polyhedrin, it has been suggested that it is a chimera derived from both Group I and II sequences (51). It is generally thought that polyhedrin serves to stabilize baculovirus virions in the environment allowing them to persist indefinitely. The polyhedrin gene is nonessential in cell culture, and occlusion-positive and negative plaques can be readily be distinguished. This, in combination with the strength of the polyhedrin promoter, led to the use of the polyhedrin locus as the site for the production of recombinant baculoviruses (4, 5). The crystal structure of AcMNPV polyhedra has been described (52).

### Ac9 (543aa:60.7kDa), (Bm2:542aa:60.9kDa) (Ha9:413aa:45.9kDa), (pp78/83, Orf1629).

Homologs of pp78/83 are found in all lepidopteran NPV (I and II) genomes. It is an essential gene. Because it is located adjacent to the polyhedrin gene, it was originally manipulated via complementation to elevate the frequency of obtaining recombinant baculoviruses at the polyhedrin locus (53). It is phosphorylated (54) and is a structural protein located at one end of nucleocapsids (54, 55). Ac9 is a Wiskott-Aldrich syndrome protein (WASP)-like protein involved in nuclear actin assembly during the baculovirus infection that leads to movement of virions through the cytoplasm of the infected cell (56, 57).

### Ac10 (272aa:32kDa), (Bm3:275aa:32.4kDa) (Ha10:267aa:31.5kDa), (Protein kinase-1 (PK-1)).

Homologs of pk-1 are found in lepidopteran NPV and GV genomes, but not in other lineages. AcMNPV PK-1 shows significant relatedness to some insect orfs, e.g., Anopheles gambiae (E = 3e-18). Purified PK-1 was able to phosphorylate histone substrates (58). A bacmid with a knockout of pk-1 produced no viral progeny, although DNA replication was unaffected. It was also found that the kinase catalytic domain was required for infectivity. Cells transfected with the mutant bacmids showed extensive arrays of tubular structures that appeared to lack DNA suggesting that the phosphorylation of one or more proteins was required for capsid morphogenesis (59). Ts mutants characterized for defects in very late gene expression contained mutations in pk-1 (60). In addition, inactivation of pk-1 mRNA using DNAzyme technology caused a reduction in the expression from the polyhedrin promoter (61). PK-1 also may be associated with a very late transcription complex and be involved in the phosphorylation of LEF-8 (62). Purified PK1 of SpltNPV-I was found to bind to the polyhedrin promoter, suggesting that it might act as a very late gene transcription factor (63).

### Ac11 (340aa:40.1kDa), (Bm4:340aa:39.8kDa).

Homologs of Ac11 are found in all lepidopteran Group I NPV and in one Group II (LdMNPV) genomes, but not in other lineages. Ac11/Bm4 is likely to be nonessential because when Bm4 was deleted, the virus appeared normal (15).

### Ac12 (217aa:25.4kDa).

Homologs of Ac12 are found in only three additional lepidopteran NPVs, including PlxyNPV, RoMNPV and LdMNPV. Analysis by HHpred (64) predicts that it contains an F-box domain that is involved in a ubiquitin pathway. It shows limited similarity to the tryptophan repeat gene family proteins of Amsacta moorei entomopoxvirus (E = 0.12) (see also Ac30).

### Ac13 (327aa:38.7kDa), (Bm5:331aa:39.3kDa)(Ha123:385aa:44.5kDa).

Homologs of Ac13 are found in all Group I, II, and GV genomes, but not in other lineages. Analysis by HHpred (64) predicts that it contains coiled-coil regions and has some structural similarity to fibrinogen and borealin, a chromosomal passenger protein that is involved in the stability of mitotic spindles. Ac13/Bm5 is likely to be nonessential because when Bm5 was deleted, the virus appeared normal (15). In addition Bm5 appears to encode a late expressed protein not associated with BV or ODV (65).

### *Ac14 (266aa:30.8kDa), (Bm6:270aa:31.1kDa), (Ha124:245aa:29kDa)(Lef-1, DNA primase).

LEF-1 is a core gene present in all baculovirus genomes. Purified LEF-1 has DNA primase activity (45). It interacts with Ac6 (LEF-2) (41), the baculovirus DNA primase accessory factor and is required for transient DNA replication (42, 43). Lef-1 is likely an essential gene as a deletion/insertion mutant in the BmNPV homolog (Bm6) could not be isolated (15, 66).

### Ac15 (506aa:57kDa), (Bm7:506aa:57.0kDa), (Ha126:515:58.9kDa), EGT.

Ac15 encodes ecdysteroid UDP-glucosyltransferase (67) and homologs are found in all Group I, II, and most GV genomes, but not in other lineages. Homologs are found in a variety of insects, e.g., B. mori (E = 3e-50). The function of EGT is to block molting and pupation in infected larvae by catalyzing the transfer of glucose from UDP-glucose to ecdysteroids, thereby inactivating these insect molting hormones (68, 69). This is thought to prolong the feeding stage of infected larvae, thereby allowing the virus to replicate over a longer period in larger larvae, resulting in a higher yield of virus. AcMNPV and BmNPV mutants in which the egt gene is inactivated are viable (69) but their survival time is reduced (39, 70). Spontaneous deletions of the egt gene commonly occur in cell culture (71).

### Ac16 (225aa:25.9kDa), (Bm8:229aa:26.2kDa) (BV/ODV-E26).

Homologs of Ac16 are found in all lepidopteran Group I NPV genomes, but not in other lineages. Ac16 interacts with fp25 (Ac61), forms a complex with cellular actin (72) and is palmitoylated (73). It was found to be associated with the envelopes of both BV and ODV and was called BV/ODV-E26, and was also identified as being associated with ODV by mass spectrometry analysis (74). However, in BmNPV, the homolog of AcMNPV Ac16 (Bm8) was not identified as a virion structural protein (75). It was suggested that the difference in the results was due to the source of the antibody (76). In BmNPV, Bm8 directly interacts with IE-1 (77). Similar observations were made in AcMNPV with Ac16 interacting with both IE-1 and IE-0 (78). In addition, Bm8 was found to interact with cellular membrane-bound proteins or secreted proteins (79). A mutant, in which AcMNPV orf16 (called DA26) was insertionally inactivated was viable and showed no difference from wt in T. ni or S. frugiperda cells or larvae (80). Initial attempts at isolation of null mutants of BmNPV (Bm8) were not successful, but a C-terminal deletion mutant was viable (75), although this mutant was unable to produce BV titers as high as wt. However, a bacmid deleted for Bm8 was viable (15). It was also found that Bm8 appears to inhibit occlusion body production in middle silk glands and its deletion accelerated the death of infected insects (39). In AcMNPV, deletion of Ac16 resulted in a delay in full levels of DNA synthesis and BV production in one study (81), but had lesser effects in another (78). Analysis by HHpred (64) predicts that it contains a coiled-coil region.

### Ac17 (209aa:23.9kDa), (Bm9:210aa:24.1kDa), (Ha128:266aa:30.4kDa).

Homologs of Ac17 are found in all Group I and II (except TnSNPV and ChchNPV) NPV genomes. It is an early expressed gene with a product of about 19 kDa that localizes to the cytoplasm (82). A homolog of Ac17 in HearNPV (He128) is expressed late and was found in the cytoplasm (83). Deletion of Ac17 did not affect DNA synthesis, although BV production was reduced by up to a factor of 10 to 100 (81). Deletion of both Ac16 and Ac17 was similar to the Ac17 deletion although there were more significant delays for DNA replication and BV titers to reach levels similar to the Ac17 deletion alone (81). Similar results were reported for a BmNPV bacmid knock out. In addition, the mutant BmNPV took significantly longer to kill larvae and required higher titers BV to achieve an LD_50_ (84). The predicted size of Ac17 is longer than previously reported (12).

### Ac18 (353aa:40.9kDa), (Bm10:356aa:41.5kDa).

Homologs of Ac18 are found in all Group I and II NPV genomes. An AcMNPV bacmid deleted for Ac18 was infectious with an LD50 in T. ni larvae similar to wt, but took somewhat longer to kill larvae than wt (85).

### Ac19 (108aa:12.2kDa), (Bm11:110aa:12.5kDa), (Ha115:129aa:15.3kDa).

Homologs of Ac19 are found in all Group I and most group II NPVs. Ac19 is likely to be nonessential because when it a BmNPV Bm11 deletion was viable (15, 39).

### Ac20/21 (417aa:47.7kDa), (Bm12:440aa:50.0kDa), (Ha131: 265aaa:30.4kDa)(arif-1).

This region has been resequenced in AcMNPV strains C6 and also in strains E, E2, and L1, and in all cases it was found that Ac20 and 21 are a single orf (11), see also (12). In addition, these two orfs are combined as a single orf in several closely related viruses. Homologs of arif-1 are present in all Group I and most Group II genomes. AcMNPV orf20/21 is called actin-rearrangement-inducing factors (arif-1). It is expressed as an early gene and transfection of a plasmid containing this gene into Tn-368 cells is able to induce actin rearrangement (86). Arif-1 was found to colocalize with F-actin at the plasma membrane and deletion mutants showed a loss of actin concentration at the plasma membrane. Deletions of the C-terminal half of the gene or insertion of the LacZ gene near the center of the orf resulted in constructs that showed no significant loss of infectivity in Tn-368 or Sf cells (11). Analysis by HHpred (64) predicts that Ac21 has an extensive region that resembles structures found in the largest subunit of RNA polymerase II, fibrinogen, and rhodopsin.

### *Ac22 (382aa:43.8kDa), (Bm13:382aa:43.8kDa), (Ha132:383:44.5kDa) (PIF-2).

This gene is a member of the per os infectivity factor (87) gene group. These genes can be deleted and the mutant are still infectious for cultured cells, but are not orally infectious for insects (88). It is present in all baculovirus genomes and is also present in a nudivirus genome (89). For more information see Ac138 (p74) and Chapter 3.

### Ac23 (690aa:79.9kDa), (Bm14:673aa:78.0kDa), (Ha133:677aa:78.2kDa), F (Fusion) protein.

Ac23 is a homolog of the predicted fusion protein (F) of Group II lepidopteran NPVs, GVs, and the dipteran virus (CuniNPV). Homologs are found in all baculoviruses except the hymenopteran viruses. In Group II viruses such as LdMNPV and HaSNPV, Ac23 homologs (ld130, Ha133) encode low pH-activated fusion proteins. In Group I viruses, they appear to be inactive as fusion proteins and have been replaced by gp64, which is not found in the Group II viruses, GVs, or hymenopteran or dipteran viruses. Orthologs of the F gene are also found as the env gene of insect retroviruses (90), and are also present in some insect genomes (91). They also appear to be related to the fusion (F) proteins of the paramyxoviridae (see Chapter 2). Although inactive in Group I viruses, the Acorf23 homolog is glycosylated and associated with the envelope of BV and with the membranes of OpMNPV-infected cells (92). In AcMNPV, Ac23 is also associated with BV membranes and its deletion from the genome results in infectious virus, but the time to kill larvae was somewhat extended (10). Ac23 was found to be associated with ODV as was the homolog in CuniNPV (74, 93).

### Ac24 (169aa:19.2kDa), (Bm15:169aa:19.4kDa), Protein kinase interacting protein (PKIP).

Homologs are found in all Group I and II NPV genomes. This gene product was found to interact with AcMNPV protein kinase I (see Ac10) in a yeast two-hybrid assay. It stimulates PK-1 activity in vitro. PKIP appears to be essential as attempts to isolate a deletion mutant were unsuccessful (94). Ts mutants in PKIP are defective in very late transcription (95). BmNPV bacmids deleted for Bm15 were viable, but the infection spread slower than wt in cultured cells (15).

### Ac25 (316aa:36.6kDa), (Bm16:317aa:36.7kDa),(Ha25:324aa:37.6kDa), DNA binding protein (DBP).

Ac25 encodes a single-stranded DNA binding protein called DBP. Homologs are found in all sequenced baculovirus genomes, except that of the dipteran (CuniNPV) (although an orf is present with ~50% identity over 22 aa) and in some instances multiple copies of the dbp gene are present. It has properties similar to the other baculovirus SSB, LEF-3 (Ac67), in that it interacts with itself and is capable of both unwinding and annealing DNA (96). It is an essential gene, as bacmids lacking Ac25 are noninfectious and appear to produce defective nucleocapsids. Although not a virion structural protein, DBP exhibits a tight association with subnuclear structures, suggesting that it is a component of the virogenic stroma (96), and when DBP was deleted from an AcMNPV bacmid, cells transfected with this construct appeared to lack a virogenic stroma. This suggested that dbp is required for the production of nucleocapsids and the virogenic stroma (97).

### Ac26 (129aa:14.6kDa), (Bm17:129aa:14.5kDa), Ha26:133aa:15kDa).

Homologs of Ac26 are found in the genomes all Group I, and most Group II NPV genomes. Bm17 is expressed as a late gene and is localized to both the nucleus and cytoplasm (98). When Bm17 was deleted from a BmNPV bacmid, the virus was viable, but the infection spread slowly in cell culture (15).

### Ac27 (286aa:33.3kDa), (Bm18:292aa:34.0kDa), iap-1.

Ac27 is a member of the inhibitor of apoptosis (iap) gene family. Up to 5 iap homologs are found in baculovirus genomes (99), however AcMNPV has two copies, iap-1 and -2. Unlike iap-2, which is found in both Group I and II NPVs, iap-1 appears to be confined to Group I lepidopteran NPVs and is a member of a lineage distinct from the other iap homologs. Deletion mutants of iap-1 were similar to wt in their replication in cells lines and larvae of T. ni and S. frugiperda. However, when they were co-infected with wt virus in Tn-368 (but not Sf-21) cells, the mutants appeared to out compete wt virus (100). Evidence suggested that transfection of AcMNPV iap-1 into T. ni cells suppressed apoptosis by HearNPV infections, although a recombinant HearNPV expressing iap-1 also suppressed apoptosis, BV production was not rescued (101). In another investigation in EppoMNPV, The iap-1 gene was able to delay apoptosis onset caused by inducing agents such as actinomycin but was not able to prevent apoptosis upon prolonged exposure of the cells to the inducer (102). In another study, transient expression of iap-1 form a variety of viruses induced apoptosis and it was suggested that this might facilitate dissemination of the virus (103).

### Ac28 (173aa:20.4kDa), (Bm19:173aa:20.3kDa), (Ha24:187aa:22.2kDa), Lef-6.

Homologs of lef-6 are found in the genomes of all lepidopteran NPVs and GVs. It was originally identified because it was required for transient transcription of late genes (104). A bacmid deleted for lef-6 was infectious, but the virus was severely compromised. The major effect appeared to be reflected in a delay in the onset of late transcription (105). Using the HHpred program (64), AcMNPV LEF-6 showed a 68% probability of being related to the RNA binding domain of the mRNA export factor TAP (106).

### Ac29 (71aa:8.6kDa), (Bm20:71aa:8.6kDa), (Ha23:67aa:8.3kDa).

Homologs of Ac29 are found in all Group I and most Group II and GV genomes. A BmNPV bacmid deleted for Bm20 was viable (15).

### Ac30 (463aa:54.7kDa), (Bm21:472aa:55.8kDa).

Homologs of Ac30 are present in the genomes of all Group 1 NPVs. It has homology to a family of genes that encode tryptophan repeat gene family proteins (see also Ac12) that are also found in entomopox viruses. e.g., Melanoplus sanguinipes entomopoxvirus (E = 1e-11). These proteins contain 3 to 12 copies of a 23-amino acid sequence containing tryptophan, leucine and isoleucine residues (107). Ac30 is likely to be nonessential because when the ortholog (Bm21) was interrupted by insertional/deletion mutagenesis in BmNPV, the virus appeared to be normal, although it resulted in a longer survival time suggesting that the mutant was less virulent that wt (108).

### Ac31 (151aa:16.2kDa), (Bm23:151aa:16.3kDa), SOD.

Ac31 has homology to super oxide dismutase (109). Homologs are found in the genomes of almost all lepidopteran baculovirus genomes (it appears to be absent only in EppoNPV, a member of Group II, and SpliGV). It has a high degree of similarity to SOD from a variety of insects, including B. mori (E = 8E-49). Insect hemocytes are phagocytic cells similar to neutrophils and can destroy invading pathogens by the production of superoxide (110). Superoxide can be inactivated by SOD by converting it to hydrogen peroxide, which is also toxic, but can itself be inactivated with catalase yielding water and O_2_. Many baculoviruses may infect hemocytes and in this manner can spread an infection throughout an insect. The expression of viral SOD might mitigate the effects of superoxide production by hemocytes. An enzymatic activity could not be confirmed for AcMNPV SOD and AcMNPV deleted for sod replicated normally in cultured cells and insect larvae. The sod-deleted viruses showed no reduction in replication when grown in the presence of paraquat, a superoxide anion inducer (109). In one study, deletion of the sod gene from BmNPV (Bm23) indicated that it was essential for replication in BmN cells (111), however, another report indicated that a Bm23-deleted bacmid was viable (15).

### Ac32 (181aa:20.6kDa), (Bm24:182aa:20.8kDa), (Ha113:301aa:34.4kDa) fgf.

Ac32 has homology to fibroblast growth factor (FGF). Orthologs are found in the genomes of all lepidopteran baculoviruses and may reflect several independent lineages. AcMNPV fgf is most closely related to a non-baculovirus gene in D. melanogaster called branchless (E = 3e-24). In contrast, a Group II fgf homolog from LdMNPV is less closely related to the insect homologs (e.g. D. melanogaster branchless E = 2e-10) and the GV homologs show only limited similarity to NPV fgf homologs (e.g., AcMNPV vs CpGV FGFs = ~10% identity). It has been suggested all of the NPV fgfs are monophyletic, however the possibility of at least two capture events of fgf in the GVs has not been ruled out (112). AcMNPV FGF is a secreted protein that stimulates insect cell motility (113). In BmNPV, the FGF homolog is glycosylated, which is essential for its (114, 115) and binds to an insect receptor of FGF/branchless called breathless (114). Although the deletion of fgf in AcMNPV showed no differences from wt on cultured cells (116), the time of death was delayed when fed to two insect species (117). Similar results were observed for a BmNPV fgf deletion (118). It has been suggested that FGF may play a role in dissemination of the virus within the host insect (117). Recent evidence suggests that vFGF initiates a cascade of events that may accelerate the establishment of systemic infections. This involves two processes. vFGF from virus infected midgut cells diffuse through the basal lamina and attract tracheal cells so that they are adjacent to infected midgut cells but separated by the basal lamina. vFGF then activates FGF receptors located on the tips of tracheal cells. This leads to the activation of matrix metalloproteases located in the same subcellular region via a MAP kinase or NFkB pathway. Matrix metalloproteases subsequently activate effector caspases that move extracellularly so that they are positioned for the degradation of the basal lamina by digestion of the laminin component. The delaminated tracheal cells are then susceptible to virus infection. This allows the transit of the virus through tracheal cells to other tissues and results in the systemic infection (119). This theory is supported by evidence for the activation of matrix metalloproteinases, the activation of effector caspases, and the degradation of laminin after the per os infection of midgut cells.

### Ac33 (182aa:20.8kDa) (polynucleotide kinase (PNK)).

Orthologs of Ac33 are found in most Group II and a few Group I and GV genomes. Homology searches indicate that it has significant similarity to polynucleotide kinase-3'-phosphatase of Apis mellifera (E = 9e-36) and somewhat lesser to the human homolog (E = 1e-28). In other organisms this enzyme has functions similar to T4 PNK. It is predicted to have structural similarity to Chain B of a DNA repair enzyme, polynucleotide kinase with an E value of 1.0e-^32^ (120). As previously suggested, Ac33 also has structural similarity to histidinol-phosphatase (an enzyme in the histidine biosynthesis pathway) (121). Orthologs are not present in BmNPV (16) or HaSNPV (17).

### Ac34 (215aa:24.9kDa), (Bm25:215aa:24.8kDa), (Ha27:255aa:29.5kDa).

Orthologs of Ac34 are found in Group I and II NPV genomes. Ac34 localizes to both the nuclei and cytoplasm of infected cells but does not appear to be a structural protein. Deletion of Ac34 from an AcMNPV bacmid resulted a delay in late gene expression, a100-fold reduction the viral titer, but did not appear to affect DNA replication. This mutant was unable to establish a fatal infection in the larvae of T. ni via per os exposure (122). In another study, deletion of Ac34 resulted in no BV production, but reduction of Ac34 expression by RNAi, elevated the expression of a heterologous gene expressed from the polyhedrin promoter (123). Deletion of Bm25 also resulted in a compromised virus (15).

### Ac35 (77aa:8.7kDa), (Bm26:77aa:8.7kDa),(Ha28:83aa:9.2kDa), ubiquitin-like protein.

Orthologs of ubiquitin have been found in the genomes of all alpha and beta baculoviruses, but are not present in hymenopteran or dipteran baculoviruses (124). Ac35 is expressed from both early and late promoter elements (125, 126). It was observed that late in infection recombinant virus expressing GFP fusions of ubiquitin from BmNPV localized throughout the nuclei with a few concentrated foci in the cytoplasm, whereas that of HaSNPV localized mostly to the peripheral regions of nuclei (127). The phylogenetic tree indicates that, whereas the ubiquitin of most eukaryotes is almost invariant, the baculovirus tree shows a higher degree of phylogenetic diversity, particularly between GVs and NPVs, suggesting that it may have been independently incorporated into a viral genome more than once. It is highly conserved among different NPVs showing at least 76% amino acid sequence identity. The most closely related non-baculovirus homologs of Ac35 are from vertebrates, e.g., rat (E = 2e-28). It is BV associated (27) and appears to be present on the inner surface of viral envelopes (128). A viral mutant with a frameshift of Ac35 is viable, but a 5–10-fold reduction in BV was observed (129). It has been suggested that viral ubiquitin may inhibit steps in the host degradative pathway to stabilize what would otherwise be a short-lived viral protein (130). The Spodoptera litura NPV genome was found to contain a gene that is a fusion of ubiquitin and gp37 (=Ac64). In addition, it was noted that unfused homologs of both these proteins are found in entomopox viruses (131). Although the significance of the linkage of these two proteins is not known, other such proteins have been termed 'rosetta stone' proteins because they reveal proteins that interact with one another and participate in the same molecular pathways. Consequently, when a mutation event occurs that leads to the fusion of two proteins that normally function together, the mutation is preserved because such a linkage is a normal feature of the two proteins. The presence of homologs of both these proteins in two disparate families of viruses along with the presence of a fused orf in the SlNPV genome, suggests that these orfs may participate in the same pathway, possibly as participants in a ubiquitin pathway or in ubiquitin inhibition.

### Ac36 (275aa:31.3kDa), (Bm27:277aa:31.5kDa), (Ha31:311aa:35.2kDa), 39K;pp31.

Pp31 was originally identified because it contains an early promoter that is stimulated by IE-1 (132). Homologs are found in all lepidopteran NPV and GV genomes. It is phosphorylated and localized to the virogenic stroma of infected cells, and is capable of binding to DNA but is not a virion structural protein (133), although it was reported to be BV associated in a proteomic study (27). Purified PP31 was found to bind to single-stranded and double-stranded DNA with equal affinities and inhibited transcription in vitro (134). Phosphorylation of pp31 appeared to be a dynamic process (135). Several basic regions were identified that may be involved in nuclear localization or DNA binding (136). Pp31 stimulates late gene expression in a transient transcription assay (137). Deletion of the pp31 homolog in BmNPV (Bm27) resulted in virus that, although viable, showed a reduction in late gene transcription, a 100 fold reduction in BV production, and improper formation of the virogenic stroma (66). Similar results were obtained for an AcMNPV bacmid deleted for pp31 and it was observed that the deletion resulted in a significant decrease of the transcription of six late genes (138).

### Ac 37 (112aa:13.1kDa), (Bm28:112aa:13.1kDa), (Ha32:127aa:14.6 kDa), Lef-11.

Lef-11 is present in all baculovirus genomes, except the dipteran CuniNPV. It was identified as being stimulatory for late gene expression in a transient transcription assay (43). An AcMNPV bacmid deleted for lef-11 failed to replicate and no DNA synthesis or late gene transcription were evident, indicating that it is an essential gene. Although LEF-11 localizes to nuclei of infected cells and appears to be essential for DNA replication, no domains associated with other factors involved in DNA replication have been reported and its role in DNA replication is not known (105).

### Ac38 (216aa:25.3kDa), (Bm29:217aa:25.5kDa), (Ha33:238aa:28.4kDa), Nudix, ADP-ribose pyrophosphatase (ADPRase).

Homologs of Ac38 are found in all lepidopteran NPVs and GVs. It contains a conserved Nudix ([underlined: nu]cleotide [underlined: di]phosphate [underlined: X]) motif (GX_5_EX_7_REUXEEXGU; X= any aa, U represents l, L, or V) (139) and has a homology to ADPRase, a subfamily of Nudix pyrophosphatases. Ac38 was shown to have ADPRase activity and a deletion mutant was severely compromised and produced BV at 1% the level of wt (140). Proteins of the nudix superfamily are common in all organisms and have been reported in other viruses including T4 bacteriophage, African swine fever virus (ASFV), and poxviruses. A vaccinia virus nudix protein may negatively regulate viral gene expression by acting as a decapping enzyme (141). Deletion of the gene in vaccinia resulted in smaller plaque and low virus yield (142), similar to the Ac38-deleted AcMNPV. Ha33 of the Heliocoverpa armigera NPV is a homolog Ac38 and was found to be associated with the envelope of budded virions (143).

### Ac39 (363aa:43.5kDa), (Bm30:362aa:43.4kDa).

Homologs of Ac39 are found in a few Group I NPV closely related to AcMNPV and at least two Group II (Adho-and ClbiNPV) genomes. Deletion showed no effects on growth curves or virus production (144).

### *Ac40 (401aa:47.5kDa), (Bm31:399aa:47.3kDa), (Ha35:3590aa:39kDa), P47, a subunit of the baculovirus polymerase.

P47 homologs are found in all baculovirus genomes. P47 was originally identified as the site of a ts mutation that caused a defect in late gene expression (145, 146). P47 was found to be required for transient late gene transcription (137) and to be a component of the baculovirus late polymerase complex (147). It is likely an essential gene as a deletion/insertion mutant in the BmNPV lef-8 homolog (Bm31) could not be isolated (15, 66).

### Ac41 (181aa:21.1kDa), (Bm32:183aa:21.1kDa), (Ha36:223aa:25.8kDa), Lef-12.

Lef-12 is found in about one-half the Group I and Group II NPV genomes sequenced. Although 18 genes were originally identified as being involved in transient expression from a late promoter (137), when individually cloned, the genes failed to support late transcription. Because of its close proximity to Ac 40 (p47), Ac41 (lef-12) had not been identified in the initial screen. It was subsequently demonstrated to be required for transient late gene transcription in S. frugiperda cells (148, 149), but not in T. ni cells (148). Mutants with lef-12 interrupted by insertional mutagenesis or by mutation of the ATG translation initiation codon were viable in both S. frugiperda and T. ni cells, although reduced yields of BV were observed (20-40% or wt) in both cell lines and the infection cycle appeared to be slowed (150). Although expressed as an (aphidicolin sensitive) late gene, initiation of lef-12 mRNA did not appear to occur at conventional late (or early) promoter elements. It was suggested that lef-12 may be functionally redundant in the AcMNPV genome and, therefore, it is not essential for late transcription when the rest of the virus genome is present (150).

### Ac42 (506aa:59.1kDa), (Bm33:506aa:59.2kDa), gta.

Ac42 has homology to 'global transactivator,' the DEAD-like helicase superfamily that are enzymes involved in ATP-dependent unwinding of DNA or RNA. They contain an SNF2 family N-terminal domain that is present in proteins involved in some processes, such as regulation of transcription, DNA recombination and repair, chromatin unwinding, and other functions. Homologs of this gene are found in all Group I NPV genomes. It has significant similarity to a wide variety of orfs from bacteria to marsupials, e.g., (E = 9e-61). Deletion of the Ac43 homolog from BmNPV (Bm33) did not cause any defects in BV or ODV production in BmN cells. Assays in B. mori larvae showed that the mutant, although similar in infectivity to the wt, took about 15 hr longer to kill when administered either by injection or per os (151).

### Ac43 (77aa:8.8kDa), (Bm34:78aa:9.0kDa), (Ha37:80aa:9.5).

Homologs of Ac43 are found in all Group I and most Group II NPV genomes. It appears to be involved in late and very late gene expression as deletion of BmNPV Bm34 resulted in a reduction in occlusion body production and a lengthening of the time to death in larvae. These effects were attributed to a down regulation of vlf-1 which is required for very late gene expression along with the reduction expression of the fp25k (=Ac61) gene (152). A knockout of Ac43 did not appear to affect BV production, but resulted in reduced expression of polyhedrin, but those present were larger than normal. They appeared contain more singly enveloped nucleocapsids than wt (153).

### Ac44 (131aa:15kDa), (Bm35:131aa:15.0kDa).

Homologs of Ac44 are found in all of Group I and one Group II (SeMNPV) lepidopteran NPVs. Ac44 is 131 amino acids and shows homology to a 64.2 kDa inhibitor of apoptosis/RING-finger protein in the genome of Spodoptera frugiperda ascovirus 1a (E = 1e-04). The SeMNPV homolog is more closely related to the ascovirus 1a orf (E = 2e-55) than to its Group I baculovirus homologs. Ac44 may be nonessential as a BmNPV bacmid with a Bm35 knock out appeared to be normal (15).

### Ac45 (192aa:22.7kDa), (Bm36:193aa:22.5kDa).

Homologs of Ac45 are found in four close relatives of AcMNPV (PlxyNPV, BmNPV, RoMNPV, and MaviMNPV). Sequences located within Ac45 appeared to be required for Ac41 expression in a transient late transcription assay (149). Ac45 may be nonessential as a BmNPV bacmid with a Bm36 knock out appeared to be normal (15).

### Ac46 (704aa:79.1kDa). (Bm37:702aa:79.2kDa), (Ha96:672aa:76kDa), ODV-E66.

Ac46 is a component of ODV envelopes (154). Homologs of this gene are found in the genomes of all Group I NPVs, GVs, and most Group II NPVs, but not in hymenopteran or dipteran viruses. Two copies of the gene are present in some genomes (e.g., SeMNPV). When the N-terminal 23 amino acids of ODV-E66 are fused to a reporter gene, it is targeted to the nucleus (155). Ac46 shows 100% probability of being related to hyaluronidase of Streptococcus pneumonia using the HHpred program (64) and has been shown to have hyaluronan lyase activity that is capable of digesting hyaluronan, a polysaccharide that is a major component of the extracellular matrix (156). Subsequently it was shown that a truncated form lacking the N-terminal 66 amino acids was secreted into the medium by infected cells and had chondroitinase activity. Chondroitinases have been shown to regulate cytokine and growth factors and can influence a variety of processes including development, inflammation, and organ morphogenesis. Its activity as a hyaluronan lyase was minimal (157). The crystal structure has been determined (158). A peptide of about 12 aa that was similar to the AcMNPV ODV-E66 sequence was observed to bind to the epithelium of guts Heliothis virescens and inhibited infection by AcMNPV (159). When the homolog of ODV-E66 was inactivated in BmNPV (Bm37), the mutant, although viable, took more time to kill insect larvae (160). In a study of AcMNPV, an ODV-E66 deletion was observed to kill Plutella xylostella larvae as efficiently as wt, however when infected per os the LD50 was1000 fold greater for the mutant than wt virus. Therefore it was suggested that ODV-E66 is a per os infectivity factor (PIF) (161). For more information on PIFs see Chapters 2 and 3.

### Ac47 (88aa:10.5kDa), (Bm38:89aa:10.5kDa), TRAX-like.

Ac 47 homologs are found in 5 Group I lepidopteran NPVs closely related to AcMNPV. It shows 27% identity to homologs of a protein called [underlined: tr]anslin-[underlined: a]ssociated factor [underlined: X] (Trax). Although TRAX interacts with translin, which may be involved in responses to DNA damage, transport of RNA, and control of translation, its function is not known (162). Ac47 may be nonessential as a BmNPV bacmid with a Bm38 knock out appeared to be normal (15). In AcMNPV his gene was referred to as ETS and transcriptional data for Ac47 in relation to PCNA has been described (163).

### Ac48 (113aa:12.9kDa).

Ac48 homologs are found in the genomes of most Group I lepidopteran NPVs. A homolog of Ac48 is not present in the BmNPV genome (16). This gene was referred to as ETM (the mid-sized orf in the EcoRI T fragment) and transcriptional data for Ac48 in relation to PCNA has been described (163).

### Ac49 (285aa:32.1kDa) (PCNA).

Ac 49 has homology to proliferating cell nuclear antigen (PCNA). PCNA homologs have been found in a few Group I and Group II alphabaculovirus genomes. The Group I PCNA homologs appear to be insect-derived and show a high degree of similarity to insect PCNAs, e.g., S. frugiperda (E = 6e-65). In contrast, the PCNA homologs of two Group II viruses (TnSNPV and ChchNPV) belong to a different lineage and do not show such a close relationship to insect PCNAs, e.g., S. frugiperda (E = 7e-20) and are even more distantly related to the Group I baculovirus PCNAs than to those of insects. Although eukaryotic PCNA lacks an enzymatic function, it plays a role in DNA synthesis, DNA repair, and cell cycle progression. It functions as a sliding circular clamp that mediates protein interactions with DNA and is required for the coordinated synthesis of both leading and lagging strands at the replication fork during DNA replication (164). In AcMNPV it is not an essential gene (163, 165, 166) and did not appear to elevate DNA replication in transient replication assays (42). A homolog of PCNA is not present in the genome of BmNPV (16).

### *Ac50 (876aa:101.8kDa), (Bm39:877aa:101.8kDa), (Ha38:901aa:105 kDa), Lef-8, baculovirus RNA polymerase subunit.

Lef-8 was originally identified as a gene required for transient late gene expression (167). Homologs are found in all baculoviruses and are also in nudiviruses. LEF-8 contains a conserved motif found in other RNA polymerases and it is thought that this is part of the catalytic site (167, 168). It is a component of the baculovirus late RNA polymerase complex (147, 169). It is likely an essential gene; in BmNPV a ts mutant located in lef-8 (A542V) was defective for BV production at the non permissive temperature (170). In addition, a deletion mutant in the BmNPV lef-8 homolog (Bm39) was not viable (15). Also a ts mutation L531S in Ac50 abolished very late transcription at 33 ° C (171).

### Ac51 (318aa:37.5kDa), (Bm40:319aa:37.8kDa), (Ha39 :194aa :22.5kDa), DnaJ domain protein.

Homologs of Ac51 are found in all Group I and II lepidopteran NPV genomes. It is a DNA J domain protein and shows homology to a variety of bacterial proteins. In E. coli, DnaJ has been demonstrated to have chaperone activity and aids in folding of other proteins (172). The homolog of Ac51 in HearNPV (ha39) has an RNA recognition motif, localizes to the cytoplasm and is associated with BV (27, 173). It may be an essential gene as a BmNPV bacmid with Bm40 deleted was defective for viral spread (15).

### Ac52 (194aa:123.2kDa), (Bm41:194aa:23.3kDa), (Ha42:180aa:21.3kDa).

Homologs of Ac52 are found in about one-half the Group I and II lepidopteran NPV genomes. Deletion of Bm41 resulted in reduction in BV production by 1000-fold and appeared to disrupt normal nucleocapsid envelopment and polyhedron formation in infected nuclei and resulted in a 14-fold elevation of LD_50_ in larvae and an increase in time to death (174). The predicted size of Ac52 is longer (194 vs 123 aa) than previously reported (12).

### *Ac53 (139aa:17kDa), (Bm42:139aa:16.9kDa), (Ha43:136aa:16.4kDa).

Homologs of Ac53 are found in all baculoviruses. Deletion of Ac53 indicated that it was an essential gene. The mutant bacmid was able to replicate DNA, but the virions were defective and appear to lack the nucleoprotein core (175). Ac53 is predicted to contain domains structurally similar to the U-box/RING-like domains found in the E3 ubiquitin ligase family (124).

### Ac53a (78aa:8.6kDa), (Bm42a:78aa:8.6kDa), (Ha46:71aa:7.7kDa), Lef-10.

This orf was named Ac53a because it was not identified in the original AcMNPV genome sequence because it is a small orf encoding 78 aa and about half the 3' coding region overlaps the 5' region of Ac54. Homologs of lef-10 are found in the genomes of all Group I and most Group II NPV and GV genomes. Lef-10 was originally identified because it was required for late gene expression (13). When Bm42a was deleted from a BmNPV bacmid, the bacmid was not viable (15).

### *Ac54 (365aa:42.1kDa), (Bm43:365aa:42.0kDa), (Ha47:351aa:41.7kDa), Capsid protein, (vp1054).

Homologs of Ac54 are found in all baculovirus genomes. It encodes a protein required for nucleocapsid assembly. A ts mutant failed to produce nucleocapsids at the nonpermissive temperature, indicating that it is an essential gene and it was associated with both BV and ODV (176). It interacts with 38K (Ac98) (177). When the vp1054 gene was deleted from a bacmid, the bacmid did not appear to be viable and nucleocapsids appeared to be replaced with tube-like structures. It was suggested that vp1054 may be related to a cellular protein called PURa that binds to purine-rich sequences and may be involved in DNA packaging. Ac54 was shown to bind to single stranded DNA or RNA sequences that contained runs of GGN (178).

### Ac55 (73aa:8.2kDa), (Bm44:77aa:8.6kDa), (Ha48:68aa:8.0kDa).

Homologs of Ac55 are found in the genomes of all Group I and most of the Group II NPVs. It appears to be nonessential because a BmNPV mutant deleted for this gene appeared to be normal (15).

### Ac56 (84aa:9.9kDa), (Bm45:84aa:9.9kDa), (Ha49:64aa:7.4kDa).

Homologs of this orf are found in genomes of all Group I and most Group II NPVs. It appears to be nonessential because a BmNPV mutant deleted for this gene appeared to be normal (15).

### Ac57 (161aa:19kDa), (Bm46:161aa:20.2kDa), (Ha50:171aa:20.7kDa).

Homologs of this orf are found in most Group I and II NPVs. It appears to be nonessential because a BmNPV mutant deleted for this gene appeared to be normal (15). It also appeared to be non essential for HearSNPV (179).

### Ac58/59 (172aa:20.3kDa), (Bm47:171aa:37.8kDa), (Ha51:160aa:19.0kDa), ChaB-like.

These two orfs are likely a single gene, as homologs are fused in other baculoviruses and they were also found to be joined when the region was resequenced in the C-6 strain (12). This results in an orf predicted to encode 172 amino acids. Homologs of this orf are found in the genomes of all Group I and all but one (LeseNPV) Group II NPVs. It has a ChaB domain. In E. coli, ChaB is thought to regulate ChaA, a cation transporter protein. It was found to localize to nuclei of infected cells (180) and was associated with AcMNPV ODV (74). It is also BV associated (27). It appears to be nonessential because a BmNPV mutant deleted for this gene appeared to be normal (15).

### Ac60 (87aa:10.1kDa), Bm48:83aa:9.7kDa), (Ha52:88aa:10.2kDa), (ChaB-like).

Homologs of Ac60 are found in the genomes of all Group I and II NPVs and most GVs. Similar to Ac58/59, Ac60 also has a ChaB domain. It is surprising that Ac58/59 and Ac60 are both predicted to encode ChaB domains as they do not show much sequence similarity. Alignment of the sequences resulted in an amino acid sequence identity of 15%; however, it required the insertion of several gaps, so the significant of the relatedness is not clear. In SpliNPV, two adjacent ChaB homologs were also identified. Evidence suggests that they may be DNA binding proteins (181). It appears to be nonessential because a BmNPV mutant deleted for this gene appeared to be normal (15).

### Ac61 (214aa:25.2kDa), (Bm49:214aa:25.3kDa), (Ha53:217aa:25.4kDa), Few polyhedra (fp, fp-25).

Orthologs of Ac61 have been found in the genomes of all alpha, beta, and gamma baculoviruses (124). AC61 has been shown to be BV associated (27). Deletion is not lethal, but results in a 'few polyhedra phenotype' (182, 183). FP mutants are defective in virion occlusion and nucleocapsid envelopment in nuclei and release two- to fivefold more infectious BV than wt in infected Sf9 cells (183, 184). The nonlethal, but readily distinguishable phenotype has facilitated investigations on this gene. FP mutations often result from the insertion of host DNA into the fp gene (182, 185). They can also be the result of errors in DNA replication (186). Mutations in the fp gene result in a reduction in polyhedrin gene (but not p10) transcription (183). Mutations also appear to affect the levels and nuclear transport of Ac46 (ODV-E66), an ODV envelope protein (187, 188). In BmNPV fp mutants, the few virions that were occluded appear to lack envelopes (189). A combination of reduction in the level of polyhedrin and an ODV envelope protein could contribute to the FP phenotype. The defect in occlusion and in the ODV envelope could lead to the availability of more virions for budding. A reduced level of liquefaction of larvae was also noted with an fp mutant in BmNPV (189). This was attributed to the involvement of Bm49 in the regulation of v-cathepsin expression (190). In T. ni cells, double p35 (see Ac135) and fp mutants underwent apoptosis, whereas p35 mutants alone did not, suggesting that the fp gene may have pro-apoptotic properties in this cell line (191). In contrast, in BmNPV infected BmN cells, deletion of fp25k did not affect apoptosis induced by a virus with p35 deleted (192). Fp25k mutants of AcMNPV produce virions that are occluded with different efficiencies depending on the cell line or insect. When replicated in Sf cells or insects the efficiency was lower than in T. ni Hi F cells or larvae (193). The fp25k gene was also found to contain two hypermutable sequences of 7 adenine residues and the mutant 25k genes expressed different amounts of polyhedrin mRNA and protein depending on the cell line (194).

### *Ac62 (516aa:59.3kDa), (Bm50:490aa:56.4kDa), (Ha55:519aa:60.0kDa), Lef-9, baculovirus RNA polymerase subunit.

Lef-9 homologs are present in all baculovirus and also nudivirus genomes. It was found to be required for transient late gene expression (13) and subsequently shown to be a subunit of the baculovirus RNA polymerase (147). It contains a 7-amino acid motif (NTDCDGD or NRDCDGD except NADFDGD in the dipteran virus) similar to the Mg++ binding sequence (NADFDGD) found in the catalytic center in large RNA polymerase subunits of a few DNA-dependent RNA polymerases (13). The D residues bind Mg++ and are conserved in all these sequences. It is likely an essential gene as an insertion/deletion mutant in the BmNPV homolog (Bm50) could not be isolated (66) or did not replicate (15).

### Ac63 (155aa:18.5kDa), (Bm51:155aa:18.5kDa), (Ha121:154aa:18.5kDa).

Homologs of Ac63 are found in five Group I and six Group II lepidopteran NPVs. A homolog in a nudivirus has been reported (195). It appears to be associated with BV envelopes (196). It appears to be nonessential because a BmNPV mutant deleted for this gene appeared to be normal (15).

### Ac64 (302aa:34.8kDa), (Bm52:294aa:33.8kDa), (Ha58:279aa:32.1kDa), (GP37/P34.8, spindlin, fusolin, spheroidin-like protein).

The terminology of Ac64 has a confusing history and in addition to gp37 has been referred to as p34.8, spindlin, fusolin, or spheroidin-like protein because of homology with an entomopox virus gene (197, 198). Evidence suggests that it is not a spheroidin-like homolog (199). Orthologs of gp37 have been found in the genomes of all alpha and beta baculoviruses (124). In AcMNPV it is expressed as a late gene (200). In addition to entomopox, it is related to orfs in a variety of eubacteria, e.g., Vibrio alginolyticus (E = 5e-27). It has been suggested that the granulovirus gp37 lineage is more closely related to the entompox lineage than to gp37s from NPVs (201). A homolog of Ac64 is referred to as chitinase B in the marine bacterium Pseudoalteromonas sp. and was found to bind to, but not digest chitin (202). The gp37 homolog in SpltNPV has been reported to contain chitin binding domains and is capable of binding to chitin (203). The gp37 of CpGV also bound chitin and was able to enhance per os infections (204). Insect proteins, such as the coagulation protein hemolectin, also have chitin-binding domains (205). Whether gp37 somehow inhibits or redirects such pathways remains to be determined. GP37 was reported to be polyhedron associated in AcMNPV and to be N-glycosylated (198). It was also found to be BV associated (27). In OpMNPV infected L. dispar cells, GP37 was found to be an N-glycosylated protein located in cytoplasmic occlusions late in infection (206). The gp37 gene is nonessential for replication in cell culture or T. ni larvae (197). Similar results were observed for the BmNPV homolog (Bm52) (15). The Spodoptera litura NPV genome was found to contain a gene that is a fusion of ubiquitin and gp37 (for discussion, see Ac35, ubiquitin) and the protein was associated with the envelopes of BV and ODV (131) .

### *Ac65 (984aa:114.3kDa), (Bm53:986aa:114.4kDa), (Ha67:1020aa:119.3kDa) (DNA polymerase).

Homologs are found in all baculoviruses. The nonbaculovirus homologs showing the highest level of similarity are found in herpesviruses, e.g., human herpes virus 7 (E = 1e-25), several protozoans, and archae. A DNA polymerase homolog was originally identified in the AcMNPV genome by hybridization with degenerate primers designed based on a highly conserved domain in other DNA polymerases (207). A 3'→5' exonuclease activity specific for single-stranded DNA was shown to be associated with the DNA polymerase from Bombyx mori NPV (BmNPV) (208) and AcMNPV (209), suggesting that a proofreading activity was associated with this enzyme. A purified DNA polymerase from AcMNPV was characterized as being active on singly primed M13 templates (210). The polymerase is highly processive on poly (dA)-oligo dT (209). Mutations of AcMNPV DNA polymerase resistant to a variety of inhibitors have been described (211). DNA polymerase is an essential gene because deletion is lethal in AcMNPV (212) and BmNPV (15, 66).

### *Ac66 (808aa:94kDa), (Bm54:805aa:93.3kDa), (Ha66:785aa:88.9kDa).

Homologs of Ac66 appear to be present in all baculoviruses. Many viruses appear to have two copies Ac66 of homologs, and some may have three copies (99). Ac66 is closely related to a variety of proteins including a predicted orf in the protozoan Trichomonas vaginalis (E = 6e-20), an actin binding protein in Dictyostelium discoideum (E = 1e-14), rabbit myosin heavy chain (E = 2e-14), and centromere protein E of Canis familiaris (E = 2e-14). It has a few conserved domains, including Smc, which is a chromosome segregation ATPase involved in cell division and chromosome partitioning, desmoplakin, the main adhesive junction protein in epithelia and cardiac muscle, and a domain in a chromosome segregation protein. It was found to be associated with AcMNPV (74) and HearNPV (Ha66) (213) ODV and AcMNPV BV (27). Ac66 is oriented in the opposite direction of DNA polymerase (Ac65) and its promoter region overlaps with the 5' region of the DNA pol orf. This orientation is conserved in many, if not all baculoviruses. Although the orfs adjacent to DNA polymerase in Neodiprion (e.g., NeSeNPV) and CuniNPVs show little homology to Ac66, they and Ac66 show homology to the same proteins, i.e., they both show almost 100% probability of being related to colicin 1a and myosin using the HHpred program (64). Consequently, it is likely that Ac66 is conserved throughout the baculoviruses. Ac66 is transcribed as a late gene and its expression does not affect the expression of DNA pol (214). An AcMNPV bacmid deleted for Ac66 was severely compromised and BV titers derived from transfected cells were reduced by over 99% compared with wt. In addition, at low titers the mutant BV appeared to infect single cells and was unable to spread to other cells. Although the nucleocapsids appeared to be normal and had an electron dense core, suggesting that they contained DNA, they appeared to be trapped in the virogenic stroma, suggesting that Ac66 was required for the efficient egress of virions from nuclei. The deletion did not affect the levels of DNA replication or polyhedrin transcription, but the production of occlusion bodies was eliminated (215). This suggests that Ac66 is required both for egress of virions from nuclei and also may be involved in the ennucleation of polyhedra. For additional discussion, see Chapter 5. A bacmid deleted from Bm54 produced non-infectious BV and appeared to be properly assembled. Polyhedron formation also appeared to be affected (216).

### Ac67 (385aa:44.6kDa), (Bm55:385aa:44.9kDa), (Ha65:379aa:44.0kDa), LEF-3.

Lef-3 was originally found to be essential for DNA replication in transient assays (42, 43). Homologs of lef-3 are found in the genomes of lepidopteran NPVs and GVs, but not those of hymenopteran or the dipteran NPVs. LEF-3 is a single-stranded DNA binding protein (SSB) (217) and interacts with itself as a homo-oligomer (218). It also binds to helicase (219) and facilitates its transport into the nucleus (220). It can also drive nuclear transport into mammalian cells (221). It also may have a function in DNA replication in addition to its requirement as a helicase transport factor (222, 223). LEF-3 also interacts with alkaline nuclease and may regulate the function of this enzyme (224, 225); it is capable of both unwinding and annealing DNA depending on its concentration or redox state (226, 227); and it can facilitate the production of structures resembling recombination intermediates via strand exchange between donor and recipient molecules in vitro (228). The lack of conservation of LEF-3 in baculoviruses might not be unexpected because, although homologs of alkaline nuclease are present in many organisms (see Ac133) and many have been reported to interact with an SSB (e.g., herpesvirus, ICP8 and lambda phage, red-beta), clear sequence relationships between the various SSBs are not evident (229). Insertion/deletion mutants of lef-3 are lethal (66, 223). In another report a bacmid deleted for LEF-3 showed some evidence for limited amounts of DNA replication and late gene expression, and some infectious virus was observed although over100,000 times less than wt (230).

### *Ac68 (192aa:22.3kDa), (Bm56:134aa:15.8kDa), (Ha64:133aa:15.6kDa).

Homologs of Ac68 are present in all baculoviruses. A frame shift in this gene did not affect transient late gene expression (149) and a deletion of Ac68 resulted in no major effects on AcMNPV production and TCID50, and no differences in the number, size, and shape of polyhedra were noted, although the lethal time was longer in T. in larvae (231). In contrast, another report suggested that Ac68 was a per os infectivity factor (PIF-6) as a deletion mutant, although producing normal appearing polyhedra, failed to kill T. ni larvae (230). In addition, it is reported to be associated with the AcMNPV PIF complex (40). When the homolog in BmNPV (Bm56) was deleted in a bacmid, no effects on titers in cultured cells or in BV-injected larvae were detected, although the lethal time in larvae was longer. Although enveloped ODV were present, the polyhedra produced by the mutant bacmid were abnormal and lacked virions, suggesting that Bm56 is involved in polyhedron morphogenesis (232).

### Ac69 (262aa:30.4kDa), (Bm57:262aa:30.4kDa), (Ha63:274aa:31.6kDa), (MTase).

Ac69 encodes a methyltransferase and orthologs are found in the genomes of all Group I NPVs, except OpMNPV and about one-half of Group II NPVs and one hymenopteran NPV. The homolog present in the hymenopteran NPV (NeseNPV) falls within an insect, rather than a baculovirus lineage. Homologs are found in a nudivirus (Hz-1) and a variety of insects, e.g., Anopheles gambiae (E = 8e-18) and other invertebrates and vertebrates. Ac69 was found to stimulate late gene transcription in a transient assay (149). The gene encodes a protein with RNA Cap (Nucleoside-2′-O)-Methyltransferase activity. AcMNPV, with a null mutation of the gene, replicated normally in cell culture (233). Similar results were observed for a knockout of the homolog (Bm57) in BmNPV (15).

### Ac70 (290aa:34.4kDa), host cell-specific factor-1 (hcf-1).

Homologs are present in only three other baculoviruses; two are close relatives of AcMNPV and their HCF-1 orfs are 99% (PlxyNPV) and 84% (RoMNPV) identical to that of AcMNPV, whereas the homolog in ClbiNPV is more distantly related (21% identical). HCF-1 was found to be required for transient expression of a late promoter-reporter gene by a late expression factor library in T. ni cells, but not SF-21 cells (234). AcMNPV with null mutations in hcf-1 were found to replicate normally in both Sf-21 cells and S. frugiperda larvae. However, in T. ni cells replication was impaired and in T. ni larvae the mutant showed a significantly reduced infectivity by intrahemocelic injection. Although oral infectivity was relatively normal in T. ni larvae, the insects died more slowly than when infected with wt (235). It was suggested that HCF-1 is a RING finger-containing protein that is dependent upon self-association and gene repression for its activity (236).

### Ac71 (249aa:28.6kDa), (Bm58:249aa:28.7kDa), (Ha62:250aa:29.3kDa), iap-2.

Ac71 encodes an inhibitor of apoptosis-2 (iap-2) gene. Homologs of iap-2 are found in the genomes of all Group I and most Group II NPVs, and as with all iap genes more distant relatives are found in many organisms. It is BV associated in AcMNPV (27). Deletion of iap-2 had no effect on viral replication in cell culture; however, this may have been due to the presence of another apoptotic suppressor, p35 (237). In contrast, deletion of iap-2 (bm58) from the BmNPV genome indicated that it was required for replication in BmN cells (111). Evidence suggested that transfection of AcMNPV iap-2 into T. ni cells suppressed apoptosis by HearNPV infections, and although a recombinant HearNPV expressing iap-2 also suppressed apoptosis, BV production was not rescued (101). In Epiphyas postvittana NPV, the iap-2 homolog was found to have anti apoptotic activity when expressed from a CMV promoter in S. frugiperda cells (102). However, it was observed that ipa-2 of Lymantria dispar MNPV induced apoptosis when transfected into Ld652Y cells. However, it was suggested apoptosis was suppressed by the virus because of the presence of the apoptotic repressor, apsup in LdMNPV (238).

### Ac72 (60aa:7.1kDa), (Bm58a,60aa,7.1kDa).

Homologs of Ac72 are found in the genomes of all sequenced Group I NPVs, but not in other viruses. In BmNPV, deletion of this orf caused no observable changes from wt (15)

### Ac73 (99aa:11.5kDa), (Bm59:99aa:11.5kDa).

Homologs of Ac73 are found in the genomes of all sequenced Group I NPVs, but not in other viruses. It is BV associated in AcMNPV (27). In BmNPV this gene appears to be essential (15).

### Ac74 (265aa:30.6kDa), (Bm60:268aa:31.0kDa), (Ha68:152aa:17.6kDa).

Homologs of Ac74 are found in the genomes of all Group I and about half Group II NPVs, but is not present in hymenopteran or dipteran NPVs or GVs. It is BV associated in AcMNPV (27). Bm60 was found to be expressed as a late gene and was localized to both the cytoplasm and nucleus of infected cells (239). It was found to be associated with AcMNPV ODV (74), but not in HearNPV ODV (213). Deletion of Bm60 from BmNPV resulted in a reduction and delay in DNA synthesis, a reduction in BV production by about 10-fold, and a lengthening of the time to kill larvae (240).

### Ac75 (133aa:15.5kDa), (Bm61:133aa:15.5kDa), (Ha69:127aa:14.9kDa).

Homologs of Ac75 are present in all lepidopteran NPV, GV and hymenopteran NPV genomes, but not in the dipteran virus genome. It was found to be associated with both BV and ODV of BmNPV and localized to the ring zone of infected cells (241). In BmNPV it appears to be essential because when deleted, no BV were detected and the virions appeared to be retained in the nuclei (242).

### Ac76 (84aa:9.4kDa), (Bm62:85aa:9.6kDa) (Ha70:85aa:10.0kDa).

Homologs of Ac76 are present in the genomes of all lepidopteran NPVs, GVs, and hymenopteran NPVs, but have not been reported in the dipteran virus genome. Ac76 localized to the ring zone late in infection. It is an essential gene, as deletion of ac76 resulted in a mutant bacmid able to produce DNA to normal levels, but was deficient in intra nuclear microvesicles and was unable to produce BV (243). Ac76 appears to be present as a stable dimer that is resistant to denaturation and functions as a type II integral membrane protein in which the C-terminus is located in the ER lumen and the N-terminus interacts with the cytosol (244).

### *Ac77 (379aa:44.4kDa), (Bm63:379aa:44.3.0kDa), (Ha71:412aa:47.9kDa), Very late factor-1 (Vlf-1).

Homologs are found in all baculoviruses. The most closely related nonbaculovirus homologs are found in a number of eubacterial species, e.g., Caldicellulosiruptor saccharolyticus (E = 1e-06). Homologs are also reported in nudiviruses (195). VLF-1 is a member of the lambda integrase (245) family of proteins. Integrases are a large group of site-specific DNA recombinases that catalyze DNA rearrangements and are involved in the integration and excision of viral genomes and decatenation of newly replicated chromosomes. A feature of these enzymes is that a conserved tyrosine forms a covalent link with DNA during the cleavage process. VLF-1 was originally identified because it influences the hyperexpression of very late genes (245). It was found to bind near the regulatory region of very late genes (246). Whereas mutations to the region that affected very late gene transcription were not lethal, other mutations, including mutation of the conserved tyrosine, appeared to be lethal to the virus (247). VLF-1 appears to be a structural protein present in both BV and ODV (247) and localizes to the ends of nucleocapsids, suggesting that it is a structural protein (248) and is required for the production of nucleocapsids. Although vlf-1 is an essential gene, an AcMNPV bacmid with vlf-1 knocked out (248-250) was able to synthesize viral DNA at levels similar to control bacmids. However, the mutant produces tube-like capsids that appear to lack DNA. Characterization of a mutant of the conserved tyrosine indicated the nucleocapsids were unable to be released from the virogenic stroma, suggesting that the protein may be involved in a final step in the maturation of DNA (248). VLF-1 showed structure-dependent binding to DNA substrates with the highest binding affinity to cruciform DNA that mimics a structure common to recombination intermediates (251). See also Chapters 5 and 6.

### *Ac78 (109aa:12.5kDa), (Bm64:110aa:12.7kDa), (Ha72:110aa:12.7kDa).

Ac78 is a core gene (124); the ortholog in HearNPV is associated with the ODV envelopes (252) and in BmNPV, the gene appeared to be essential (15). When deleted from AcMNPV, DNA replication appeared to be unaffected, nucleocapsids appeared to be confined to the nucleus, infectious BV were not produced, and polyhedra lacked occluded virions. Ac78 also appeared to be envelope associated in both BV and ODV (253). The homolog of Ac78 in HearNPV was found to be essential for production of infectious viruses and interacted with the baculovirus sulfhydryl oxidase, p33 (254).

### Ac79 (104aa:12.2kDa), (Bm65:104aa:12.2kDa).

Homologs are present in all Group I, about half the Group II NPV and GV genomes. It was found to be associated with AcMNPV ODV(74). It has homology to ascovirus orfs from T. ni (E = 1e-18) and S. frugiperda (2e-11), Chilo iridescent virus (E = 3e-10), and orfs from a variety of Yersinia sp (e.g., E = 2e-10), Serratia sp., and other bacteria. It is predicted to be homologous to an endonuclease in a number of these organisms. It has been suggested that Ac79 is a member of the UvrC superfamily of endonucleases that are involved in DNA repair (255). It shows a high degree of similarity both in sequence and predicted structure to EF2693 from E. faecalis (256). Bacmids deleted for Ac79 resulted in reduced BV production and smaller plaque size, and showed some tube-like structures that may be aberrant capsids. Point mutations in conserved motifs shared by Ac79 and the endonuclease superfamily failed to cause production of the tube-like structures but one of the mutations caused a reduction in BV production (257). One study of BmNPV suggested that Bm65 is an essential gene (258), whereas another study indicated that it produced BV and could spread between cells but with reduced efficiency (15).

### *Ac80 (409aa:45.4kDa), (Bm66:403aa:44.9kDa), (Ha73:322aa:36.6kDa), GP41, tegument protein.

GP41 is a tegument protein modified with O-linked N-acetylglucosamine, located between the virion envelope and capsid (259, 260). It was found to be associated with ODV by mass spectrometry (74, 213). Homologs are present in all baculovirus genomes. Based on the characterization of a ts mutant, Ac80 is an essential gene required for the egress of nucleocapsids from the nucleus (261). A deletion mutant of the homologous gene in BmNPV (Bm66) indicated that it produced BV and could spread between cells but with reduced efficiency (15).

### *Ac81 (233aa:26.9kDa), (Bm67:234aa:27.0kDa), (Ha74:241aa:27.7kDa),.

Homologs of this orf appear to be present in all baculovirus genomes. A homolog has also been reported in nudiviruses (195). The BmNPV homolog (Bm67) appears to be a late expressed nonstructural gene that localizes to the cytoplasm (262). When put through the HHpred program (64) that compares predicted proteins to known structures, Ac81 and its ortholog from NeseNPV showed relatedness to the HIV TAT protein with a probability of greater than 80%. It may be essential because a deletion mutant of the homologous gene in BmNPV (Bm67) was severely compromised and did not appear to produce BV (15).

### Ac82 (180aa:19.8kDa), (Bm68:181aa:20.1kDa), (Ha75:225aa:24.9kDa), Telokin-like protein (TLP).

Telokin-like protein is not like telokin! Homologs of Ac82 are found in the genomes of all lepidopteran NPVs and GVs. A protein called telokin is identical to 157 C-terminal amino acids of the myosin light chain kinase (MLCK), but is expressed independently. Telokin is the myosin binding fragment of myosin light chain kinase and is involved in muscle contraction. A polyclonal antibody prepared against smooth muscle telokin reacted with a protein from cell extracts of AcMNPV-infected Sf9 cells. This protein was called telokin-like protein. Clones that reacted with the antibody were isolated from a cDNA library of AcMNPV infected sf9 cells (263). The clones showed no sequence homology to telokin but when expressed in a pET vector, the product reacted with the telokin polyclonal antiserum. The AcMNPV sequence that produced the reactive protein contains portions of Ac82. The crystal structure of AcMNPV TLP was determined, but showed no similarity to telokin or any other characterized protein (264). Therefore, although this protein has been called telokin-like protein, its resemblance to telokin appears to be an artifact of the polyclonal antiserum. Consequently, information on a function for one of the few baculovirus specific proteins for which a crystal structure has been determined is still lacking. It is likely to be nonessential because when it was deleted in BmNPV (Bm68) the virus appeared to be normal, but production of BV and DNA replication was somewhat delayed. Although it showed nuclear localization and did not concentrate at the plasma cell membrane, it was found to be associated with the envelope/tegument of budded virions (265). In AcMNPV a TS mutant appeared to cause a major reduction in BV production (171).

### *Ac83 (847aa:96.2kDa), (Bm69:839aa:95.8kDa), (Ha76:816aa:93.5kDa), VP91.

Ac83 encodes a virion capsid protein called VP91 that was originally characterized in OpMNPV (266). It has also been shown to be ODV associated in AcMNPV, CuniNPV, and HaSNPV by mass spectrometry (74, 93, 267) and was found as a component of the per os infectivity factor (PIF) complex (40). Homologs are encoded by all baculovirus and are also found in nudiviruses (195) and possibly in several insect genomes, e.g., Anopheles gambiae (E = 5e-04). Ac83 is predicted to contain a chitin binding domain and has a high degree of predicted structural similarity by HHpred (64) to Tachycitin, a 73aa antimicrobial peptide (268). When the ac83 deleted from an AcMNPV bacmid, the bacmid was non infectious. However when just the chitin domain was deleted, the virus was unable to infect larvae via the midgut, but could infect via intrahaemocoelic injection, indicating that Ac83 is a per os infectivity factor and that chitin binding plays a major role in the ability of the virus to initiate midgut infection (269). This suggests that ac83 likely plays two or more roles in virus infection. A deletion mutant of this gene in BmNPV (Bm69) did not produce BV and results in the production of tubular structures (270).

### Ac84 (188aa:21.7kDa).

This orf is only found in a few other NPVs: PlxyNPV, ChchNPV, and RoMNPV, and TnSNPV. A homolog is also found in ascoviruses, e.g., T. ni ascovirus (E = 3e-10). It is not found in the BmNPV or the HaSNPV genomes.

### Ac85 (53aa:6.4kDa).

This small orf encoding 53 aa is only found in two other NPVs that are AcMNPV variants: PlxyNPV and RoMNPV. This gene is not found in the BmNPV or HaSNPV genomes.

### Ac86 (684aa:80.8kDa) (PNK/PNL).

This gene encodes a protein with RNA ligase, polynucleotide 5'-kinase, and polynucleotide 3'-phosphatase activities and may be part of an RNA repair pathway (271). Homologs are only found in 5 baculovirus genomes, three are closely related to AcMNPV including AgMNPV, ApNPV, and RoMNPV, whereas the other is in a GV, SpliGV. A closely related orf is also found in a T. ni ascovirus (E = 2e-125). Ac86 appears to be a nonessential gene expressed early in infection (272). This gene is not found in the BmNPV or HaSNPV genomes.

### Ac87 (126aa:15kDa), (Bm70:126aa:15.1kDa).

This gene appears to be present in most Group I lepidopteran NPV genomes. It was suggested that the homolog in BmNPV (Bm70) might encode a capsid protein called p15 (273). It is likely nonessential, as a deletion mutant in BmNPV (Bm70) appeared normal (15).

### Ac88 (264aa:30.1kDa), (Bm71:267aa:30.7kDa), (Ha77:283aa:32.3kDa), CG30.

Homologs of Ac88 appear to be present in the genomes of most Group I and II NPVs, and also may be present in a single GV (SpliGV). An orf in Clostridium perfringens showed significant similarity (E = 2e-06). Ac88 contains predicted zinc finger and leucine finger domains (274). It was found to be associated with AcMNPV (74), but not in HearNPV ODV (213). Deletion of this gene from AcMNPV resulted in only subtle differences from wt (275). However, deletion of the gene from BmNPV (Bm71) resulted in a 10 to 100 fold reduction in titer and showed a longer lethal time (276). In another study of Bm71, a deletion and two RING finger mutants were constructed. The deletion mutant produced fewer BV and fewer occlusion bodies were released into the hemolymph of infected larvae. The RING finger mutants released fewer OBs into larval hemolymph. They also noted that cg30 localized to nuclei of infected cells (277).

### *Ac89 (347aa:39kDa), (Bm72:350aa:39.3kDa), (Ha78:293aa:33.4kDa), VP39.

This gene encodes the major capsid protein VP39. It is present in all baculovirus genomes. It was originally characterized in OpMNPV (278) and AcMNPV (279). It interacts with 38K (Ac98) (177). Deletion of Bm72 from BmNPV resulted in no apparent BV production (15). It has been observed that VP39 interacts with a conserved domain of kinesin 1 and it has been suggestion that this interaction is involved in the transport of nucleocapsids destined to become BV to the cell membrane after their assembly in nuclei (280).

### *Ac90 (464aa:53.9kDa), (Bm73:465aa:54.0kDa), (Ha79:3461aa:54.0kDa), LEF-4.

LEF-4 is an enzyme involved in RNA capping and is a component of the late baculovirus RNA polymerase (147). It is present in all baculovirus genomes and is also present in nudivirus genomes (195). This gene was originally identified as being essential for late transcription (137). LEF-4 was subsequently found to be an RNA capping enzyme (281, 282). The addition of an mRNA 5' cap structure involves the hydrolysis of the gamma phosphate of the 5'-triphosphate of the first nucleotide of pre-mRNA and the capping reaction that involves the transfer of GMP from GTP. The two reactions involve two different enzymatic activities: an RNA 5' triphosphatase to remove the terminal gamma phosphate and the addition of GMP by guanylyltransferase. These two activities are present on a single protein located at the N- and C-termini, respectively, in metazoans and plants. Although having similar activity, LEF-4 is unrelated to this category of capping enzyme, but is a member of metal dependent group of capping enzymes found in fungi and protozoa (281, 283, 284). The 5' cap structure appears to serve two roles. It protects the 5' end of the mRNA from degradation by exonucleases and it interacts with translation initiation factors, thereby facilitating the initiation of translation. Capping in eukaryotes involves an enzyme that associates with the highly repetitive carboxy terminal domain (CTD) of the β' subunit of RNA polymerase II. Because the baculovirus polymerase lacks a similar domain, it is likely that it evolved to include the enzyme as part of the RNA polymerase complex. However, assuming these reactions are free from exonuclease, it is not clear why LEF-4 is required for transcription in in vitro assays. These assays monitor RNA transcripts that would not need to be capped in order to be detected. This suggests that LEF-4 may play a structural role in the organization of the polymerase subunits, or it may have some other function. LEF-4 is an essential gene and could not be deleted (285). For more information see Chapter 6.

### Ac91 (224aa:24.1kDa), (Bm74:154aa:17.3kDa).

Homologs of this gene are found in genomes of all Group I lepidopteran NPV and two GV (CpGV and PlxyGV) genomes. It has an unusual predicted amino acid sequence: 31% proline and 18% ser/thr residues. In HearNPV the Ac91 homolog (ha80) was expressed first cytoplasmically and then in nuclei, but did not appear to be a structural protein of BV or ODV (286). Deletion of Bm74 causes few differences from wt and repair viruses in DNA synthesis or BV titers. However, the lethal time in larvae was longer by 14.7 hr (287).

### *Ac92 (259aa:30.9kDa), (Bm75:259aa:30.9kDa), (Ha80:254aa:30.8kDa), p33, sulfhydryloxidase (sox).

Ac92 is a flavin adenine dinucleotide (FAD)-linked sulfhydryl oxidase (288) (289). Proteins with sulfhydryl oxidase activity have been implicated in the protection of cells from oxidative stress caused by apoptosis (290) (291). Orthologs of Ac92 are present in all sequenced baculovirus genomes, it is associated with BV and ODV, and it is an essential gene as viable recombinants deleted for this gene have not been isolated (289) (292). Ac92 is able to form a stable complex with the human tumor suppressor gene p53 when it was expressed in a baculovirus system. When expressed by itself, p33 shows diffuse cytoplasmic staining and punctate staining of nuclei. However, when co-expressed with p53, it exclusively localizes to nuclei. Expression of human p53 in Sf cells causes apoptosis that can be blocked by co-expression of baculovirus anti-apoptotic suppressors p35 or OpIAP. However, co-expression of p53 with p33 elevated the induction of apoptosis about two fold. By proteomic analysis, p33 appears to be an ODV-associated protein in AcMNPV (74) and HearNPV (213, 267). The crystal structure of Ac92 was described as a novel dimer composed of two pseudodimers (293). The structure of Bm75 has also been reported (294). An ortholog of P53 has been described for S. frugiperda (295) and similar to human p53, Sfp53 was found to interact with Ac92 (296). It interacts with the Sfp53 DNA binding domain and a point mutation in Sfp53 that inactivated DNA binding also inactivated binding of Ac92 to Sfp53. Ac92 was also shown to oxidize Sfp53 in vitro. However, despite the ability of p33 to interact with and oxidize Sfp53 in cultured cells, no effects on Sfp53-mediated apoptosis or virus replication were observed (296). Effects on other cell types or in whole insects was not ruled out by these studies.

### *Ac93 (161aa:18.4kDa), (Bm76:161aa:18.4kDa) (Ha81:162aa:19.1kDa).

This gene appears to be present in all baculovirus genomes (297). An Ac93 knockout did not produce infectious BV and may be involved in the formation of intranuclear microvesicles, (297). In addition, a BmNPV bacmid deleted for Bm76 did not produce BV (15).

### *Ac94 (228aa:25.5kDa), (Bm77:228aa:25.6kDa), (Ha82:230aa:25.9kDa), ODV-E25 (p25, 25k).

Ac94 appears to be encoded by all baculovirus genomes (297). The protein encoded by this gene was originally identified in OpMNPV, and immunogold staining with a specific antibody against Ac94 was localized to ODV envelopes (298). It has also been shown to be associated with BV and ODV of AcMNPV and HearNPV (27, 74, 213, 267). The hydrophobic N-terminal 24 aa of AcMNPV ODV-E25 appears to be a nuclear targeting signal (155). Deletion of Ac94 resulted in a 100 fold reduction in infectious BV. In addition, ODV were not evident and although polyhedra were produced, they lacked virions (299). It has been reported that when ODV-E25 is expressed as an early gene under the IE-1 promoter, it accumulated on the cytoplasmic side of the nuclear membrane rather than within nuclei, and budded virus production was severely reduced. This suggests that it might play a role in the shift from BV to ODV virions. In addition, expression from the very late polyhedrin or p10 promoter reduced and delayed occlusion body formation suggesting that it may play a role in virion occlusion (300) (301). Subsequently it was found that the open reading frame of ODV-E25 encodes a microRNA that down regulates ODV-E25 expression. It was suggested that this might result in a reduction in infectious virus production and be involved in the shift to occluded virus production (302).

### *Ac95 (1221aa:143kDa), (Bm78:1222aa:143.6kDa), (Ha84:1253aa:146.0kDa), DNA helicase (p143).

Homologs of DNA helicase are present in all baculovirus genomes. This gene was initially identified as a ts mutant that was unable to synthesize DNA at 33° (303). The defect was localized to a homolog of DNA helicase with a predicted mass of 143 kDa (304). P143 is required for transient DNA replication (42, 43) and shows ATPase activity and is able to unwind a DNA primer annealed to a larger DNA molecule in an ATPase-dependent manner (305). Helicase is dependent on an interaction with LEF-3 for transport to the nucleus (see Ac67, LEF-3) (220). Mutations in this gene have been implicated in affecting viral host range (306, 307). Deletion is probably lethal as deletion/insertion mutants of this gene in BmNPV (Bm84) could not be isolated (66).

### *Ac96 (173aa:19.8kDa), (Bm79:182aa:21.0kDa), (Ha85:173aa:19.8kDa) PIF-4.

This orf appears to be present in all baculoviruses and homologs also appear to be present in nudiviruses (195). The homolog in BmNPV (Bm79) is an ODV envelope associated protein (308) and was also found associated with the envelopes of BV (309). Deletion of Ac96 from a bacmid construct resulted in a virus that could replicate in cell lines, but not insects. Consequently it was concluded that Ac96 is a per os infectivity factor, the 4^th^ such protein identified in the AcMNPV genome (309).

### Ac97 (56aa:6.5kDa).

This is a small orf (56 aa) and appears to be present only in AcMNPV. There is no homolog in BmNPV and it is positioned at the location of the apparent insertion of two bro (Ac2) homologs (see Ac2). The lack of this orf in closely related viruses may indicate that it is not a functional orf.

### *Ac98 (320aa:38kDa), (Bm82:320aa:38.0kDa), (Ha86:321aa:37.9kDa), 38K.

Ac98 encodes a predicted protein of 38k and orthologs are present in all baculovirus genomes. AcMNPV Ac98 interacts with itself, VP1054 (Ac54), VP39 (Ac89), and VP80 (Ac104) and is associated with BV and ODV nucleocapsids (177). In HearNPV it interacted with itself, ODV-E56,GP41, PIF-2 and PEF-3 (310). An AcMNPV bacmid deletion construct, although unable to produce infectious virions, was capable of DNA synthesis, but nucleocapsid formation was disrupted. Tube-like structures that appeared to lack DNA, but stained with an anti-vp39 antibody were observed (311). It has also been suggested that Ac98 is capable of stimulating transcription in a transient transcription assay (312). When put through the HHpred program (64) that compares predicted proteins to known structures (see Chapter 6), Ac98 showed relatedness to a set of enzymes including CTD phosphatases with a probability of almost 100%. Dephosphorylation of the CTD can negatively regulate RNA polymerase II by inhibiting RNA elongation (313, 314). Although it is required for nucleocapsid formation, it does not appear to be a structural component of ODV as determined by proteomic analysis (74, 213). However, it was detected in CuniNPV ODV (93).

### *Ac99 (265aa:31kDa), (Bm83:265aa:31.1kDa), (Ha87:315aa:37.0kDa), (LEF-5).

Homologs of lef-5 are found in all baculoviruses and are also present in nudiviruses (195). LEF-5 was originally identified as being required for transient late gene expression (315). It was demonstrated to interact with itself and to contain a domain similar to that of the RNA polymerase II elongation factor TFIIS (316). Subsequent investigations indicated that LEF-5 did not enable the baculovirus polymerase to transit pause sites, and it was concluded that it functions as an initiation factor, rather than an elongation factor (317). A lef-5 knockout bacmid appeared to express early genes and replicate DNA normally, but was defective in late gene transcription, and did not yield any detectable virus when transfected in to Sf9 cells. (318).

### *Ac100 (55aa:6.9kDa), (Bm84:65aa: 8.1kDa), (Ha88:109aa:11.5kDa),p6.9.

P6.9 is a small (55 aa) arginine/serine/threonine-rich DNA binding protein (319). Homologs appear to be found in all baculoviruses, but are apparently difficult to detect because of their small size and repetitive amino acid content (320). It was originally shown to be a DNA binding protein in a GV (321), and the homolog was isolated from AcMNPV (319). The high concentration of arginine and ser/thr residues is similar to protamines that are present in sperm nuclei of many higher eukaryotes and are involved in the production of highly condensed DNA. Protamines are also small molecules of 44-65 amino acids (322, 323). Arginine is positively charged, and the polyarginine tracts in protamines neutralize the phosphodiester backbone, whereas the ser and thr residues interact with other protamine molecules, thereby yielding a neutral, highly compact complex that is biochemically inert. P6.9 localizes to the nuclear matrix during infection (324). It was found to elevate virus transcription at 12-24 hpi, but did not appear to be involved in basal levels of virus transcription. It was also found to co-localize with viral DNA during this same time frame and to fractionate with RNA polymerase II at 24 hpi (325). P6.9 appears to be phosphorylated immediately upon synthesis and dephosphorylated when complexed with DNA (326). Some localizes to the virogenic stroma but the majority was found near the inner nuclear membrane throughout the infection. It shows distinct patterns of phosphorylation with multiple forms present in association with ODV, however, only the dephosphorylated form was associated with BV (327). It is not clear whether the phosphorylated form of p6.9 is present within the ODV virions bound to DNA, or possibly a contaminant of the exterior. With BV, contaminating phosphorylated p6.9 would likely be stripped off as the virions are transported through the cytoplasm. Using an AcMNPV bacmid deleted for p6.9, nucleocapsids were not produced although tube-like structures similar to those associated with the deletion of VLF-1 and Ac98 (see above) were observed. The mutant appeared to synthesize normal amounts of DNA, but did not produce infectious virus (328).

### *Ac101 (361aa:41.5kDa), (Bm85:362aa:41.6kDa), (Ha89:369aa:42.6kDa), BV/ODV-C42.

Ac101 encodes a capsid-associated protein of both BV and ODV (74). Homologs have been identified in all sequenced baculovirus genomes (124). It was reported to interact in a yeast two-hybrid assay and by native gel electrophoresis (329) with pp78/83 (Ac8) that has been shown to localize to the basal end region of nucleocapsids (54, 55). Evidence suggests that it binds to PP78/83 and transports it into nuclei (330) and is involved in actin polymerization (331). It also interacts with FP25 (Ac61) and Ac141 (332). Deletion of Ac101 from an AcMNPV bacmid appeared to affect nucleocapsid formation but, although lethal, did not appear to affect DNA synthesis (333). Deletion/mutation of Ac101 was also reported to be lethal by others (330, 334).

### Ac102 (122aa:13.3kDa), (Bm86:123aa:13.5kDa), (Ha90:122aa:13.8kDa), p12.

Homologs of Ac102 are found in all lepidopteran NPV, and GV genomes, but not in hymenopteran or dipteran viruses. It appears to encode an ODV-associated protein (74) in AcMNPV and HearNPV (267). It is involved in the nuclear localization of G-actin (38, 335). Deletion is lethal as insertion/deletion mutants of this gene could not be isolated in AcMNPV (38, 334) and viral spread to other cells was not observed with a BmNPV (Bm86) knockout (15).

### *Ac103 (387aa:45.3kDa), (Bm87:387aa:45.4kDa), (Ha91:377aa:44.0kDa), p45.

Homologs of Ac103 are present in all baculovirus genomes (124). Deletion of Ac103 was lethal, no viable BV were detected, and the constructs appeared to be deficient in the envelopment of ODV and their incorporation into occlusion bodies (336).

### Ac104 (691aa:79.9kDa), (Bm88:692aa:79.9kDa), (Ha92:605aa:69.7kDa), vp80 capsid, vp87.

Homologs of Ac104 are found in all Group I and II lepidopteran NPV genomes, but not in those of GVs or hymenopteran or dipteran NPVs. It is capsid associated in both OpMNPV (337) and AcMNPV (74, 338, 339) and interacts with 38K (Ac98) (177). Deletion of Vp80 showed that it is an essential gene and resulted in nucleocapsids that were unable to move from the virogenic stroma (340). It appears to localize in nuclei near actin scaffolds that connect the virogenic stroma to the nuclear envelope. In addition, it co-immunoprecipitates with actin. It also appears to localize to one end of nucleocapsids and contains sequences similar to paramysin motifs that may be involved in the transport of virions to the periphery of nuclei (338). It forms dimers, contains a C-terminal region that was predicted to contain a basic helix-loop-helix domain, and binds to DNA (341).

### Ac105 (553aa:65.6kDa), (Bm89:289aa:34.3kDa), He65.

Homologs of Ac105 are found in the genomes of most Group I, about one-half the Group II and three GVs (Agse-, Ha-, and XecnGV). It is a member of a distinct family of ligases that includes editing ligases of trypanosomes, putative RNA ligases of many species of archaea, and also baculoviruses and an entomopoxviruses (342). It is an early-transcribed gene (343). It may be involved in the nuclear localization of G-actin (335). It appears to be a non essential gene in AcMNPV (38) and BmNPV (15).

### Ac106/107 (243aa:28.3kDa), (Bm90:249aa:28.9kDa) (Ha101:253aa:29.0kDa).

These two orfs are likely a single gene as homologs are fused in many baculoviruses and were found to be joined when the region was resequenced in the C-6 strain (12). Homologs are found in all Group I and II lepidopteran NPV, GV and hymenopteran NPV genomes, but not in that of the dipteran NPV. Deletion of Bm90 resulted in a mutant that was unable to spread between cells indicating that it is an essential gene (15).

### Ac108 (105aa:11.8kDa), (Bm91:105aa:11.8kDa) (Ha95:94aa:11.0kDa).

Orthologs of Ac108 have been found in the genomes of all alpha, beta, and gamma baculoviruses (124). Although Ac108 was not found to be ODV-associated in AcMNPV (74) or HearNPV (213), the homolog in the Antheraea pernyi nucleopolyhedrovirus (p11) was found to be associated with ODV (344). In addition, it was present in the PIF complex of AcMNPV in another report (40). Furthermore, the ortholog in Spodoptera frugiperda MNPV (sf58) appeared to be a per os infectivity factor (PIF) as mutant BV were infectious by injection of larvae, but mutant ODV were not infectious when fed to larvae (345). In BmNPV, Bm91 was ODV associated, but appeared to be non essential (15, 346).

### *Ac109 (390aa:44.8kDa), (Bm92:391aa:45.0kDa), (Ha94:361aa:41.5kDa).

Homologs of Ac109 are present in all baculovirus genomes. Evidence suggests that it is ODV-associated in AcMNPV (74) and Helicoverpa armigera NPV (Ha94-ODV-EC43) (213, 347) and also is BV-associated in AcMNPV (27, 348). Four studies have examined deletions of Ac109 and demonstrate that it is an essential gene and when deleted, DNA replication is not affected. One study reported that deletion of Ac109 resulted in a block in nucleocapsid and polyhedron formation (349). However, the other reports described different results. One indicated that polyhedra and virions were produced by Ac109 deletions, but the virus was not infectious (348). Another study found similar results but also showed that the nucleocapsids had defects in envelopment and the polyhedra lacked virions (350). A fourth report also described similar findings but indicated that the BV produced by a Ac109 knockout could enter the cytoplasm, but not nuclei and also noted that the occlusion bodies lacked virions (351).

### Ac110 (56aa:6.8kDa), (Bm92a), (Ha93:58aa:6.9kDa).

Homologs of Ac110 are present in all lepidopteran baculovirus genomes. Deletion of Bm92a had no effects on virus replication (15).

### Ac111 (67aa:8.2kDa), (Bm93:67aa: 8.2kDa), (Ha116:71aa:8.2kDa).

Homologs of Ac111 are present in genomes of all Group I, four Group II (Hear-, Heze-, Ld-, and LeseNPV) and two GVs (SpliGV and XecnGV). Deletion of Bm93 had no effects on virus replication (15).

### Ac112/113 (258aa:30.9kDa).

These two orfs are likely a single gene as homologs are fused in many baculoviruses and were found to be joined when the region was resequenced in the C-6 strain (12). Homologs are present in three Group I variants of AcMNPV (Ac-, Plxy-, and RoMNPV), one Group II NPV (LdMNPV) and three GV (Spli- Hear-, and XecnGV) genomes. It shows highly significant homology to FPV217, a hypothetical protein of fowlpox virus (E = 8e-28). BLAST searches with FP217 only picks out baculovirus Ac112 homologs. A related orf is not present in BmNPV (16). The ortholog of this orf in LdMNPV (ld109) is a suppressor of apoptosis called apsup. They show about 30% amino acid sequence identity, but Ac112/113 did not show any apoptotic activity (352).

### Ac114 (424aa:49.3kDa), (Bm94:424aa:49.4kDa).

Homologs of Ac114 are found in all Group I NPV genomes. It shows some homology to a hypothetical orf of Plasmodium falciparum 3D7 (E = 5e-04). In AcMNPV it appears to be an ODV (74, 353) and BV associated protein (27). It is likely to be nonessential, as a BmNPV bacmid deleted for this gene (Bm94) appeared similar to wt (15).

### *Ac115 (204aa:23kDa), (Bm95:204aa:23.0kDa), (Ha90:199aa:22.4kDa), pif-3.

Homologs of pif-3 appear to be present in all baculovirus genomes. It is also present in nudivirus genomes (195). Like other pif genes, pif-3 is required for oral infectivity of insect but not for infection of cultured cells (88). It forms a complex with PIF-1 and PIF-2 (310). For more information see Ac138 (p74).

### Ac116 (56aa:6.4kDa), (Bm95a).

Homologs of Ac116 are found only in four Group I NPVs (Ac-, Ro-, Bm-, and PlxyNPV). Deletion Bm95a and Bm96 showed no defects as did deletion of Bm96 alone, therefore Bm95 appears to be non essential (15).

### Ac117 (95aa:11kDa), (Bm96:95aa:10.9kDa), (Ha110:88aa:10.1kDa).

Homologs of Ac117 are found in the genomes of all Group I and seven group II NPVs. It is likely to be nonessential, as insertion/deletion mutants of this gene in BmNPV (Bm96) were similar to wt, although a slight effect on the motility of infected larvae was noted (15, 160).

### Ac118 (157aa:18.7kDa).

Homologs are only found in three Group I NPVs (Ac-, Ro- and PlxyNPV) genomes. A related orf is not present in BmNPV.

### *Ac119 (530aa:59.8kDa), (Bm97:527aa:59.8kDa), (Ha111:528aa:60.3kDa), pif-1.

Homologs of pif-1 are present in all baculovirus genomes and are also present in nudivirus genomes (195). This gene can be deleted and the mutant is still infectious for cultured cells, but is not orally infectious for insects (88). It forms a complex with PIF-2 and PIF-3 (310). For more information see Ac138 (p74).

### Ac120 (82aa:9.5kDa), (Bm98:82aa:9.5kDa).

Homologs of Ac120 are found in all Group I and most Group II genomes. It is likely to be nonessential, as an insertion/deletion mutation of this gene in BmNPV (Bm98) had no apparent effect on infectivity (15).

### Ac121 (58aa:6.7kDa), (Bm98a).

Homologs of Ac121 are only found in the genomes of Bm- and PlxyNPV. It may be a transcriptional activator of some early genes, including IE1 and pp31 (354). However, it does not appear to activate late gene expression (149). In BmNPV, it appeared to be non essential (15).

### Ac122 (62aa:7.2kDa), (Bm99:61aa:7.1kDa).

Homologs of Ac122 are present in all sequenced Group I genomes except EppoNPV. It is likely to be nonessential, as an insertion mutation of this gene in BmNPV (Bm99) had no apparent effect on infectivity (15).

### Ac123 (215aa:25kDa), (Bm100:225aa:26.0kDa), Protein kinase 2 (PK2).

Homologs of Ac123 are found only in BmNPV, PlxyNPV and RoMNPV and they are all over 98% identical to AcPK2. PK2 is closely related to translation initiation factor eIF 2α kinase (e.g., B. mori (E = 2e-20)), and the homology appears to be focused on the C-terminal region of the kinase domain (355). An AcMNPV mutant deleted for pk2 displayed no differences from wt in its infectivity to cultured cells and insect larvae (355). In contrast, PK2 (Bm100) from BmNPV was found to be required for replication in BmN cells (111). In addition, novel eIF-2alpha kinase called BeK was identified from B. mori. It has a distinct N-terminal requlatory region not shared by other eIF-2alpha kinases. BmPK2 was found to be capable of inhibiting the enzymatic activity of BeK (356). AcMNPV PK2 was found to inhibit yeast and human eIF2α kinases (357). Insect cells infected with wt showed reduced eIF2α phosphorylation and increased translational activity that was not observed in cells infected with the pk2 deletion mutant. It was suggested that this gene could be involved in a mechanism for inactivating a host stress response to virus infection (357). Sf9 cell infection by AcMNPV deleted for PK2 or by wt virus both encoding the p35 anti-apoptotic gene was found to induce the expression of BiP. BiP is a stress marker of the endoplasmic reticulum and a chaperone. It was observed, however, that the UV induction of eIF2alpha phosphorylation and the activation of caspase were mitigated more effectively by the wt virus than the mutant virus that lacks pK2, which is an eIF2alpha kinase inhibitor (358).

### Ac124 (247aa:28.5kDa), (Bm101:244aa:28.1kDa).

Homologs of Ac124 are present in the genomes of all sequenced Group I lepidopteran NPVs. It has been shown to be BV associated (27). In BmNPV, it appeared to be a non essential gene (15).

### Ac125 (226aa:26.6kDa), (Bm102:227aa:26.6kDa), lef-7.

Homologs of lef-7 are present in the genomes of all Group I, three Group II (Se-, Sf- and MacoNPV A) and two GVs ( Ha- and XecnGV). Lef-7 is stimulatory for transient DNA replication (43, 359). When deleted, infection was unaffected in Tn368 cells, but in Sf21 and Se1c cells DNA replication was 10% of wt (360). Deletion of BmNPV lef-7 also caused a reduction in BmNPV DNA synthesis (66). LEF-7 was found to be involved in the regulation of the DNA damage response (DDR). It appears to be an F-box protein that interacts with host S-phase kinase-associated protein 1 (SKP1). SKP1 is a component of a complex that interacts with and targets proteins for polyubiquitination. Deletion of lef-7 from the AcMNPV genome resulted in the accumulation of phosphorylated H2AX and activation of the DDR that led to a major reduction in late gene expression and reduced infectious virus production by 100 fold. It was suggested that LEF-7 may interfere with the phosphorylation of H2AX thereby diverting host DDR proteins from cellular chromatin, so that they can be exploited for viral DNA replication (361).

### Ac126 (551aa:61.4kDa), (Bm103:552aa:61.8kDa), (Ha41:570aa:65.5kDa), chitinase.

As of 2008, homologs of chitinase were reported in genomes of all Group I (except AgMNPV), all Group II (except AdhoNPV) and four GVs (Agse, Cp-, Ha-, and XecnGV) and is phylogenetically clustered with a number of lepidopteran chitinases, i.e., it shows 63% aa sequence identity to B. mori chitinase. Comparison of BmNPV and B. mori chitinases indicated that, although closely related, they have different properties; the viral chitinase is retained in the cell and functions under alkaline conditions, whereas the host enzyme is secreted and has reduced activity at higher pH (362). Phylogenetic studies indicate that it is more closely related to the chitinase of proteobacteria that employ the enzyme to degrade fungal chitins (363). It has a mode of action similar to Serratia marcescens chitinase to which it is 60.5% identical and processively hydrolyzes beta-chitin (364). In conjunction with Ac127 (cathepsin), chitinase participates in the liquefaction of insects late in infection. It is a late expressed gene and its product is localized to the cytoplasm (365) and also is BV associated (27). When it is deleted along with Ac127 (cathepsin), insects remained intact for several days after death (366). Chitinase is localized to the endoplasmic reticulum in infected cells by KEDL, an endoplasmic reticulum retention motif (367, 368). The retention in the ER may prevent the premature death and liquefaction of infected insects, allowing the virus to continue to replicate. It is thought that the presence of chitinase and cathepsin assists in the dissemination of the virus by degrading the insect upon its death. The facility with which a virus (Anticarsia gemmatalis NPV) can be processed for use as a biocontrol agent has been attributed to its lack of these two genes, thereby allowing collection of the virus from intact rather than disintegrated insects (369).

### Ac127 (323aa:36.9kDa), (Bm104:323aa:36.9kDa), (Ha56:365aa:42.0kDa), cathepsin, vcath, a metalloprotease.

Homologs of Ac127, cathepsin, have a similar distribution to Ac126 (chitinase) and are present in the genomes of all Group I (except AgMNPV), all Group II and four GVs (Agse-, Cp-, Crle-, and XecnGV). The baculovirus genes are closely related to insect cathepsins, i.e. Ac127 is 39% identical to an Apis mellifera cathepsin. The baculovirus cathepsin appears to participate along with chitinase in the liquefaction of infected insects (see Ac126) (370). When it is deleted along with Ac126 (chitinase), insects remained intact for several days after death (366). It has been suggested that Ac127 is synthesized in an inactive form that is activated upon death of the insect by lysosomal proteinases (371). It was subsequently demonstrated that AcMNPV and CfMNPV cathepsins are expressed as pre-proenzymes that are cleaved in infected cells (372). Viral chitinase (see above) is apparently synthesized before cathepsin to facilitate cathepsins retention in the ER. Cathepsin is synthesized as an inactive precursor (preproV-CATH) and upon translation the N-terminal 22 amino acids encompassing the signal peptide causes the localization to the ER during which the signal peptide is cleaved. Within the ER the viral chitinase appears to interact with the proV-CATH and assists in the proper folding and causes its retention in the ER (373). Upon death of the host proV-CATH is cleaved and activated and released from the ER along with chitinase to facilitate the degradation of the insect and release of the virus.

### Ac128 (530aa:60.6kDa), (Bm105:530aa:60.6kDa), gp64, gp67.

gp64 encodes a low pH activated envelope fusion protein, and homologs are present in all Group I genomes. It is one of the major distinguishing features of these viruses. It is thought that all Group I viruses use GP64 for the entry of BV into cells, whereas all other baculoviruses lack a gp64 homolog and use the F protein (ac23 homolog) except for hymenopteran NPVs which lack both genes. In addition to the Group I NPVs, homologs of gp64 are also found in thogotoviruses, which are members of the Orthomyxoviridae (374). GP64 (375-377) is a fatty acid acylated glycoprotein (378). Deletion of gp64 is lethal and results in viruses that replicate in a single cell, but cannot bud out and infect surrounding cells (379, 380). The postfusion structure of GP64 has been described (381).

### Ac129 (198aa:22.1kDa), (Bm106:195aa:21.8kDa), (Ha118:248aa:28.4kDa), p24-capsid.

Homologs of Ac129 are present in the genomes of all Group I /II and GV genomes. Ac129 (p24) is associated with both BV and ODV of AcMNPV and OpMNPV (27, 382). Its presence in AcMNPV ODV was confirmed, however, the HearNPV homolog, He118, was not found associated with ODV (213). It is likely to be nonessential, as interruption of this gene with a transposable element in a strain of AcMNPV has been reported (383, 384). In addition, insertion/deletion mutations of this gene in BmNPV (Bm106), although viable, took slightly longer to kill insects than wt (160). Also, LdMNPV, the original strain sequenced, lacked this gene, whereas it is present in other strains (385).

### Ac130 (106aa:12.1kDa), (Bm107:106aa:12.1kDa), (Ha119:94aa:10.7kDa), gp16.

Homologs of Ac130 are present in the genomes of all Group I, all Group II except (LdMNPV and LeseNPV), but are not present in those of GVs. In OpMNPV, the homolog (Op128) is glycosylated and localized near the nuclear membrane in the cytoplasm. Although it appeared to be associated with envelopes of nucleocapsids in the cytoplasm, it was not associated with either ODV or BV (386). It appears to be a non essential gene in BmNPV (15).

### Ac131 (322aa:36.4kDa), (Bm108:315aa:35.4kDa), (Ha120:340aa:39.1kDa), calyx, polyhedron envelope (PE) protein, pp34.

Orthologs of Ac131 have been found in the genomes of all alpha, beta, and gamma baculoviruses (124)(173). In addition, domains of PE may be present as fusion with segments of p10 in some GVs (see below). The calyx/polyhedron envelope was originally found to be composed of carbohydrate (387); subsequently a phosphorylated protein component was identified (388) and was shown to be associated with the calyx/PE (389). Similar results were obtained for OpMNPV and it was also found to be associated with p10 fibrillar structures (390-393). In addition, in some viral genomes, genes are present that appear to be fusions of both PE and p10 protein domains (394, 395). The Ac131 encoded protein appears to be an integral component of the calyx/PE, and when the gene is deleted, polyhedra lack an intact calyx/PE, and have a rough surface showing cavities where virions have apparently been dislodged (396). It has also been reported to be BV associated (27) although what role it may play in this phenotype is not clear. The function of the calyx/PE appears to be to encase the occlusion body in order to enhance its stability. See Chapter 2 for additional information. The predicted size of Ac131 is longer (322 vs 252 aa) than previously reported (12).

### Ac132 (219aa:25.1kDa), (Bm109:220aa:25.2kDa).

Homologs of Ac132 are present in all sequenced Group I genomes. Ac132 was identified as being associated with AcMNPV ODV(74) and BV (27). Bm109 was also reported to be ODV associated (397). In BmNPV, it appear to be an essential gene (15).

### *Ac133 (419aa:48.3kDa), (Bm110:420aa:48.5kDa), (Ha114:428aa:49.4kDa), Alkaline nuclease (AN).

Homologs of alkaline nuclease (AN) are found in all baculovirus genomes. They are also found in a variety of other viruses such as lambda phage and herpes viruses. In these viruses, the AN homolog associates with an SSB and has an exonuclease activity which generates 3' single-strand DNA ends that can participate in DNA recombination. In AcMNPV, AN interacts and co-purifies with the SSB LEF-3 and has both a 5'→3' exonuclease and an endonuclease activity (224, 225, 398). Deletion of Ac133 is lethal (399, 400). It is thought that AN is involved in DNA recombination. Homologs are also present in nudiviruses and hytrosaviruses. In Epinotia aporema granulovirus (EpapGV), the ortholog of Ac133 is fused with an ortholog of helicase 2 (401) (see Chapter 13) suggesting that they might act together possibly for the maturation of Okazaki intermediates. Ac133 may act as Fen nuclease in this process as its endonuclease and the single strand specific 5' to 3' exonuclease could be involved in the digestion of the primer overhangs generated by helicases.

### Ac134 (Bm111:803aa:94.5kDa) (p94).

Homologs of Ac134 are present in the genomes of most Group I, three Group II (MacoA- MacoB-, Se- and SfMNPV), and three GVs (Agse-, Hear- and XecnGV). Homologs are found in several polydnaviruses, e.g., Cotesia congregata bracovirus (E = 7e-40) and entomopox viruses, e.g., Melanoplus sanguinipes entomopoxvirus (E = 1e-04), and several protozoa, some of which are insect-associated, e.g., the acetyl-CoA carboxylase 1 precursor of Plasmodium yoelii (E = 2e-05). The disruption of the p94 gene showed no effect on the ability of AcMNPV to infect S. frugiperda larvae by either the oral or intrahaemocelic route (402).

### Ac135 (299aa:34.8kDa), (Bm112:299aa:34.5kDa), p35.

P35 is an inhibitor of apoptosis, and homologs are limited to a few Group I NPVs closely related to AcMNPV. A homolog has also been reported in a GV of Choristoneura occidentalis (ChocGV) (394), and a variant (p49) is found in a Group II NPV (SpliNPV) genome (403, 404). Furthermore, a homolog most closely related to SpliNPV p49 has also been identified in an entomopox virus genome (405). P35 is able to block apoptosis in S. frugiperda cells caused by AcMNPV infection (406). Although deletion mutants are viable, they are severely compromised in BV production in Sf cells (406, 407). The crystal structure of p35 has been described (408) (409). For additional information, see Chapter 7.

### Ac136 (240aa:27.3kDa), (Bm113:240aa:27.3kDa), (Ha22:267aa:30.5kDa), p26.

Homologs of p26 are present in the genomes of all Group I, all Group II except (SpliNPV), but are not present in those of GVs. Multiple copies of the gene may be present. Homologs are also found in the genomes of numerous pox viruses, e.g., Vaccinia (E = 0.15, 25% identity over 201 aa). Ac126 forms homodimers and is primarily a cytoplasmic protein (410). The examination of an AcMNPV deleted for p26 revealed no differences from wt in the cells and larvae tested (411). However, a deletion of p26 along with p10 and p74 resulted in polyhedra lacking virions (412).

### Ac137 (94aa:10.3kDa), (Bm114:70aa:7.5kDa), (Ha21:87aa:9.3kDa), p10.

Homologs of p10 are found in the genomes of all Group I and II NPVs and most GVs, in some instances in multiple copies (413). They are also present in all hymenopteran NPV genomes. A p10 homolog has been characterized in an entomopox virus (414). P10 was originally identified as a very late hyperexpressed gene (415) and therefore the p10 promoter has been used in expression vectors (416). P10 interacts with tubulin (417) and forms two different types of structures; microtubule-associated filaments, and tube-like structures that surround the nucleus (418). As noted above, p10 appears to be associated with the PE protein (Ac131) and in some viral genomes, genes are present that appear to be fusions of both PE and p10 protein domains (394, 395). Deletions of P10 result in polyhedra that resemble those produced by mutants lacking the calyx/polyhedron envelope protein (Ac131); they are fragile, have a rough surface showing cavities where virions have apparently been dislodged, and often show an incomplete calyx/polyhedron envelope (396, 419, 420). For more information, see Chapter 2.

### *Ac138 (645aa:73.9kDa), (Bm115:645aa:74.0kDa), (Ha20:688aa:78.4kDa), p74-pif.

P74 was the first member to be identified of proteins called per os infectivity factors that are required for oral infection of insects, but are dispensable for infection of cultured cells. Homologs of p74 along with the other pif genes, pif-1 (ac119), -2 (ac22), and -3 (ac115) are present in all baculovirus genomes and are also found in genomes of nudiviruses (195). P74 was the first such protein identified and characterized (87, 421-424). Three other pif genes were identified in BmNPV (425) and subsequently their homologs were characterized in AcMNPV. AcMNPV deleted for pif-1, -2, or -3 are not orally infectious for T. ni or S. exigua larvae based on feeding of 10,000 PIB of the deleted virus. They are also not orally infectious for H. virescens, except for the pif-2 mutant that shows limited infectivity. In contrast, injection of 1 pfu, of the three deletion mutants, into third instar larvae of the three insect species caused over 80% mortality. In addition, PIF1, PIF2, and p74 mediate specific binding of occlusion derived virus to midgut cells, suggesting that they are directly involved in virus cell interaction as an initial step in infection (88). Although PIF-3 appears to be an ODV associated protein (426), it does not appear to be involved in specific binding and its function is not known. Both P74 (421) and a homolog of PIF-1 from Spodoptera littoralis NPV (427) also appear to be components of the ODV envelope. Co-infection with a wt- and a p74-deleted virus expressing gfp resulted in per os infection by the gfp expressing virus, suggesting the p74 did not have to be directly associated with a virus to facilitate per os infection. In addition, a 35-kDa binding partner for AcMNPV P74 was detected in extracts of brush border membrane vesicles from host larvae (Spodoptera exigua), but not from a nonhost (Helicoverpa armigera larvae) (424). The identity of this host protein has not been determined. By proteomic analysis, P74 was found associated with AcMNPV, HearNPV and CuniNPV ODV (74, 213) (93); however, the other PIF proteins showed differing associations,e.g., CuniNPV (PIF-1,2,3), AcMNPV (PIF-2) and HearNPV (PIF-1). Ac145 and Ac150 also may be pif genes (see below). P74 appears to be cleaved into two fragments by a protease associated with occlusion bodies produced in insects. This cleavage does not occur in polyhedra produced in cell culture. The significance of the cleavage is not clear because cell culture and insect produced polyhedra appear to be equally infectious (428).

### Ac 139 (449aa:52.6kDa), (Bm116:451aa:52.6kDa), (Ha16:284aa:33.6kDa),ME53.

Homologs of ac139 are present in the genomes of all the lepidopteran NPVs and GVs, but have not been reported in hymenopteran or diperan baculovirus genomes. It is BV and ODV associated (429). One study indicated that AcMNPV deleted for this gene is not viable and fails to replicate its DNA and does not produce nucleocapsids. However, cells transfected with DNA from the mutant showed early stages of cpe, including nuclear enlargement and the formation of granular material in the nucleus (430). This suggests that the mutant is blocked in an early gene function. This is consistent with its original characterization as a major early gene (431). However, another study showed that deletion of Ac139 did not alter DNA replication, but results in a 1000-fold reduction in BV titer. In addition, it was found that it appears to be required both early and late in infection (429). ME53 fused to GFP localized mostly to the cytoplasm early and to nuclei late in infection. However, foci of ME53 were also noted at the cell periphery late in infection and co-localized with gp64 and VP39-capsid and was capsid associated in BV. It was suggested that it may provide a connection between the nucleocapsid and the viral envelope (432).

### Ac140 (60aa:7.1kDa).

This orf encodes 60 aa and is only found in AcMNPV.

### Ac141 (261aa:30.1kDa), (Bm117:261aa:30.1kDa), (Ha8:285aa:33.2kDa), exon0.

Homologs of Ac141 are found in all lepidopteran NPVs, and orfs with low homology are also found in GV genomes. In AcMNPV it is associated with both BV and ODV nucleocapsids (27, 433) and interacts with BV/ODV-C42 (Ac101) and FP25 (Ac61) (332). Ac141 contains a predicted RING finger domain (434) that is a type of zinc finger comprising 40-60 residues that binds two zinc atoms and may be involved in protein-protein interactions. Deletion of Ac141 severely compromises BV production and results in virus that appear to be restricted to cells initially infected, suggesting that Ac141 may be required for efficient egress of BV (433, 434). It appears to both co-localize with and co-purifiy with β-tubulin, and inhibitors of microtubules reduced BV production by over 85% (435). It has also been shown to interact with a conserved domain of kinesin 1, a motor protein involved in transporting cargo along microtubules to the periphery of the cell further supporting a role for microtubules in the transport of virions to the cell surface (280). Therefore, it has been suggested that the interaction of Ac141 with microtubules might be involved in the egress of BV.

### *Ac142 (477aa:55.4kDa), (Bm118:476aa:55.5kDa), (Ha9:468aa:55.3kDa), p49.

Homologs of Ac142 have been identified in all sequenced baculovirus genomes. Ac142 is associated with both BV and ODV virions, and deletion of Ac142 appeared to affect nucleocapsid formation but, although lethal, did not appear to affect DNA synthesis (333). Another study describing a different bacmid construct that deleted less of the Ac142 gene showed similar results except that some nucleocapsids appeared to be fully formed, but were un-enveloped in the nucleus and were not occluded (436). It is unclear whether the difference in the two studies was due to the removal of a 3' processing signal for the upstream Ac141 gene in the former investigation, or to the presence of a significant portion of the Ac142 orf in the latter study. A BmNPV deleted for Bm118 failed to produce BV and produced polyhedra lacking virions. There appeared to be a defect in nucleocapsid formation as elongated capsid-like particles apparently devoid of DNA were observed (437). Mass spectrometry also suggests that Ac142 is ODV-associated in three different viruses (74, 93, 213).

### *Ac143 (90aa:9.7kDa), (Bm119:101aa:10.4kDa), (Ha10:81aa:8.8kDa), ODV-E18.

Homologs of Ac143 are present in the genomes of all baculoviruses. An antibody generated against an Ac143-GST fusion reacted with a protein of 18 kDa in the ODV envelope fraction, and Ac143 was named ODV-E18 (438). Ac143 and its HearNPV homolog were found in surveys of ODV-associated proteins by mass spectrometry (74, 213). No BV is produced when Ac143 is deleted (439). Ac143 was found to be BV associated in a proteomic analysis (27).The predicted size of Ac143 is longer than previously reported (90 vs 62aa) (12).

### *Ac144 (290aa:33.5kDa), (Bm120:290aa:33.5kDa), (Ha11:284aa:33.3kDa).

Homologs of Ac144 are present in all sequenced baculovirus genomes. Ac144 was named ODV-EC27; however, other data suggests that it is present in both BV and ODV and has a molecular weight of 33.5 kDa (see below). Mass spectrometry also suggests that Ac144 is ODV-associated in three different viruses (74, 93, 213). A variety of investigations have been conducted on Ac144. Initially, it was confirmed that its transcript initiates at a late promoter element (438). Later, it was suggested that it is a multifunctional cyclin and may be involved in regulating the cell cycle during virus infection (440). It was reported to interact in a yeast two-hybrid assay with Ac101 described above (also named C42) and with both Ac101 and p78/83 (Ac9) in native gel electrophoresis assays (329). Although this orf was designated as ODV-EC27, another investigation using an HA-tagged Ac144 recombinant virus and anti-HA monoclonal antibodies found that Ac144 was expressed as an ~ 33.5 kDa protein which conforms to the predicted MW (333). In addition, it was found to be BV associated (27, 333). It was also found that deletion of Ac144 appeared to affect nucleocapsid formation but, although lethal, did not appear to affect DNA synthesis (333).

### Ac145 (97.0aa:8.9kDa), (Bm121:95aa:11.0kDa), (Ha12:92aa:10.8kDa), (pif?).

Ac145 and Ac150 encode small proteins (~9 and 11 kDa, respectively) that are related to one another (23% aa sequence identity) and are also related to a gene encoding an 11-kDa protein in an entomopox virus of Heliothis armigera. Close relatives of Ac145 are found in all baculovirus genomes including lepidopteran NPVs and GVs, and hymenopteran NPVs, but not the dipteran NPV. In contrast to Ac145, close relatives of Ac150 are only found in a few NPVs closely related to AcMNPV. However, it shows significant homology (E = ~10^-3^) to predicted proteins from several dipteran insects. Ac145 and 150 are predicted to encode a domain thought to bind to chitin (441). In one study (442), deletion of Ac145 led to a sixfold drop in infectivity in T. ni, but not H. virescens larvae. An effect of deletion of Ac150 was not detected. Deletion of both genes causes a major (39-fold) reduction of infectivity for H. virescens. Injection of BV of the double mutant intrahemocoelically was as infectious as wt suggesting that these genes play a role in oral infection. These properties suggest that Ac145 and Ac150 are pif genes. Products of ac145 and ac150 were found to be associated with both BV and ODV. In another study (443), occluded virions deleted for Ac150 were found to be significantly less virulent when administered per os than the wt virus in Heliothis virescens, S. exigua and T. ni larvae. Evidence suggested that the mutant had a reduction in its ability to establish primary infections in midgut cells. The Ac145 homolog in HearSNPV was found to bind to chitin (444). For related genes see Ac138 (p74). The predicted size of Ac145 is longer (97 vs 77 aa) than previously reported (12).

### Ac146 (201aa:22.9kDa), (Bm122:201aa:22.9kDa), (Ha13:203aa:22.9kDa).

Homologs of Ac146 are present in the genomes of all lepidopteran NPV and GV genomes, but are not present in those of hymenopteran or dipteran. When Bm122 was fused with gfp, nuclear localization was observed (445). Ac146 is expressed at late times pi. Deletion resulted in a defective virus that did not produce BV. A HA-tagged Ac146 bacmid construct indicated that Ac146 was associated with both BV nucleocapsids, but not envelopes and ODV suggesting that it may be a structural protein. In BV it appeared as a polypeptide of 23kDa that conforms to its predicted mass, whereas in ODV, there were two sizes, one of 23kDa and the other of 34kDa. It is likely an essential gene, as infectious BV was not produced by an mutant deleted for Ac146 (446).

### Ac147 (582aa:66.9kDa), (Bm123:584aa:66.9kDa), (Ha14:655aa:76.0kDa), immediate early gene-1 (IE-1).

Homologs of IE-1 have been identified in all Group I and II genomes sequenced. They also appear to be present in all GV genomes, but the homology is very low, e.g., XcGVorf9 vs. Ac147 show about 10% amino acid sequence identity. However, the orientation and position of XcGV orf9 relative to more conserved orfs is similar to Ac147, suggesting that the limited homology might be real. In addition, the limited identity is located in conserved regions that are identified by other more convincing alignments, e.g., Ac-Ie1 vs. Ld-Ie1 (23% identity). Part of the IE-1 population is called IE-0 and is translated from a larger spliced mRNA, which is the only major spliced transcript described for baculoviruses (see below Ac147-0). IE-1 was originally identified because of its ability to transactivate early promoters of AcMNPV (132). The ability of IE-1 to transactivate transcription is greatly enhanced when the activated gene is linked to hr sequences (447). It also may participate in the negative regulation of some genes (448). IE-1 is required for transient DNA replication (42, 43). Whereas deletions of either IE-1 or IE-0 can support infectious virus production, inactivation/deletion of both these genes is lethal (449). Similar results were reported for BmNPV (66).

### Ac147-0 (636aa:72kDa) (ie-0).

Part of the IE-1 population is called IE-0 and is translated from a larger spliced mRNA, which is the only major spliced transcript described for baculoviruses and in AcMNPV results in an additional 54 amino acids at the N-terminus of IE-1 for a total of 636 amino acids (450). AcMNPV IE-1 is present as a homodimer but also can form a heterodimer with IE-0, and either IE-1 or IE-0 can support infectious virus production; however, there were subtle differences in timing of events and production of BV and polyhedra, depending on which gene is being expressed, suggesting that both ie-0 and ie-1 are required for wt levels of infection. As described above, ie-0 can be eliminated, as long as IE-1 is being produced (449). In contrast, in LdMNPV only the spliced form is able to transactivate transient transcription and DNA replication (451).

### *Ac148 (376aa:40.9kDa), (Bm124:375aa:41.3kDa), (Ha15:354aa:38.9kDa), odv-e56, PIF-5.

Homologs of odv-e56 are present in the genomes of all baculovirus and are also present in nudivirus genomes (195). ODV-E56 localizes to the envelopes of occluded virions (452) in AcMNPV and other baculoviruses (453) and has also been reported to be associated with AcMNPV BV (27). An insertion mutant, in which the lacZ gene was placed in frame at about amino acid 139 (out of 376) was viable (452). Ac148 and its homologs in HearNPV and CuniNPV were found to be ODV associated (74, 93, 213). Deletion of Ac148 from a bacmid construct resulted in a virus that could replicate in cell lines, but not insects. Consequently it was concluded that Ac148 is a per os infectivity factor, the 5^th^ such protein identified in the AcMNPV genome (454, 455). Similar conclusions were drawn for a BmNPV deletion of Bm124 (456).

### Ac149 (107aa:12.4kDa), (Bm125:106aa:12.3kDa).

Homologs of Ac149 are present in 4 other Group I viruses closely related to AcMNPV (Bm-, Mavi-, Plxy-, and RoNPV). It is likely to be nonessential as BmNPV with insertion/deletion mutations of this gene (Bm125) appeared normal (15).

### Ac150 (99aa:11.2kDa), (Bm126:115aa:13.4kDa), pif?.

Ac150 is related to Ac145. In contrast to Ac145 homologs that are found in lepidopteran NPV and GV and hymenopteran NPV genomes, Ac150 is only found in a few group I NPVs closely related to AcMNPV. in AcMNPV, deletion results in less infectivity by occluded virions for larvae (443). In BmNPV, deletion resulted in no apparent difference in BV production of mean lethal dose by occlusion bodies although the lethal time was extended somewhat (457). For more information, see Ac145 and Ac138 (p74).

### Ac151 (408aa:47kDa), (Bm127:422aa:48.8kDa), ie-2/ie-n.

Homologs of ie-2 are limited to the genomes of all Group I lepidopteran NPVs. IE-2 contains a predicted RING finger domain and shows significant levels of similarity to a protein of Trichomonas vaginalis (E = 1e-06), an anaerobic, parasitic flagellated protozoan. IE-2 was found to augment activation by IE-1 (458-460). BmNPV IE-2 interacts with itself (461). IE-2 was required for optimal origin specific plasmid DNA replication in Sf-21 cells, but had little effect in Tn-368 cells (234). Ie-2 deletion mutants behaved differently in Sf-21 cells in which the infection was delayed vs. Tn-5B1-4 cells, in which the infection was not delayed. In insect larvae, the mutant viruses were significantly less infectious than wt, which appeared to be due to a lack of virions in the occlusion bodies (462). IE-2 may also be involved in cell cycle regulation (463).

### Ac152 (92aa:10.8kDa).

Homologs of Ac152 are present in the genomes of four Group I NPVs closely related to AcMNPV, and three Group II NPVs. It is associated with the nuclear localization of G-actin (335). Deletion resulted in reduced BV titers (38). Orthologs are not found in the BmNPV or HaSNPV genomes.

### Ac153 (321aa:37.4kDa), (Bm128:309aa:36.1kDa), pe38.

Ac153 homologs have an unusual distribution being found in all Group I NPV and four GV genomes. Duplicate copies appear to be present in some of the genomes. Ac153 was originally identified because of its early transcription profile and the presence of predicted zinc finger and leucine zipper motifs (464). However,in OpMNPV it was shown to be expressed as full length (34 kda) and truncated (20 kda) forms with the larger variant functioning as a transcriptional transactivator of an early promoter (465). In addition, it appears to activate DNA replication in transient assays (42). Deletion of pe38 results in a reduction in the expression of several genes, a delay in DNA replication, a 99% reduction in BV production, and reduced levels of DNA synthesis and was less orally infectious in larvae (466, 467).

### Ac154 (81aa:9.4kDa), (Bm129:77aa:8.9kDa).

Homologs of Ac154 are present in 4 other Group I viruses closely related to AcMNPV (Bm-, Mavi-, Plxy-, and RoNPV). It is likely to be nonessential, as an insertion mutation of this gene in BmNPV (Bm129) had no apparent effect on infectivity (15).

### Hrs (homologous regions).

In AcMNPV, hrs are comprised of repeated units of about 70-bp with an imperfect 30-bp palindrome near their center. They are repeated at eight locations in the genome with 2 to 8 repeats at each site. They are highly variable, and although they are closely related within a genome, they may show very limited homology between different viruses. For example, in the CpGV genome, tandem repeated sequences are not evident, although a 75-bp imperfect palindrome is present at 13 different locations on the genome (468). In addition, in the TnSNPV (Group II) and several other genomes, hrs were not found (469), reviewed in (470). Hrs have been implicated both as transcriptional enhancers and origins of DNA replication for several baculoviruses (447, 471-475). They bind the transcriptional activator IE-1 (Ac147) (476-478) and this binding may cause IE-1 to localize into foci which may be a prelude to replication loci (479). Hrs contain a high concentration of cAMP and TPA response elements (CRE and TRE) that bind cellular transcription factors and stimulate RNA polymerase II dependent transcription and enhance activation by IE-1 (480). It has been shown that deletion of individual hrs or combinations of two hrs does not appear to affect virus replication in cultured cells (481).

## References

1 Vail P., et al. (1971). Recipocal infectivity of nuclear polyhedrosis viruses of the cabbage looper and alfalfa looper. J. Invertebr. Pathol.
2 Vaughn J.L., et al. (1977). The establishment of two cell lines from the insect Spodoptera frugiperda (Lepidoptera: Noctuidae). In Vitro.
3 Hink W.F. (1970). Established insect cell line from the cabbage looper, Trichoplusia ni. Nature.
4 Smith G.E., Summers M.D., Fraser M.J. (1983). Production of human beta interferon in insect cells infected with a baculovirus expression vector. Mol. Cell. Biol.
5 Pennock G.D., Shoemaker C., Miller L.K. (1984). Strong and regulated expression of Escherichia coli B-galactosidase in insect cells with a baculovirus vector. Mol. Cell. Biol.
6 Ayres M.D., et al. (1994). The complete DNA sequence of Autographa californica nuclear polyhedrosis virus. Virology.
7 Luckow V.A., et al. (1993). Efficient generation of infectious recombinant baculoviruses by site-specific transposon-mediated insertion of foreign genes into a baculovirus genome propagated in Escherichia coli. J. Virol.
8 Bideshi D.K., Federici B.A. (2000). The Trichoplusia ni granulovirus helicase is unable to support replication of Autographa californica multicapsid nucleopolyhedrovirus in cells and larvae of T. ni. J Gen Virol.
9 Datsenko K.A., Wanner B.L. (2000). One-step inactivation of chromosomal genes in Escherichia coli K-12 using PCR products. Proc Natl Acad Sci U S A.
10 Lung O.Y., Cruz-Alvarez M., Blissard G.W. (2003). Ac23, an envelope fusion protein homolog in the baculovirus Autographa californica multicapsid nucleopolyhedrovirus, is a viral pathogenicity factor. J Virol.
11 Roncarati R., Knebel-Morsdorf D. (1997). Identification of the early actin-rearrangement-inducing factor gene, arif-1, from Autographa californica multicapsid nuclear polyhedrosis virus. J Virol.
12 Harrison R.L., Bonning B.C. (2003). Comparative analysis of the genomes of Rachiplusia ou and Autographa californica multiple nucleopolyhedroviruses. J. Gen Virol.
13 Lu A., Miller L.K. (1994). Identification of three late expression factor genes within the 33.8- to 43.4-map-unit region of Autographa californica nuclear polyhedrosis virus. J. Virol.
14 Harrison R.L., Lynn D.E. (2007). Genomic sequence analysis of a nucleopolyhedrovirus isolated from the diamondback moth, Plutella xylostella. Virus Genes.
15 Ono C., et al. (2012). Phenotypic grouping of 141 BmNPVs lacking viral gene sequences. Virus Res.
16 Gomi S., Majima K., Maeda S. (1999). Sequence analysis of the genome of Bombyx mori nucleopolyhedrovirus. J Gen Virol.
17 Chen X., et al. (2001). The sequence of the Helicoverpa armigera single nucleocapsid nucleopolyhedrovirus genome. J Gen Virol.
18 Kim D., Weaver R.F. (1993). Transcriptional mapping and functional analysis of the protein tyrosine/serine phosphatase (PTPase) gene of the Autographa californica nuclear polyhedrosis virus. Virology.
19 Sheng Z., Charbonneau H. (1993). The baculovirus Autographa californica encodes a protein tyrosine phosphatase. J. Biol. Chem.
20 Gross C.H., Shuman S. (1998). Characterization of a Baculovirus-Encoded RNA 5'-Triphosphatase. J. Virol.
21 Takagi T., et al. (1998). A protein tyrosine phosphatase-like protein from baculovirus has RNA 5'-triphosphatase and diphosphatase activities. Proc Natl Acad Sci U S A.
22 Changela A., et al. (2005). Crystal structure of baculovirus RNA triphosphatase complexed with phosphate. J Biol Chem.
23 Li Y., Miller L.K. (1995). Properties of a baculovirus mutant defective in the protein phosphatase gene. J. Virol.
24 Kamita S.G., et al. (2005). A baculovirus-encoded protein tyrosine phosphatase gene induces enhanced locomotory activity in a lepidopteran host. Proc Natl Acad Sci U S A.
25 Katsuma S., et al. (2012). The baculovirus uses a captured host phosphatase to induce enhanced locomotory activity in host caterpillars. PLoS Pathog.
26 van Houte S., et al. (2012). Protein Tyrosine Phosphatase-Induced Hyperactivity Is a Conserved Strategy of a Subset of BaculoViruses to Manipulate Lepidopteran Host Behavior. PLoS One.
27 Wang R., et al. (2010). Proteomics of the Autographa californica Nucleopolyhedrovirus Budded Virions. J Virol.
28 Bideshi D.K., et al. (2003). Phylogenetic analysis and possible function of bro-like genes, a multigene family widespread among large double-stranded DNA viruses of invertebrates and bacteria. J Gen Virol.
29 Asgari S., et al. (2007). Sequence and organization of the Heliothis virescens ascovirus genome. J. Gen Virol.
30 Kuzio J., et al. (1999). Sequence and analysis of the genome of a baculovirus pathogenic for Lymantria dispar. Virology.
31 Lopez Ferber M., et al. (2001). Diversity, distribution, and mobility of bro gene sequences in Bombyx mori nucleopolyhedrovirus. Virus Genes.
32 Zhou J.B., et al. (2012). Identification of a new Bombyx mori nucleopolyhedrovirus and analysis of its bro gene family. Virus Genes.
33 Kang W., et al. (1999). Characterization of baculovirus repeated open reading frames (bro) in Bombyx mori nucleopolyhedrovirus. J. Virol.
34 Zemskov E.A., Kang W., Maeda S. (2000). Evidence for nucleic acid binding ability and nucleosome association of Bombyx mori nucleopolyhedrovirus BRO proteins. J. Virol.
35 Kang W.K., et al. (2003). Interaction of Bombyx mori nucleopolyhedrovirus BRO-A and host cell protein laminin. Arch Virol.
36 Olivera B.M., et al. (1994). Calcium channel diversity and neurotransmitter release: The w-conotoxins and w-agatoxins. Ann. Rev. Biochem.
37 Eldridge R., Li Y., Miller L.K. (1992). Characterization of a baculovirus gene encoding a small conotoxin-like polypeptide. J. Virol.
38 Gandhi K.M., et al. (2012). Nuclear localization of actin requires AC102 in Autographa californica multiple nucleopolyhedrovirus-infected cells. J Gen Virol.
39 Katsuma S., et al. (2012). Baculovirus-encoded protein BV/ODV-E26 determines tissue tropism and virulence in lepidopteran insects. J Virol.
40 Peng K., et al. (2012). Characterization of novel components of the baculovirus per os infectivity factor complex. J Virol.
41 Evans J.T., Leisy D.J., Rohrmann G.F. (1997). Characterization of the interaction between the baculovirus replication factors, LEF-1 and LEF-2. J. Virol.
42 Kool M., et al. (1994). Identification of genes involved in DNA replication of the Autographa californica baculovirus. Proc. Natl. Acad. Sci. USA.
43 Lu A., Miller L.K. (1995). The roles of eighteen baculovirus late expression factor genes in transcription and DNA replication. J. Virol.
44 Wu C.P., et al. (2010). Autographa californica multiple nucleopolyhedrovirus LEF-2 is a capsid protein required for amplification but not initiation of viral DNA replication. J Virol.
45 Mikhailov V.S., Rohrmann G.F. (2002). The Baculovirus Replication Factor LEF-1 is a DNA Primase. J. Virol.
46 Merrington C.L., et al. (1996). An Autographa californica nucleopolyhedrovirus lef-2 mutant: consequences for DNA replication and very late gene expression. Virology.
47 Sriram S., Gopinathan K.P. (1998). The potential role of a late gene expression factor, lef2, from Bombyx mori nuclear polyhedrosis virus in very late gene transcription and DNA replication. Virology.
48 Gearing K.L., Possee R.D. (1990). Functional analysis of a 603 nucleotide open reading frame upstream of the polyhedrin gene of Autographa californica nuclear polyhedrosis virus. J. Gen Virol.
49 Afonso C.L., et al. (2001). Genome sequence of a baculovirus pathogenic for Culex nigripalpus. J Virol.
50 Perera O.P., et al. (2006). Molecular analysis of an occlusion body protein from Culex nigripalpus nucleopolyhedrovirus (CuniNPV). J Invertebr Pathol.
51 Jehle J.A. (2004). The mosaic structure of the polyhedrin gene of the Autographa californica nucleopolyhedrovirus (AcMNPV). Virus Genes.
52 Ji X., et al. (2010). How baculovirus polyhedra fit square pegs into round holes to robustly package viruses. EMBO J.
53 Kitts P.A., Possee R.D. (1993). A method for producing recombinant baculovirus expression vectors at high frequency. BioTechniques.
54 Vialard J.E., Richardson C.D. (1993). The 1,629-nucleotide open reading frame located downstream of the Autographa californica nuclear polyhedrosis virus polyhedrin gene encodes a nucleocapsid-associated phosphoprotein. J. Virol.
55 Russell R.L.Q., Funk C.J., Rohrmann G.F. (1997). Association of a baculovirus encoded protein with the capsid basal region. Virology.
56 Goley E.D., et al. (2006). Dynamic nuclear actin assembly by Arp2/3 complex and a baculovirus WASP-like protein. Science.
57 Ohkawa T., Volkman L.E., Welch M.D. (2010). Actin-based motility drives baculovirus transit to the nucleus and cell surface. J Cell Biol.
58 Reilly L.M., Guarino L.A. (1994). The pk-1 gene of Autographa californica multinucleocapsid nuclear polyhedrosis virus encodes a protein kinase. J. Gen. Virol.
59 Liang C., et al. (2013). Autographa californica multiple nucleopolyhedrovirus PK-1 is essential for nucleocapsid assembly. Virology.
60 Fan X., Thirunavukkarasu K., Weaver R.F. (1996). Temperature-sensitive mutations in the protein kinase-1 (pk-1) gene of the Autographa californica nuclear polyhedrosis virus that block very late gene expression. Virology.
61 Mishra G., et al. (2008). Inhibition of Autographa californica nucleopolyhedrovirus (AcNPV) polyhedrin gene expression by DNAzyme knockout of its serine/threonine kinase (pk1) gene. Virus Res.
62 Mishra G., Chadha P., Das R.H. (2008). Serine/threonine kinase (pk-1) is a component of Autographa californica multiple nucleopolyhedrovirus (AcMNPV) very late gene transcription complex and it phosphorylates a 102kDa polypeptide of the complex. Virus Res.
63 Mishra G., Gautam H.K., Das R.H. (2007). Serine/Threonine kinase dependent transcription from the polyhedrin promoter of SpltNPV-I. Biochem Biophys Res Commun.
64 Soding J. (2005). Protein homology detection by HMM-HMM comparison. Bioinformatics.
65 Zhou Y., et al. (2010). Characterization of a late expression gene of Bombyx mori nucleopolyhedrovirus. Z Naturforsch C.
66 Gomi S., et al. (1997). Deletion analysis of four of eighteen late gene expression factor gene homologues of the baculovirus, BmNPV. Virology.
67 Wang Y., et al. (1995). Interaction of p53 with its consensus DNA-binding site. Mol Cell Biol.
68 O'Reilly D.R., Miller L.K. (1989). A baculovirus blocks insect molting by producing ecdysteroid UDP-glucosyl transferase. Science.
69 O'Reilly D.R., Miller L.K. (1990). Regulation of expression of a baculovirus ecdysteroid UDPglucosyltransferase gene. J. Virol.
70 O’Reilly D.R., Miller L.K. (1991). Improvement of a baculovirus pesticide by deletion of the egt gene. Bio/Technology.
71 Kumar S., Miller L.K. (1987). Effects of serial passage of AcNPV in cell culture. Virus Res.
72 Beniya H., Braunagel S.C., Summers M.D. (1998). Autographa californica nuclear polyhedrosis virus: subcellular localization and protein trafficking of BV/ODV-E26 to intranuclear membranes and viral envelopes. Virology.
73 Burks J.K., Summers M.D., Braunagel S.C. (2007). BV/ODV-E26: a palmitoylated, multifunctional structural protein of Autographa californica nucleopolyhedrovirus. Virology.
74 Braunagel S.C., et al. (2003). Determination of the protein composition of the occlusion-derived virus of Autographa californica nucleopolyhedrovirus. Proc Natl Acad Sci U S A.
75 Imai N., et al. (2004). Bombyx mori nucleopolyhedrovirus orf8 encodes a nucleic acid binding protein that colocalizes with IE1 during infection. Arch Virol.
76 Braunagel S.C., Summers M.D. (2007). Molecular Biology of the Baculovirus Occlusion-Derived Virus Envelope. Curr Drug Targets.
77 Kang W., et al. (2005). IE1 and hr facilitate the localization of Bombyx mori nucleopolyhedrovirus ORF8 to specific nuclear sites. J. Gen Virol.
78 Nie Y., Fang M., Theilmann D.A. (2009). AcMNPV AC16 (DA26, BV/ODV-E26) regulates the levels of IE0 and IE1 and binds to both proteins via a domain located within the acidic transcriptional activation domain. Virology.
79 Kang W., et al. (2012). Identification and characterization of host factors interacting with Bombyx mori nucleopolyhedrovirus ORF8. J Microbiol.
80 O'Reilly D.R., et al. (1990). Characterization of the DA26 gene in a hypervariable region of the Autographa californica nuclear polyhedrosis virus genome. J Gen Virol.
81 Nie Y., Theilmann D.A. (2010). Deletion of AcMNPV AC16 and AC17 results in delayed viral gene expression in budded virus infected cells but not transfected cells. Virology.
82 An S.H., et al. (2006). Characterization of Autographa californica multiple nucleopolyhedrovirus ORF17. Acta Virol.
83 An S.H., et al. (2005). Characterization of a late expression gene, Open reading frame 128 of Helicoverpa armigera single nucleocapsid nucleopolyhedrovirus. Arch Virol.
84 Yang Z.N., et al. (2009). Bombyx mori nucleopolyhedrovirus ORF9 is a gene involved in the budded virus production and infectivity. J Gen Virol.
85 Wang Y., et al. (2007). ac18 is not essential for the propagation of Autographa californica multiple nucleopolyhedrovirus. Virology.
86 Dreschers S., Roncarati R., Knebel-Morsdorf D. (2001). Actin rearrangement-inducing factor of baculoviruses is tyrosine phosphorylated and colocalizes to F-actin at the plasma membrane. J Virol.
87 Pijlman G.P., et al. (2002). Pivotal role of the non-hr origin of DNA replication in the genesis of defective interfering baculoviruses. J Virol.
88 Ohkawa T., et al. (2005). Specific binding of Autographa californica M nucleopolyhedrovirus occlusion-derived virus to midgut cells of Heliothis virescens larvae is mediated by products of pif genes Ac119 and Ac022 but not by Ac115. J. Virol.
89 Cheng C., et al. (2002). Analysis of the Complete Genome Sequence of the Hz-1 Virus Suggests that It Is Related to Members of the Baculoviridae. J. Virol.
90 Pearson M.N., Rohrmann G.F. (2002). Transfer, incorporation, and substitution of envelope fusion proteins among members of the Baculoviridae, Orthomyxoviridae, and Metaviridae (insect retrovirus) families. J. Virol.
91 Malik H.S., Henikoff S. (2005). Positive Selection of Iris, a Retroviral Envelope-Derived Host Gene in Drosophila melanogaster. PLoS Genet.
92 Pearson M.N., Russell R., Rohrmann G.F. (2001). Characterization of a baculovirus encoded protein that is associated with infected-cell membranes and budded virions. Virology.
93 Perera O., et al. (2007). Proteins associated with Culex nigripalpus nucleopolyhedrovirus occluded virions. J Virol.
94 Fan X., McLachlin J.R., Weaver R.F. (1998). Identification and characterization of a protein kinase-interacting protein encoded by the Autographa californica nuclear polyhedrosis virus. Virology.
95 McLachlin J.R., Yang S., Miller L.K. (1998). A baculovirus mutant defective in PKIP, a protein which interacts with a virus-encoded protein kinase. Virology.
96 Mikhailov V.S., Vanarsdall A.L., Rohrmann G.F. (2007). Isolation and characterization of the DNA-binding protein (DBP) of the Autographa californica multiple nucleopolyhedrovirus. Virology.
97 Vanarsdall A.L., Mikhailov V.S., Rohrmann G.F. (2007). Characterization of a baculovirus lacking the DBP (DNA-binding protein) gene. Virology.
98 Shen H., et al. (2012). Characterization of Bombyx mori nucleopolyhedrovirus Bm17. J Basic Microbiol.
99 Esteban D.J., Da Silva M., Upton C. (2005). New bioinformatics tools for viral genome analyses at Viral Bioinformatics - Canada. Pharmacogenomics.
100 McLachlin J.R., et al. (2001). Deletions in the Ac-iap1 gene of the baculovirus AcMNPV occur spontaneously during serial passage and confer a cell line-specific replication advantage. Virus Res.
101 Zeng X., et al. (2009). Functional analysis of the Autographa californica nucleopolyhedrovirus IAP1 and IAP2. Sci China C Life Sci.
102 Maguire T., et al. (2000). The inhibitors of apoptosis of Epiphyas postvittana nucleopolyhedrovirus. J Gen Virol.
103 Ikeda M., et al. (2011). Baculovirus IAP1 induces caspase-dependent apoptosis in insect cells. J Gen Virol.
104 Passarelli A.L., Miller L.K. (1994). Identification and transcriptional regulation of the baculovirus lef-6 gene. J. Virol.
105 Lin G., Blissard G.W. (2002). Analysis of an Autographa californica nucleopolyhedrovirus lef-11 knockout: LEF-11 is essential for viral DNA replication. J Virol.
106 Liker E., et al. (2000). The structure of the mRNA export factor TAP reveals a cis arrangement of a non-canonical RNP domain and an LRR domain. Embo J.
107 Afonso C.L., et al. (1999). The genome of Melanoplus sanguinipes entomopoxvirus. J Virol.
108 Huang J., et al. (2008). Open reading frame Bm21 of Bombyx mori nucleopolyhedrovirus is not essential for virus replication in vitro, but its deletion extends the median survival time of infected larvae. J Gen Virol.
109 Tomalski M.D., Eldridge R., Miller L.K. (1991). A baculovirus homolog of a Cu/Zn superoxide dismutase gene. Virology.
110 Bergin D., et al. (2005). Superoxide production in Galleria mellonella hemocytes: identification of proteins homologous to the NADPH oxidase complex of human neutrophils. Infect Immun.
111 Katsuma S., et al. (2008). Genome-wide survey for baculoviral host homologs using the Bombyx genome sequence. Insect Biochem Mol Biol.
112 Popovici C., et al. (2005). An evolutionary history of the FGF superfamily. Bioessays.
113 Detvisitsakun C., et al. (2005). Stimulation of cell motility by a viral fibroblast growth factor homolog: proposal for a role in viral pathogenesis. Virology.
114 Katsuma S., et al. (2006). Lepidopteran ortholog of Drosophila breathless is a receptor for the baculovirus fibroblast growth factor. J Virol.
115 Katsuma S., Shimada T., Kobayashi M. (2004). Characterization of the baculovirus Bombyx mori nucleopolyhedrovirus gene homologous to the mammalian FGF gene family. Virus Genes.
116 Detvisitsakun C., et al. (2006). Analysis of a baculovirus lacking a functional viral fibroblast growth factor homolog. Virology.
117 Detvisitsakun C., Cain E.L., Passarelli A.L. (2007). The Autographa californica M nucleopolyhedrovirus fibroblast growth factor accelerates host mortality. Virology.
118 Katsuma S., et al. (2006). In vivo and in vitro analyses of a Bombyx mori nucleopolyhedrovirus mutant lacking functional vfgf. Virology.
119 Means J.C., Passarelli A.L. (2010). Viral fibroblast growth factor, matrix metalloproteases, and caspases are associated with enhancing systemic infection by baculoviruses. Proc Natl Acad Sci U S A.
120 Wang Y., et al. (2007). MMDB: annotating protein sequences with Entrez's 3D-structure database. Nucleic Acids Res.
121 Lauzon H.A., et al. (2005). Gene organization and sequencing of the Choristoneura fumiferana defective nucleopolyhedrovirus genome. J Gen Virol.
122 Cai Y., et al. (2012). An ac34 Deletion Mutant of Autographa californica Nucleopolyhedrovirus Exhibits Delayed Late Gene Expression and a Lack of Virulence In Vivo. J Virol.
123 Salem T.Z., Zhang F., Thiem S.M. (2012). Reduced expression of Autographa californica nucleopolyhedrovirus ORF34, an essential gene, enhances heterologous gene expression. Virology.
124 Garavaglia M.J., et al. (2012). Ac53, ac78, ac101 and ac103 are newly discovered core genes in the family Baculoviridae. J Virol.
125 Guarino L.A. (1990). Identification of a viral gene encoding a ubiquitin-like protein. Proc Natl Acad Sci U S A.
126 Lin X.A., et al. (2008). Characterization of the Autographa californica nucleopolyhedrovirus ubiquitin gene promoter. Z Naturforsch [C].
127 Guo Z.J., et al. (2011). Ubiquitins of Bombyx mori nucleopolyhedrovirus and Helicoverpa armigera nucleopolyhedrovirus show distinct subcellular localization in infected cells. Acta Virol.
128 Guarino L.A., Smith G., Dong W. (1995). Ubiquitin is attached to membranes of baculovirus particles by a novel type of phospholipid anchor. Cell.
129 Reilly L.M., Guarino L.A. (1996). The viral ubiquitin gene of Autographa californica nuclear polyhedrosis virus is not essential for viral replication. Virology.
130 Haas A.L., et al. (1996). Functional characterization of the ubiquitin variant encoded by the baculovirus Autographa californica. Biochemistry.
131 Li Z., et al. (2003). Characterization of a novel ubiquitin-fusion gene Uba256 from Spodoptera litura nucleopolyhedrovirus. Gene.
132 Guarino L.A., Summers M.D. (1986). Functional mapping of a trans-activating gene required for expression of a baculovirus delayed-early gene. J. Virol.
133 Guarino L.A., et al. (1992). The baculovirus phosphoprotein pp31 is associated with the virogenic stroma. J. Virol.
134 Guarino L.A., Mistretta T.A., Dong W. (2002). DNA binding activity of the baculovirus late expression factor PP31. Virus Res.
135 Broussard D.R., Guarino L.A., Jarvis D.L. (1996). Dynamic phosphorylation of Autographa californica nuclear polyhedrosis virus pp31. J Virol.
136 Broussard D.R., Guarino L.A., Jarvis D.L. (1996). Mapping functional domains in AcMNPV pp31. Virology.
137 Todd J.W., Passarelli A.L., Miller L.K. (1995). Eighteen baculovirus genes, including lef-11, p35, 39K, and p47, support late gene expression. J. Virol.
138 Yamagishi J., et al. (2007). The AcMNPV pp31 gene is not essential for productive AcMNPV replication or late gene transcription but appears to increase levels of most viral transcripts. Virology.
139 Mildvan A.S., et al. (2005). Structures and mechanisms of Nudix hydrolases. Arch Biochem Biophys.
140 Ge J., et al. (2007). AcMNPV ORF38 protein has the activity of ADP-ribose pyrophosphatase and is important for virus replication. Virology.
141 Parrish S., Resch W., Moss B. (2007). Vaccinia virus D10 protein has mRNA decapping activity, providing a mechanism for control of host and viral gene expression. Proc Natl Acad Sci U S A.
142 Parrish S., Moss B. (2006). Characterization of a vaccinia virus mutant with a deletion of the D10R gene encoding a putative negative regulator of gene expression. J Virol.
143 Wang D., et al. (2005). Characterization of Helicoverpa armigera nucleopolyhedrovirus orf33 that encodes a novel budded virion derived protein, BV-e31. Arch Virol.
144 Yu M., Carstens E.B. (2011). Characterization of an Autographa californica multiple nucleopolyhedrovirus mutant lacking the ac39(p43) gene. Virus Res.
145 Partington S., et al. (1990). Isolation of temperature sensitive mutants of Autographa californica nuclear polyhedrosis virus: phenotype characterization of baculovirus mutants defective in very late gene expression. Virology.
146 Carstens E.B., Lu A.L., Chan H.L.B. (1993). Sequence, transcriptional mapping, and overexpression of p47, a baculovirus gene regulating late gene expression. J. Virol.
147 Guarino L.A., et al. (1998). A virus-encoded RNA polymerase purified from baculovirus-infected cells. J. Virol.
148 Rapp J.C., Wilson J.A., Miller L.K. (1998). Nineteen baculovirus open reading frames, including LEF-12, support late gene expression. J Virol.
149 Li L., Harwood S.H., Rohrmann G.F. (1999). Identification of additional genes that influence baculovirus late gene expression. Virology.
150 Guarino L.A., Mistretta T.A., Dong W. (2002). Baculovirus lef-12 is not required for viral replication. J Virol.
151 Katsuma S., et al. (2008). Bombyx mori nucleopolyhedrovirus SNF2 global transactivator homologue (Bm33) enhances viral pathogenicity in B. mori larvae. J Gen Virol.
152 Katsuma S., Shimada T. (2009). Bombyx mori nucleopolyhedrovirus ORF34 is required for efficient transcription of late and very late genes. Virology.
153 Tao X.Y., et al. (2013). Functional characterization of Autographa californica multiple nucleopolyhedrovirus ORF43 and phenotypic changes of ORF43-knockout mutant. J Microbiol.
154 Hong T., Braunagel S.C., Summers M.D. (1994). Transcription, translation, and cellular localization of PDV-E66: A structural protein of the PDV envelope of Autographa californica nuclear polyhedrosis virus. Virology.
155 Hong T., Summers M., Braunagel S. (1997). N-terminal sequences from Autographa californica nuclear polyhedrosis virus envelope proteins ODV-E66 and ODV-E25 are sufficient to direct reporter proteins to the nuclear envelope, intranuclear microvesicles and the envelope of occlusion derived virus. Proc. Natl. Acad. Sci. U S A.
156 Vigdorovich V., Miller A.D., Strong R.K. (2007). Ability of hyaluronidase 2 to degrade extracellular hyaluronan is not required for its function as a receptor for jaagsiekte sheep retrovirus. J Virol.
157 Sugiura N., et al. (2011). Baculovirus envelope protein ODV-E66 is a novel chondroitinase with distinct substrate specificity. J Biol Chem.
158 Kawaguchi Y., et al. (2012). Crystallization and X-ray diffraction analysis of chondroitin lyase from baculovirus: envelope protein ODV-E66. Acta Crystallogr Sect F Struct Biol Cryst Commun.
159 Sparks W.O., Rohlfing A., Bonning B.C. (2011). A peptide with similarity to baculovirus ODV-E66 binds the gut epithelium of Heliothis virescens and impedes infection with Autographa californica multiple nucleopolyhedrovirus. J Gen Virol.
160 Gomi S., Kamita S.G., Maeda S. (1999). Deletion analysis of all genes of Bombyx mori nucleopolyhedrovirus (BmNPV). RIKEN Review.
161 Xiang X., et al. (2011). Autographa californica multiple nucleopolyhedrovirus odv-e66 is an essential gene required for oral infectivity. Virus Res.
162 Claussen M., et al. (2006). Functional characterization of Drosophila Translin and Trax. Genetics.
163 Crawford A.M., Miller L.K. (1988). Characterization of an early gene accelerating expression of late genes of the baculovirus Autographa californica nuclear polyhedrosis virus. J. Virol.
164 Johnson A., O'Donnell M. (2005). CELLULAR DNA REPLICASES: Components and Dynamics at the Replication Fork. Ann. Rev. Biochem.
165 Iwahori S., Ikeda M., Kobayashi M. (2002). Generation and characterization of Autographa californica nucleopolyhedrovirus mutants defective in pcna gene homologoue. J. Insect Biotechnol. Sericology.
166 Iwahori S., Ikeda M., Kobayashi M. (2004). Association of Sf9 cell proliferating cell nuclear antigen with the DNA replication site of Autographa californica multicapsid nucleopolyhedrovirus. J Gen Virol.
167 Passarelli A.L., Todd J.W., Miller L.K. (1994). A baculovirus gene involved in late gene expression predicts a large polypeptide with a conserved motif of RNA polymerases. J. Virol.
168 Titterington J.S., Nun T.K., Passarelli A.L. (2003). Functional dissection of the baculovirus late expression factor-8 gene: sequence requirements for late gene promoter activation. J Gen Virol.
169 Crouch E.A., et al. (2007). Inter-subunit interactions of the Autographa californica M nucleopolyhedrovirus RNA polymerase. Virology.
170 Shikata M., et al. (1998). Isolation and characterization of a temperature-sensitive mutant of Bombyx mori nucleopolyhedrovirus for a putative RNA polymerase gene. J Gen Virol.
171 Gauthier D., et al. (2012). Characterization of an Autographa californica multiple nucleopolyhedrovirus dual mutant: ORF82 is required for budded virus production, and a point mutation in LEF-8 alters late and abolishes very late transcription. J Gen Virol.
172 Langer T., et al. (1992). Successive action of DnaK, DnaJ and GroEL along the pathway of chaperone-mediated protein folding. Nature.
173 Xu H.J., et al. (2006). Characterization of ORF39 from Helicoverpa armigera single-nucleocapsid nucleopolyhedrovirus, the gene containing RNA recognition motif. J Biochem Mol Biol.
174 Tian C.H., et al. (2009). Involvement of Bombyx mori nucleopolyhedrovirus ORF41 (Bm41) in BV production and ODV envelopment. Virology.
175 Liu C., et al. (2008). Autographa californica multiple nucleopolyhedrovirus ac53 plays a role in nucleocapsid assembly. Virology.
176 Olszewski J., Miller L.K. (1997). Identification and characterization of a baculovirus structural protein, VP1054, required for nucleocapsid formation. J. Virol.
177 Wu W., et al. (2008). Autographa californica Multiple Nucleopolyhedrovirus 38K Is a Novel Nucleocapsid Protein That Interacts with VP1054, VP39, VP80 and Itself. J Virol.
178 Marek M., et al. (2013). Baculovirus VP1054 is an acquired cellular PURα, a nucleic-acid6n binding protein specific for GGN repeats. J Virol.
179 Chen Y., et al. (2012). Helicoverpa armaigera nucleopolyhedrovirus ORF50 is an early gene not essential for virus propagation in vitro and in vivo. Virus Genes.
180 Guo Z.J., et al. (2010). Identification of a novel functional nuclear localization signal in the protein encoded by open reading frame 47 of Bombyx mori nucleopolyhedrovirus. Arch Virol.
181 Li Z., et al. (2006). Characterization of two homologues of ChaB in Spodoptera litura multicapsid nucleopolyhedrovirus. Gene.
182 Beames B., Summers M.D. (1989). Location and nucleotide sequence of the 25k protein missing from baculovirus few polyhedra (FP) mutants. Virology.
183 Harrison R.L., Jarvis D.L., Summers M.D. (1996). The role of the AcMNPV 25K gene, "FP25," in baculovirus polh and p10 expression. Virology.
184 Fraser M.J., et al. (1985). Transposon mediated mutagenesis of a baculovirus. Virology.
185 Beames B., Summers M.D. (1990). Sequence comparison of cellular and viral copies of host cell DNA insertions found in Autographa californica nuclear polyhedrosis virus. Virology.
186 Bischoff D.S., Slavicek J.M. (1997). Phenotypic and genetic analysis of Lymantria dispar nucleopolyhedrovirus few polyhedra mutants: mutations in the 25K FP gene may be caused by DNA replication errors. J. Virol.
187 Braunagel S.C., et al. (1999). Mutations within the Autographa californica nucleopolyhedrovirus FP25K gene decrease the accumulation of ODV-E66 and alter its intranuclear transport. J Virol.
188 Rosas-Acosta G., Braunagel S.C., Summers M.D. (2001). Effects of deletion and overexpression of the Autographa californica nuclear polyhedrosis virus FP25K gene on synthesis of two occlusion-derived virus envelope proteins and their transport into virus-induced intranuclear membranes. J Virol.
189 Katsuma S., et al. (1999). Characterization of the 25K FP gene of the baculovirus Bombyx mori nucleopolyhedrovirus: implications for post-mortem host degradation. J Gen Virol.
190 Katsuma S., Nakanishi T., Shimada T. (2009). Bombyx mori nucleopolyhedrovirus FP25K is essential for maintaining a steady-state level of v-cath expression throughout the infection. Virus Res.
191 Kelly B.J., et al. (2006). Dual mutations in the Autographa californica nucleopolyhedrovirus FP-25 and p35 genes result in plasma-membrane blebbing in Trichoplusia ni cells. J Gen Virol.
192 Nakanishi T., Shimada T., Katsuma S. Characterization of a Bombyx mori nucleopolyhedrovirus mutant lacking both fp25K and p35. Virus Genes.
193 Cheng X.H., et al. (2012). Cell-dependent polyhedra production and virion occlusion of AcMNPV fp25k mutants in vitro and in vivo. J Gen Virol.
194 Cheng X.H., et al. (2012). Reduction of polyhedrin mRNA and protein expression levels in Sf9 and High Five cell lines but not in Sf21 infected with AcMNPV fp25k mutants. J Gen Virol.
195 Wang Y., et al. (2007). The genome of Gryllus bimaculatus nudivirus indicates an ancient diversification of baculovirus-related nonoccluded nudiviruses of insects. J Virol.
196 Tian C.H., et al. (2008). Bombyx mori nucleopolyhedrovirus ORF51 encodes a budded virus envelope associated protein. Virus Genes.
197 Cheng X., Krell P., Arif B. (2001). P34.8 (GP37) is not essential for baculovirus replication. J Gen Virol.
198 Vialard J.E., Yuen L., Richardson C.D. (1990). Identification and characterization of a baculovirus occlusion body glycoprotein which resembles spheroidin, an entomopoxvirus protein. Journal of Virology.
199 Hall R.L., Moyer R.W. (1993). Identification of an Amsacta spheroidin-like protein within occlusion bodies of Choristoneura entomopoxviruses. Virology.
200 Wu J., Miller L.K. (1989). Sequence, transcription, and translation of a late gene of the Autographa californica nuclear polyhedrosis virus encoding a 34.8 K polypeptide. Journal of General Virology.
201 Salvador R., et al. (2012). Analysis of EpapGV gp37 gene reveals a close relationship between granulovirus and entomopoxvirus. Virus Genes.
202 Techkarnjanaruk S., Goodman A.E. (1999). Multiple genes involved in chitin degradation from the marine bacterium Pseudoalteromonas sp. strain S91. Microbiology.
203 Li Z., et al. (2003). Characterization of a chitin-binding protein GP37 of Spodoptera litura multicapsid nucleopolyhedrovirus. Virus Res.
204 Liu X., et al. (2011). Synergistic effects of Cydia pomonella granulovirus GP37 on the infectivity of nucleopolyhedroviruses and the lethality of Bacillus thuringiensis. Arch Virol.
205 Lemaitre B., Hoffmann J. (2007). The host defense of Drosophila melanogaster. Annu Rev Immunol.
206 Gross C.H., et al. (1993). A 37 kda glycoprotein from a baculovirus of Orgyia pseudotsugata is localized to cytoplasmic inclusion bodies. Journal of Virology.
207 Tomalski M.D., Wu J., Miller L.K. (1988). The location, sequence, transcription, and regulation of a baculovirus DNA polymerase gene. Virology.
208 Mikhailov V., et al. (1986). Characterization of 3' -> 5' exonuclease associated with DNA polymerase of silkworm nuclear polyhedrosis ivrus. Nucleic Acids Research.
209 McDougal V.V., Guarino L.A. (1999). Autographa californica nuclear polyhedrosis virus DNA polymerase: measurements of processivity and strand displacement. J Virol.
210 Hang X., Guarino L.A. (1999). Purification of Autographa californica nucleopolyhedrovirus DNA polymerase from infected insect cells. J Gen Virol.
211 Feng G., et al. (2012). Selection and Characterization of Autographa californica Multiple Nucleopolyhedrovirus DNA Polymerase Mutations. J Virol.
212 Vanarsdall A.L., Okano K., Rohrmann G.F. (2005). Characterization of the replication of a baculovirus mutant lacking the DNA polymerase gene. Virology.
213 Deng F., et al. (2007). Proteomics analysis of Helicoverpa armigera single nucleocapsid nucleopolyhedrovirus identified two new occlusion-derived virus-associated proteins, HA44 and HA100. J Virol.
214 Ohresser M., et al. (1994). Temporal regulation of a complex and unconventional promoter by viral products. J. Virol.
215 Ke J., et al. (2008). Autographa californica multiple nucleopolyhedrovirus ac66 is required for the efficient egress of nucleocapsids from the nucleus, general synthesis of preoccluded virions and occlusion body formation. Virology.
216 Zhang M.J., et al. (2012). Bombyx mori nucleopolyhedrovirus ORF54, a viral desmoplakin gene, is associated with the infectivity of budded virions. Arch Virol.
217 Hang X., Dong W., Guarino L.A. (1995). The lef-3 gene of Autographa californica nuclear polyhedrosis virus encodes a single-stranded DNA-binding protein. J. Virol.
218 Downie K., Adetola G., Carstens E.B. (2013). Characterization of protein-protein interaction domains within the baculovirus Autographa californica multiple nucleopolyhedrovirus late expression factor LEF-3. J Gen Virol.
219 Evans J.T., et al. (1999). Characterization of the interaction between the baculovirus ssDNA- binding protein (LEF-3) and putative helicase (P143). J Gen Virol.
220 Wu Y., Carstens E.B. (1998). A baculovirus single-stranded DNA binding protein, LEF-3, mediates the nuclear localization of the putative helicase P143. Virology.
221 Au V., Yu M., Carstens E.B. (2009). Characterization of a baculovirus nuclear localization signal domain in the late expression factor 3 protein. Virology.
222 Chen Z., Carstens E.B. (2005). Identification of domains in Autographa californica multiple nucleopolyhedrovirus late expression factor 3 required for nuclear transport of P143. J Virol.
223 Yu M., Carstens E.B. (2010). Identification of a domain of the baculovirus Autographa californica multiple nucleopolyhedrovirus single-strand DNA-binding protein LEF-3 essential for viral DNA replication. J Virol.
224 Mikhailov V., Okano K., Rohrmann G. (2003). Baculovirus Alkaline Nuclease Possesses a 5’->3’ Exonuclease Activity and Associates with the DNA-Binding Protein LEF-3. J. Virol.
225 Mikhailov V., Okano K., Rohrmann G. (2004). Specificity of the Endonuclease Activity of the Baculovirus Alkaline Nuclease for Single-stranded DNA. J. Biol. Chem.
226 Mikhailov V.S., Okano K., Rohrmann G.F. (2005). The Redox State of the Baculovirus Single-stranded DNA-binding Protein LEF-3 Regulates Its DNA Binding, Unwinding, and Annealing Activities. J Biol Chem.
227 Mikhailov V. (2000). Helix-destabilizing properties of the baculovirus single-stranded DNA-binding protein (LEF-3). Virology.
228 Mikhailov V.S., Okano K., Rohrmann G.F. (2006). Structural and functional analysis of the baculovirus single-stranded DNA-binding protein LEF-3. Virology.
229 Iyer L.M., Koonin E.V., Aravind L. (2002). Classification and evolutionary history of the single-strand annealing proteins, RecT, Redbeta, ERF and RAD52. BMC Genomics.
230 Nie Y., et al. (2012). Analysis of the autographa californica multiple nucleopolyhedrovirus overlapping gene pair lef3 and ac68 reveals that AC68 is a per os infectivity factor and that LEF3 is critical, but not essential, for virus replication. J Virol.
231 Li G., et al. (2008). Characterization of AcMNPV with a deletion of ac68 gene. Virus Genes.
232 Xu H., et al. (2008). Bombyx mori nucleopolyhedrovirus ORF56 encodes an occlusion-derived virus protein and is not essential for budded virus production. J. Gen. Virol.
233 Wu X., Guarino L.A. (2003). Autographa californica nucleopolyhedrovirus orf69 encodes an RNA cap (nucleoside-2'-O)-methyltransferase. J Virol.
234 Lu A., Miller L.K. (1995). Differential requirements for baculovirus late expression factor genes in two cell lines. J. Virol.
235 Lu A., Miller L.K. (1996). Species-specific effects of the hcf-1 gene on baculovirus virulence. J Virol.
236 Wilson J.A., et al. (2005). Expression and mutational analysis of Autographa californica nucleopolyhedrovirus HCF-1: functional requirements for cysteine residues. J Virol.
237 Griffiths C.M., et al. (1999). In vitro host range of Autographa californica nucleopolyhedrovirus recombinants lacking functional p35, iap1 or iap2. J. Gen. Virol.
238 Yamada H., et al. (2012). Baculovirus Lymantria dispar multiple nucleopolyhedrovirus IAP2 and IAP3 do not suppress apoptosis, but trigger apoptosis of insect cells in a transient expression assay. Virus Genes.
239 Du M.F., et al. (2006). Characterization of a late gene, ORF60 from Bombyx mori nucleopolyhedrovirus. J Biochem Mol Biol.
240 Guo Z.J., et al. (2010). Open reading frame 60 of the Bombyx mori nucleopolyhedrovirus plays a role in budded virus production. Virus Res.
241 Shen H., et al. (2009). Characterization of the Bm61 of the Bombyx mori nucleopolyhedrovirus. Curr Microbiol.
242 Shen H., Chen K. (2012). BM61 of Bombyx mori nucleopolyhedrovirus: its involvement in the egress of nucleocapsids from the nucleus. FEBS Lett.
243 Hu Z., et al. (2010). Autographa californica multiple nucleopolyhedrovirus ac76 is involved in intranuclear microvesicle formation. J Virol.
244 Wei D., et al. (2013). Autographa californica nucleopolyhedrovirus Ac76: a dimeric type II integral membrane protein that contains an inner nuclear membrane-sorting motif. J Virol.
245 McLachlin J.R., Miller L.K. (1994). Identification and characterization of vlf-1, a baculovirus gene involved in very late gene expression. J. Virol.
246 Yang S., Miller L.K. (1999). Activation of baculovirus very late promoters by interaction with very late factor 1. J Virol.
247 Yang S., Miller L.K. (1998). Expression and mutational analysis of the baculovirus very late factor 1 (vlf-1) gene. Virology.
248 Vanarsdall A.L., Okano K., Rohrmann G.F. (2006). Characterization of the role of VLF-1 in baculovirus capsid structure and DNA processing. J. Virol.
249 Vanarsdall A.L., Okano K., Rohrmann G.F. (2004). Characterization of a baculovirus with a deletion of vlf-1. Virology.
250 Li Y., et al. (2005). vlf-1 deletion brought AcMNPV to defect in nucleocapsid formation. Virus Genes.
251 Mikhailov V., Rohrmann G. (2002). Binding of the baculovirus very late expression factor 1 (VLF-1) to different DNA structures. BMC Mol Biol.
252 Hou D., et al. (2013). Comparative Proteomics Reveal Fundamental Structural and Functional Differences between the Two Progeny Phenotypes of a Baculovirus. J Virol.
253 Tao X.Y., et al. (2013). The Autographa californica multiple nucleopolyhedrovirus ORF78 is essential for BV production and general occlusion body formation. J. Virol.
254 Huang H., et al. (2013). Baculovirus core gene ha72 is essential for BV production and ODV occlusion and amino acid K22 plays an important role in its function. J Virol.
255 Aravind L., Walker D.R., Koonin E.V. (1999). Conserved domains in DNA repair proteins and evolution of repair systems. Nucleic Acids Res.
256 Swapna, G.V.T., et al., Solution Nmr Structure Of The Protein Ef2693 From E. Faecalis, 2005, Northeast Structural Genomics Consortium Target Efr36.
257 Wu W., Passarelli A.L. (2012). The Autographa californica M nucleopolyhedrovirus ac79 gene encodes an early gene product with structural similarities to UvrC and intron-encoded endonucleases that is required for efficient budded virus production. J Virol.
258 Tang Q., et al. (2012). Bm65 is Essential for the Propagation of Bombyx mori Nucleopolyhedrovirus. Curr Microbiol.
259 Whitford M., Faulkner P. (1992). A structural polypeptide of the baculovirus Autographa californica nuclear polyhedrosis virus contains 0-linked N-acetylglucosamine. J. Virol.
260 Whitford M., Faulkner P. (1992). Nucleotide sequence and transcriptional analysis of a gene encoding gp41, a structural glycoprotein of the baculovirus Autographa californica nuclear polyhedrosis virus. J. Virol.
261 Olszewski J., Miller L.K. (1997). A role for baculovirus GP41 in budded virus production. Virology.
262 Chen H.Q., et al. (2007). Characterization of a late gene, ORF67 from Bombyx mori nucleopolyhedrovirus. FEBS Lett.
263 Raynes D.A., Hartshorne D.J., Guerriero V.J. (1994). Sequence and expression of a baculovirus protein with antigenic similarity to telokin. J. Gen. Virol.
264 Holden H.M., et al. (1996). Molecular structure of a proteolytic fragment of TLP20. Acta Crystallogr. D Biol. Crystallogr.
265 Iwanaga M., et al. (2002). Characterization of Bombyx mori nucleopolyhedrovirus orf68 gene that encodes a novel structural protein of budded virus. Virology.
266 Russell R.L., Rohrmann G.F. (1997). Characterization of P91, a protein associated with virions of an Orgyia pseudotsugata baculovirus. Virology.
267 Hou D., et al. (2012). Comparative Proteomics Reveal Fundamental Structural and Functional Differences between the Two Progeny Phenotypes of a Baculovirus. J Virol.
268 Suetake T., et al. (2000). Chitin-binding proteins in invertebrates and plants comprise a common chitin-binding structural motif. J Biol Chem.
269 Zhu S., et al. (2013). The baculovirus core gene ac83 is required for nucleocapsid assembly and per os infectivity of Autographa californica nucleopolyhedrovirus. J Virol.
270 Xiang X., et al. (2013). Bombyx mori nucleopolyhedrovirus BmP95 plays an essential role in BV production and nucleocapsid assembly. J Gen Virol.
271 Martins A., Shuman S. (2004). Characterization of a baculovirus enzyme with RNA ligase, polynucleotide 5'-kinase, and polynucleotide 3'-phosphatase activities. J Biol Chem.
272 Durantel D., et al. (1998). The pnk/pnl gene (ORF 86) of Autographa californica nucleopolyhedrovirus is a non-essential, immediate early gene. J Gen Virol.
273 Lu M., Iatrou K. (1997). Characterization of a domain of the genome of BmNPV containing a functional gene for a small capsid protein and harboring deletions eliminating three open reading frames that are present in AcNPV. Gene.
274 Thiem S.M., Miller L.K. (1989). A baculovirus gene with a novel transcription pattern encodes a polypeptide with a zinc finger and a leucine zipper. Journal of Virology.
275 Passarelli A.L., Miller L.K. (1994). In vivo and in vitro analyses of recombinant baculoviruses lacking a functional cg30 gene. J Virol.
276 Zhang M.J., et al. (2012). Disruption of Bombyx mori nucleopolyhedrovirus ORF71 (Bm71) results in inefficient budded virus production and decreased virulence in host larvae. Virus Genes.
277 Ishihara G., Shimada T., Katsuma S. (2013). Functional characterization of Bombyx mori nucleopolyhedrovirus CG30 protein. Virus Res.
278 Pearson M.N., et al. (1988). P39, a major baculovirus structural protein: Immunocytochemical characterization and genetic location. Virology.
279 Thiem S.M., Miller L.K. (1989). Identification, sequence, and transcriptional mapping of the major capsid protein gene of the baculovirus Autographa californica nuclear polyhedrosis virus. J. Virol.
280 Danquah J.O., et al. (2012). Direct interaction of baculovirus capsid proteins VP39 and EXON0 with kinesin-1 in insect cells determined by fluorescence resonance energy transfer-fluorescence lifetime imaging microscopy. J Virol.
281 Gross C.H., Shuman S. (1998). RNA 5'-triphosphatase, nucleoside triphosphatase, and guanylyltransferase activities of baculovirus LEF-4 protein. J Virol.
282 Jin J., Dong W., Guarino L.A. (1998). The LEF-4 subunit of baculovirus RNA polymerase has RNA 5'- triphosphatase and ATPase activities. J Virol.
283 Martins A., Shuman S. (2001). Mutational analysis of baculovirus capping enzyme Lef4 delineates an autonomous triphosphatase domain and structural determinants of divalent cation specificity. J Biol Chem.
284 Martins A., Shuman S. (2002). The domain order of mammalian capping enzyme can be inverted and baculovirus phosphatase can function in cap formation in vivo. Virology.
285 Knebel-Morsdorf D., et al. (2006). Expression of baculovirus late and very late genes depends on LEF-4, a component of the viral RNA polymerase whose guanyltransferase function is essential. J Virol.
286 Wang D., Zhang C.X. (2007). Helicoverpa armigera nucleopolyhedrovirus ORF80 encodes a late, nonstructural protein. J Biochem Mol Biol.
287 Shen H., et al. (2009). Characterization of Bombyx mori nucleopolyhedrovirus orf74, a novel gene involved in virulence of virus. Virus Genes.
288 Long C.M., Rohrmann G.F., Merrill G.F. (2009). The conserved baculovirus protein p33 (Ac92) is a flavin adenine dinucleotide-linked sulfhydryl oxidase. Virology.
289 Wu W., Passarelli A.L. (2010). Autographa californica M nucleopolyhedrovirus Ac92 (ORF92, P33) is required for budded virus production and multiply-enveloped occlusion-derived virus formation. J. Virol.
290 Morel C., et al. (2007). Involvement of sulfhydryl oxidase QSOX1 in the protection of cells against oxidative stress-induced apoptosis. Exp Cell Res.
291 Thirunavukkarasu C., et al. (2008). Augmenter of liver regeneration: an important intracellular survival factor for hepatocytes. J Hepatol.
292 Nie Y., Fang M., Theilmann D.A. (2011). Autographa californica multiple nucleopolyhedrovirus core gene ac92 (p33) is required for the efficient budded virus production. Virology.
293 Hakim M., Mandelbaum A., Fass D. (2011). Structure of a baculovirus sulfhydryl oxidase, a highly divergent member of the erv flavoenzyme family. J Virol.
294 Hou Y., Xia Q., Yuan Y.A. (2012). Crystal structure of Bombyx mori nucleopolyhedrovirus ORF75 reveals a pseudo-dimer of thiol oxidase domains with a putative substrate-binding pocket. J Gen Virol.
295 Huang N., Clem R.J., Rohrmann G.F. (2011). Characterization of cDNAs encoding p53 of Bombyx mori and Spodoptera frugiperda. Insect Biochem Mol Biol.
296 Wu, W., et al., The baculovirus sulfhydryl oxidase Ac92 (P33) interacts with the Spodoptera frugiperda P53 protein and oxidizes it in vitro. 2013. 447: p. 197-207.
297 Yuan M., et al. (2011). Identification of Autographa californica nucleopolyhedrovirus ac93 as a core gene and its requirement for intranuclear microvesicle formation and nuclear egress of nucleocapsids. J Virol.
298 Russell R.L.Q., Rohrmann G.F. (1993). A 25 kilodalton protein is associated with the envelopes of occluded baculovirus virions. Virology.
299 Chen L., et al. (2012). Autographa californica multiple nucleopolyhedrovirus odv-e25 (Ac94) is required for budded virus infectivity and occlusion-derived virus formation. Arch Virol.
300 Luo X.C., et al. (2013). Effects of Early or Overexpression of the Multiple Nucleopolyhedrovirus (ODV-) on Virus Replication. PLoS One.
301 Chen L., et al. (2013). The formation of occlusion-derived virus is affected by the expression level of ODV-E25. Virus Res.
302 Zhu M., et al. (2013). A MicroRNA Encoded by Autographa californica Nucleopolyhedrovirus Regulates Expression of Viral Gene ODV-E25. J Virol.
303 Gordon J.D., Carstens E. (1984). Phenotypic characterization and physical mapping of a terperature-sensitive mutant of AcMNPV defective in DNA synthesis. Virology.
304 Lu A., Carstens E.B. (1991). Nucleotide sequence of a gene essential for viral DNA replication in the baculovirus Autographa californica nuclear polyhedrosis virus. Virology.
305 McDougal V.V., Guarino L.A. (2000). The autographa californica nuclear polyhedrosis virus p143 gene encodes a DNA helicase. J Virol.
306 Maeda S., Kamita S.G., Kondo A. (1993). Host range expansion of Autographa californica nuclear polyhedrosis virus (NPV) following recombination of a 0.6-kilobase-pair DNA fragment originating from Bombyx mori NPV. J. Virol.
307 Croizier G., et al. (1994). Extension of Autographa californica nuclear polyhedrosis virus host range by interspecific replacement of a short DNA sequence in the p143 helicase gene. Proc. Natl. Acad. Sc. USA.
308 Xu H.J., et al. (2006). Bombyx mori nucleopolyhedrovirus ORF79 encodes a 28-kDa structural protein of the ODV envelope. Arch Virol.
309 Fang M., et al. (2009). Autographa californica multiple nucleopolyhedrovirus core gene ac96 encodes a per Os infectivity factor (PIF-4). J Virol.
310 Peng K., et al. (2010). Baculovirus per os infectivity factors form a complex on the surface of occlusion-derived virus. J Virol.
311 Wu W., et al. (2006). Autographa californica multiple nucleopolyhedrovirus nucleocapsid assembly is interrupted upon deletion of the 38K gene. J Virol.
312 Hefferon K.L. (2003). ORF98 of Autographa californica nucleopolyhedrosisvirus is an auxiliary factor in late gene expression. Can J Microbiol.
313 Yeo M., et al. (2003). A novel RNA polymerase II C-terminal domain phosphatase that preferentially dephosphorylates serine 5. J Biol Chem.
314 Yeo M., Lin P.S. (2007). Functional characterization of small CTD phosphatases. Methods Mol Biol.
315 Passarelli A.L., Miller L.K. (1993). Identification of genes encoding late expression factors located between 56.0 and 65.4 map units of the Autographa californica nuclear polyhedrosis virus genome. Virology.
316 Harwood S.H., et al. (1998). AcMNPV late expression factor-5 interacts with itself and contains a zinc ribbon domain that is required for maximal late transcription activity and is homologous to elongation factor TFIIS. Virology.
317 Guarino L.A., Dong W., Jin J. (2002). In vitro activity of the baculovirus late expression factor LEF-5. J Virol.
318 Su J., Lung O., Blissard G.W. (2011). The Autographa californica multiple nucleopolyhedrovirus lef-5 gene is required for productive infection. Virology.
319 Wilson M.E., et al. Location, transcription, and sequence of a baculovirus gene encoding a small arginine-rich polypeptide. J. Virol., l.
320 Garcia-Maruniak A., et al. (2004). Sequence analysis of the genome of the Neodiprion sertifer nucleopolyhedrovirus. J Virol.
321 Tweeten K.A., Bulla L.A., Consigli R.A. (1980). Characterization of an extremely basic protein derived from granulosis virus nucleocapsid. J. Virol.
322 Balhorn R. (1982). A model for the structure of chromatin in mammalian sperm. J. Cell Biol.
323 Nakano M., et al. (1989). Conformation of the fowl protamine, galline, and its binding properties to DNA. J Biochem.
324 Wilson M.E., Price K.H. (1988). Association of Autographa californica nuclear polyhedrosis virus (AcMNPV) with the nuclear matrix. Virology.
325 Peng Y., et al. (2012). The protamine-like DNA-binding protein P6.9 epigenetically up-regulates Autographa californica multiple nucleopolyhedrovirus gene transcription in the late infection phase. Virol Sin.
326 Oppenheimer D.I., Volkman L.E. (1995). Proteolysis of p6.9 induced by cytochalasin D in Autographa californica M nuclear polyhedrosis virus-infected cells. Virology.
327 Liu X., et al. (2012). Distribution and phosphorylation of the basic protein P6.9 of Autographa californica nucleopolyhedrovirus. J Virol.
328 Wang M., et al. (2010). Specificity of baculovirus P6.9 basic DNA-binding proteins and critical role of the C terminus in virion formation. J Virol.
329 Braunagel S.C., et al. (2001). Identification of BV/ODV-C42, an Autographa californica nucleopolyhedrovirus orf101-encoded structural protein detected in infected-cell complexes with ODV-EC27 and p78/83. J. Virol.
330 Wang Y., et al. (2008). Autographa californica multiple nucleopolyhedrovirus nucleocapsid protein BV/ODV-C42 mediates the nuclear entry of P78/83. J. Virol.
331 Li K., et al. (2010). The putative pocket protein binding site of Autographa californica nucleopolyhedrovirus BV/ODV-C42 is required for virus-induced nuclear actin polymerization. J Virol.
332 Fang M., et al. (2008). Identification of AcMNPV EXON0 (ac141) domains required for efficient production of budded virus, dimerization and association with BV/ODV-C42 and FP25. Virology.
333 Vanarsdall A.L., Pearson M.N., Rohrmann G.F. (2007). Characterization of baculovirus constructs lacking either the Ac 101, Ac 142, or the Ac 144 open reading frame. Virology.
334 Lu A., et al. (1996). Nucleotide sequence, insertional mutagenesis, and transcriptional mapping of a conserved region of the baculovirus Autographa californica nuclear polyhedrosis virus (map unit 64.8-66.9). Can J Microbiol.
335 Ohkawa T., Rowe A.R., Volkman L.E. (2002). Identification of six Autographa californica multicapsid nucleopolyhedrovirus early genes that mediate nuclear localization of G-actin. J Virol.
336 Yuan M., et al. (2008). A highly conserved baculovirus gene p48 (ac103) is essential for BV production and ODV envelopment. Virology.
337 Müller R., et al. (1990). A capsid-associated protein of the multicapsid nuclear polyhedrosis virus of Orgyia pseudotsugata: Genetic location, sequence, transcriptional mapping, and immunocytochemical characterization. Virology.
338 Marek M., et al. (2011). Baculovirus VP80 protein and the F-actin cytoskeleton interact and connect the viral replication factory with the nuclear periphery. J Virol.
339 Lu A., Carstens E.B. (1992). Nucleotide sequence and transcriptional analysis of the p80 gene of Autographa californica nuclear polyhedrosis virus: a homologue of the Orgyia pseudotsugata nuclear polyhedrosis virus capsid-associated gene. Virology.
340 Marek M., et al. (2011). Engineering of baculovirus vectors for the manufacture of virion-free biopharmaceuticals. Biotechnol Bioeng.
341 Marek M., et al. (2012). Essential C-terminal region of the baculovirus minor capsid protein VP80 binds DNA. J Virol.
342 Ho C.K., Shuman S. (2002). Bacteriophage T4 RNA ligase 2 (gp24.1) exemplifies a family of RNA ligases found in all phylogenetic domains. Proc Natl Acad Sci U S A.
343 Becker D., Knebel-Morsdorf D. (1993). Sequence and temporal appearance of the early transcribed baculovirus gene HE65. J Virol.
344 Shi S.L., Pan M.H., Lu C. (2007). Characterization of Antheraea pernyi nucleopolyhedrovirus p11 gene, a homologue of Autographa californica nucleopolyhedrovirus orf108. Virus Genes.
345 Simon O., et al. (2011). Analysis of a naturally-occurring deletion mutant of Spodoptera frugiperda multiple nucleopolyhedrovirus reveals sf58 as a new per os infectivity factor of lepidopteran-infecting baculoviruses. J Invertebr Pathol.
346 Tang Q., et al. (2013). Bm91 is an envelope component of ODV but is dispensable for the propagation of Bombyx mori nucleopolyhedrovirus. J Invertebr Pathol.
347 Fang M., et al. (2003). Open reading frame 94 of Helicoverpa armigera single nucleocapsid nucleopolyhedrovirus encodes a novel conserved occlusion-derived virion protein, ODV-EC43. J Gen Virol.
348 Fang M., Nie Y., Theilmann D.A. (2009). Deletion of the AcMNPV core gene ac109 results in budded virions that are non-infectious. Virology.
349 Lin L., et al. (2009). ac109 is required for the nucleocapsid assembly of Autographa californica multiple nucleopolyhedrovirus. Virus Res.
350 Lehiy C.J., et al. (2012). Autographa californica M nucleopolyhedrovirus open reading frame 109 affects infectious budded virus production and nucleocapsid envelopment in the nucleus of cells. Virology.
351 Alfonso V., et al. (2012). AcMNPV Core Gene ac109 Is Required for Budded Virion Transport to the Nucleus and for Occlusion of Viral Progeny. PLoS One.
352 Yamada H., et al. (2011). Identification of a novel apoptosis suppressor gene from the baculovirus Lymantria dispar multicapsid nucleopolyhedrovirus. J Virol.
353 Liang G., et al. Bombyx mori nucleopolyhedrovirus ORF94, a novel late protein is identified to be a component of ODV structural protein. Curr Microbiol.
354 Gong M., Jin J., Guarino L.A. (1998). Mapping of ORF121, a factor that activates baculovirus early gene expression. Virology.
355 Li Y., Miller L.K. (1995). Expression and functional analysis of a baculovirus gene encoding a truncated protein kinase homolog. Virology.
356 Prasad M.D., et al. (2003). Cloning and characterization of an eukaryotic initiation factor-2alpha kinase from the silkworm, Bombyx mori. Biochim Biophys Acta.
357 Dever T.E., et al. (1998). Disruption of cellular translational control by a viral truncated eukaryotic translation initiation factor 2alpha kinase homolog. Proc Natl Acad Sci U S A.
358 Aarti I., Rajesh K., Ramaiah K.V. (2010). Phosphorylation of eIF2 alpha in Sf9 cells: a stress, survival and suicidal signal. Apoptosis.
359 Morris T.D., et al. (1994). Identification of lef-7: A baculovirus gene affecting late gene expression. Virology.
360 Chen C.J., Thiem S.M. (1997). Differential infectivity of two Autographa californica nucleopolyhedrovirus mutants on three permissive cell lines is the result of lef-7 deletion. Virology.
361 Mitchell J.K., Byers N.M., Friesen P.D. (2013). Baculovirus F-Box Protein LEF-7 Modifies the Host DNA Damage Response To Enhance Virus Multiplication. J Virol.
362 Daimon T., et al. (2006). Comparative studies of Bombyx mori nucleopolyhedrovirus chitinase and its host ortholog, BmChi-h. Biochem Biophys Res Commun.
363 Hughes A.L., Friedman R. (2003). Genome-Wide Survey for Genes Horizontally Transferred from Cellular Organisms to Baculoviruses. Mol Biol Evol.
364 Fukamizo T., et al. (2011). Chitinase from Autographa californica Multiple Nucleopolyhedrovirus: Rapid Purification from Sf-9 Medium and Mode of Action. Biosci Biotechnol Biochem.
365 Hawtin, R., et al. Identification of a chitinase gene in the Autographa californica nuclear polyhedrosis virus. in American Society for Virology. 1992. Ithaca, NY.
366 Hawtin R.E., et al. (1997). Liquefaction of Autographa californica nucleopolyhedrovirus-infected insects is dependent on the integrity of virus-encoded chitinase and cathepsin genes. Virology.
367 Thomas C.J., et al. (1998). Localization of a baculovirus-induced chitinase in the insect cell endoplasmic reticulum. J Virol.
368 Saville G.P., et al. (2004). Deletion of the Autographa californica nucleopolyhedrovirus chitinase KDEL motif and in vitro and in vivo analysis of the modified virus. J Gen Virol.
369 Oliveira J.V., et al. (2006). Genome of the most widely used viral biopesticide: Anticarsia gemmatalis multiple nucleopolyhedrovirus. J Gen Virol.
370 Slack J.M., Kuzio J., Faulkner P. (1995). Characterization of v-cath, a cathepsin L-like proteinase expressed by the baculovirus Autographa californica multiple nuclear polyhedrosis virus. J. Gen. Virol.
371 Hom L.G., et al. (2002). Autographa californica M nucleopolyhedrovirus ProV-CATH is activated during infected cell death. Virology.
372 Hodgson J.J., Arif B.M., Krell P.J. (2009). Autographa californica multiple nucleopolyhedrovirus and Choristoneura fumiferana multiple nucleopolyhedrovirus v-cath genes are expressed as pre-proenzymes. J Gen Virol.
373 Hodgson J.J., Arif B.M., Krell P.J. (2011). Interaction of Autographa californica multiple nucleopolyhedrovirus cathepsin protease progenitor (proV-CATH) with insect baculovirus chitinase as a mechanism for proV-CATH cellular retention. J Virol.
374 Morse M.A., Marriott A.C., Nuttall P.A. (1992). The glycoprotein of Thogoto virus (a tick-borne orthomyxo-like virus) is related to the baculovirus glycoprotein gp64. Virology.
375 Hohmann A.W., Faulkner P. (1983). Monoclonal antibodies to baculovirus structural proteins: determination of specificities by western blot analysis. Virology.
376 Whitford M., et al. (1989). Identification and sequence analysis of a gene encoding gp67 an abundant envelope glycoprotein of the baculovirus, Autographa californica nuclear polyhedrosis virus. J. Virol.
377 Volkman L.E. The 64K envelope protein of budded Autographa californica nuclear polyhedrosis virus. Curr. Top. Microbiol. Immunol., l.
378 Roberts T.E., Faulkner P. (1989). Fatty acid acylation of the 67K envelope glycoprotein of a baculovirus: Autographa californica nuclear polyhedrosis virus. Virology.
379 Monsma S.A., Oomens A.G.P., Blissard G.W. (1996). The gp64 envelope fusion protein is an essential baculovirus protein required for cell-to-cell transmission of infection. J. Virol.
380 Oomens A.G., Blissard G.W. (1999). Requirement for GP64 to drive efficient budding of Autographa californica multicapsid nucleopolyhedrovirus. Virology.
381 Kadlec J., et al. (2008). The postfusion structure of baculovirus gp64 supports a unified view of viral fusion machines. Nat Struct Mol Biol.
382 Wolgamot G.M., et al. (1993). Immunocytochemical characterization of p24, a baculovirus capsid-associated protein. J. Gen. Virol.
383 Gombart A.F., Blissard G.W., Rohrmann G.F. (1989). Characterization of the genetic organization of the HindIII-M region of the multicapsid nuclear polyhedrosis virus of Orgyia pseudotsugata reveals major differences among baculoviruses. J. Gen. Virol.
384 Schetter C., Oellig C., Doerfler W. (1990). An insertion of insect cell DNA in the 81-map-unit segment of Autographa californica nuclear polyhedrosis virus DNA. J. Virol.
385 Slavicek J.M., Hayes-Plazolles N. (2003). The Lymantria dispar nucleopolyhedrovirus contains the capsid-associated p24 protein gene. Virus Genes.
386 Gross C.H., et al. (1993). A baculovirus encoded 16 kDa glycoprotein localizes near the nuclear membrane of infected cells. Virology.
387 Minion F.C., Coons L.B., Broome J.R. (1979). Characterization of the polyhedral envelope of the nuclear polyhedrosis virus of Heliothis virescens. J. Invertebr. Pathol.
388 Whitt M.A., Manning J.S. (1988). A phosphorylated 34-kDa protein and a subpopulation of polyhedrin are thiol-linked to the carbohydrate layer surrounding a baculovirus occlusion body. Virology.
389 van Lent J.W.M., et al. (1990). Localization of the 34kDa polyhedron envelope protein in Spodoptera frugiperda cells infected with Autographa californica nuclear polyhedrosis virus. Archives of Virology.
390 Gombart A.F., et al. (1989). A baculovirus polyhedral envelope-associated protein: genetic location, nucleotide sequence, and immunocytochemical characterization. Virology.
391 Russell R.L.Q., Rohrmann G.F. (1990). A baculovirus polyhedron envelope protein: Immunogold localization in infected cells and mature polyhedra. Virology.
392 Russell R.L.Q., Pearson M.N., Rohrmann G.F. (1991). Immunoelectron microscopic examination of Orgyia pseudotsugata multicapsid nuclear polyhedrosis virus-infected Lymantria dispar cells: time course and localization of major polyhedron-associated proteins. J. Gen. Virol.
393 Lee S.Y., et al. (1996). A common pathway for p10 and calyx proteins in progressive stages of polyhedron envelope assembly in AcMNPV-infected Spodoptera frugiperda larvae. Arch Virol.
394 Escasa S.R., et al. (2006). Sequence analysis of the Choristoneura occidentalis granulovirus genome. J Gen Virol.
395 Lange M., Jehle J.A. (2003). The genome of the Cryptophlebia leucotreta granulovirus. Virology.
396 Gross C.H., Russell R.L.Q., Rohrmann G.F. (1994). The Orgyia pseudotsugata baculovirus p10 and polyhedron envelope protein genes: analysis of their relative expression levels and role in polyhedron structure. J. Gen. Virol.
397 Zhou Y., et al. (2010). Characterization of Bombyx mori Nucleopolyhedrovirus ORF109 that Encodes a 25-kDa Structural Protein of the Occlusion-Derived Virion. Curr Microbiol.
398 Li L.and Rohrmann, Characterization of a baculovirus alkaline nucleaseJ. Virol. 2000 74p6401 6407 10864651
399 Okano K., Vanarsdall A.L., Rohrmann G.F. (2004). Characterization of a baculovirus lacking the Alkaline Nuclease Gene. J. Virol.
400 Okano K., Vanarsdall A.L., Rohrmann G.F. (2007). A Baculovirus alkaline nuclease knock out construct produces fragmented DNA and aberrant capsids. Virology.
401 Ferrelli M.L., et al. (2012). Genome of Epinotia aporema granulovirus (EpapGV), a polyorganotropic fast killing betabaculovirus with a novel thymidylate kinase gene. BMC Genomics.
402 Clem R.J., Robson M., Miller L.K. (1994). Influence of infection route on the infectivity of baculovirus mutants lacking the apoptosis-inhibiting gene p35 and the adjacent gene p94. J. Virol.
403 Du Q., et al. (1999). Isolation of an apoptosis suppressor gene of the Spodoptera littoralis nucleopolyhedrovirus. J Virol.
404 Zoog S.J., et al. (2002). Baculovirus apoptotic suppressor P49 is a substrate inhibitor of initiator caspases resistant to P35 in vivo. Embo J.
405 Means J.C., Penabaz T., Clem R.J. (2007). Identification and functional characterization of AMVp33, a novel homolog of the baculovirus caspase inhibitor p35 found in Amsacta moorei entomopoxvirus. Virology.
406 Clem R.J., Fechheimer M., Miller L.K. (1991). Prevention of apoptosis by a baculovirus gene during infection of insect cells. Science.
407 Herschberger P.A., Dickson J.A., Friesen P.D. (1992). Site-specific mutagenesis of the 35-kilodalton protein gene encoded by Autographa californica nuclear polyhedrosis virus: cell line-specific effects on virus replication. J. Virol.
408 dela Cruz W.P., Friesen P.D., Fisher A.J. (2001). Crystal structure of baculovirus P35 reveals a novel conformational change in the reactive site loop after caspase cleavage. J Biol Chem.
409 Fisher A.J., et al. (1999). Crystal structure of baculovirus P35: role of a novel reactive site loop in apoptotic caspase inhibition. Embo J.
410 Goenka S., Weaver R.F. (2008). The p26 gene of the Autographa californica nucleopolyhedrovirus: Timing of transcription, and cellular localization and dimerization of product. Virus Res.
411 Simon O., et al. (2008). Effects of Acp26 on in vitro and in vivo productivity, pathogenesis and virulence of Autographa californica multiple nucleopolyhedrovirus. Virus Res.
412 Wang L., et al. (2009). Characterization of a virion occlusion-defective Autographa californica multiple nucleopolyhedrovirus mutant lacking the p26, p10 and p74 genes. J Gen Virol.
413 Hashimoto Y., et al. (2000). Sequence analysis of the Plutella xylostella granulovirus genome. Virology.
414 Alaoui-Ismaili M.H., Richardson C.D. (1998). Insect virus proteins (FALPE and p10) self-associate to form filaments in infected cells. J Virol.
415 Kuzio J.D., et al. (1984). Nucleotide sequence of the p10 polypeptide gene of Autographa californica nuclear polyhedrosis virus. Virology.
416 Weyer U., Possee R.D. (1991). A baculovirus dual expression vector derived from the Autographa californica nuclear polyhedrosis virus polyhedrin and p10 promoters: co-expression of two influenza virus genes in insect cells. J Gen Virol.
417 Patmanidi A.L., Possee R.D., King L.A. (2003). Formation of P10 tubular structures during AcMNPV infection depends on the integrity of host-cell microtubules. Virology.
418 Carpentier D.C., Griffiths C.M., King L.A. (2008). The baculovirus P10 protein of Autographa californica nucleopolyhedrovirus forms two distinct cytoskeletal-like structures and associates with polyhedral occlusion bodies during infection. Virology.
419 Vlak J.M., et al. (1988). Functional studies on the p10 gene of Autographa californica nuclear polyhedrosis virus using a recombinant expressing a p10-β-galactosidase fusion gene. J. Gen. Virol.
420 Williams G.V., et al. (1989). A cytopathological investigation of Autographa californica nuclear polyhedrosis virus p10 gene function using insertion/deletion mutants. J. Gen. Virol.
421 Faulkner P., et al. (1997). Analysis of p74, a PDV envelope protein of Autographa californica nucleopolyhedrovirus required for occlusion body infectivity in vivo. J. Gen. Virol.
422 Haas-Stapleton E.J., Washburn J.O., Volkman L.E. (2004). P74 mediates specific binding of Autographa californica M nucleopolyhedrovirus occlusion-derived virus to primary cellular targets in the midgut epithelia of Heliothis virescens larvae. J. Virol.
423 Kuzio J., Jaques R., Faulkner P. (1989). Identification of p74, a gene essential for virulence of baculovirus occlusion bodies. Virology.
424 Zhou W., et al. (2005). The function of envelope protein p74 from Autographa californica M nucleopolyhedrovirus in primary infection to host. Virus Genes.
425 Ohkawa, T., Identification and characterization of genes of the baculovirus Bombyx mori nucleopolyhedrovirus (BmNPV) involved in viral pathogenesis. . Ph.D. thesis. University of California, Davis, Calif., 1997.
426 Li X., et al. (2007). The N-terminal hydrophobic sequence of Autographa californica nucleopolyhedrovirus PIF-3 is essential for oral infection. Arch Virol.
427 Kikhno I., et al. (2002). Characterization of pif, a gene required for the per os infectivity of Spodoptera littoralis nucleopolyhedrovirus. J. Gen Virol.
428 Peng K., et al. (2011). In situ cleavage of baculovirus occlusion-derived virus receptor binding protein P74 in the peroral infectivity complex. J Virol.
429 de Jong J., et al. (2009). Autographa californica multiple nucleopolyhedrovirus me53 (ac140) is a nonessential gene required for efficient budded-virus production. J Virol.
430 Xi Q., et al. (2007). Characterization of AcMNPV with a deletion of me53 gene. Virus Genes.
431 Knebel-Mörsdorf D., Kremer A., Jahnel F. (1993). Baculovirus gene ME53, which contains a putative zinc finger motif, is one of the major early-transcribed genes. J. Virol.
432 de Jong J., et al. (2011). Immediate-early protein ME53 forms foci and colocalizes with GP64 and the major capsid protein VP39 at the cell membranes of Autographa californica multiple nucleopolyhedrovirus-infected cells. J Virol.
433 Fang M., Dai X., Theilmann D.A. (2007). Autographa californica multiple nucleopolyhedrovirus EXON0 (ORF141) is required for efficient egress of nucleocapsids from the nucleus. J Virol.
434 Dai X., et al. (2004). Autographa californica multiple nucleopolyhedrovirus exon0 (orf141), which encodes a RING finger protein, is required for efficient production of budded virus. J Virol.
435 Fang M., Nie Y., Theilmann D.A. (2009). AcMNPV EXON0 (AC141) which is required for the efficient egress of budded virus nucleocapsids interacts with beta-tubulin. Virology.
436 McCarthy C.B., et al. (2008). Autographa californica multiple nucleopolyhedrovirus ac142, a core gene that is essential for BV production and ODV envelopment. Virology.
437 Yang Z.N., et al. (2008). Characterization of Bombyx mori nucleopolyhedrovirus with a deletion of bm118. Virus Res.
438 Braunagel S.C., et al. (1996). Transcription, translation, and cellular localization of three Autographa californica nuclear polyhedrosis virus structural proteins: ODV-E18, ODV-E35 and ODV-EC27. Virology.
439 McCarthy C.B., Theilmann D.A. (2008). AcMNPV ac143(odv-e18) is essential for mediating budded virus production and is the 30th baculovirus core gene. Virology.
440 Belyavskyi M., Braunagel S.C., Summers M.D. (1998). The structural protein ODV-EC27 of Autographa californica nucleopolyhedrovirus is a multifunctional viral cyclin. Proc Natl Acad Sci U S A.
441 Dall D., Luque T., O'Reilly D.R. (2001). Insect-virus relationships: sifting by informatics. Bioessays.
442 Lapointe R., et al. (2004). Characterization of two Autographa californica nucleopolyhedrovirus proteins, Ac145 and Ac150, which affect oral infectivity in a host-dependent manner. J Virol.
443 Zhang J.H., et al. (2005). Effects of Ac150 on virulence and pathogenesis of Autographa californica multiple nucleopolyhedrovirus in noctuid hosts. J Gen Virol.
444 Wang D., Zhang C.X. (2006). HearSNPV orf83 encodes a late, nonstructural protein with an active chitin-binding domain. Virus Res.
445 Ge J.Q., et al. (2009). Characterization of an early gene orf122 from Bombyx mori nucleopolyhedrovirus. Mol Biol Rep.
446 Dickison V.L., et al. (2012). Deletion of AcMNPV ac146 eliminates the production of budded virus. Virology.
447 Guarino L.A., Summers M.D. (1986). Interspersed homologous DNA of Autographa californica nuclear polyhedrosis virus enhances delayed-early gene expression. J. Virol.
448 Leisy D.J., et al. (1997). A mechanism for negative gene regulation in Autographa californica multicapsid nuclear polyhedrosis virus. J. Virol.
449 Stewart T.M., et al. (2005). The Autographa californica multiple nucleopolyhedrovirus ie0-ie1 gene complex is essential for wild-type virus replication, but either IE0 or IE1 can support virus growth. J Virol.
450 Chisholm G.E., Henner D.J. (1988). Multiple early transcripts and splicing of the Autographa californica nuclear polyhedrosis virus IE-1 gene. J. Virol.
451 Pearson M.N., Rohrmann G.F. (1997). Splicing is required for transactivation by the immediate early gene 1 of the Lymantria dispar multicapsid nuclear polyhedrosis virus. Virology.
452 Braunagel S.C., et al. (1996). Identification and analysis of an Autographa californica nuclear polyhedrosis virus structural protein of the occlusion-derived virus envelope: ODV-E56. Virology.
453 Theilmann D.A., et al. (1996). Characterization of a highly conserved baculovirus structural protein that is specific for occlusion-derived virions. Virology.
454 Harrison R.L., Sparks W.O., Bonning B.C. (2010). Autographa californica multiple nucleopolyhedrovirus ODV-E56 envelope protein is required for oral infectivity and can be substituted functionally by Rachiplusia ou multiple nucleopolyhedrovirus ODV-E56. J Gen Virol.
455 Sparks W.O., Harrison R.L., Bonning B.C. (2011). Autographa californica multiple nucleopolyhedrovirus ODV-E56 is a per os infectivity factor, but is not essential for binding and fusion of occlusion-derived virus to the host midgut. Virology.
456 Xiang X., et al. (2010). The Bombyx mori nucleopolyhedrovirus (BmNPV) ODV-E56 envelope protein is also a per os infectivity factor. Virus Res.
457 Hao B., et al. (2009). Variants of open reading frame Bm126 in wild-type Bombyx mori nucleopolyhedrovirus isolates exhibit functional differences. J Gen Virol.
458 Carson D.D., Guarino L.A., Summers M.D. (1988). Functional mapping of an AcNPV immediate early gene which augments expression of the IE-1 trans-activated 39K gene. Virology.
459 Carson D.D., Summers M.D., Guarino L.A. (1991). Molecular analysis of a baculovirus regulatory gene. Virology.
460 Yoo S., Guarino L.A. (1994). The Autographa californica nuclear polyhedrosis virus ie2 gene encodes a transcriptional regulator. Virology.
461 Imai N., et al. (2000). Analysis of interaction between molecules of Bombyx mori nucleopolyhedrovirus IE-2 using a yeast two-hybrid system. Acta Virol.
462 Prikhod'ko E.A., et al. (1999). In vivo and in vitro analysis of baculovirus ie-2 mutants. J Virol.
463 Prikhod'ko E.A., Miller L.K. (1998). Role of baculovirus IE2 and its RING finger in cell cycle arrest. J Virol.
464 Krappa R., Knebel-Mörsdorf D. (1991). Identification of the very early transcribed baculovirus gene PE-38. J Virol.
465 Wu X., Stewart S., Theilmann D.A. (1993). Alternative transcriptional initiation as a novel mechanism for regulating expression of a baculovirus trans activator. J. Virol.
466 Milks M.L., et al. (2003). Deletion of pe38 attenuates AcMNPV genome replication, budded virus production, and virulence in Heliothis virescens. Virology.
467 Jiang S.S., et al. (2006). Temporal transcription program of recombinant Autographa californica multiple nucleopolyhedrosis virus. J Virol.
468 Luque T., et al. (2001). The complete sequence of the Cydia pomonella granulovirus genome. J Gen Virol.
469 Willis L.G., et al. (2005). Sequence analysis of the complete genome of Trichoplusia ni single nucleopolyhedrovirus and the identification of a baculoviral photolyase gene. Virology.
470 Thumbi D.K., et al. (2011). Complete sequence, analysis and organization of the Orgyia leucostigma nucleopolyhedrovirus genome. Viruses.
471 Guarino L.A., Gonzalez M.A., Summers M.D. (1986). Complete sequence and enhancer function of the homologous DNA regions of Autographa californica nuclear polyhedrosis virus. J. Virol.
472 Leisy D.J., Rohrmann G.F. (1993). Characterization of the replication of plasmids containing hr sequences in baculovirus-infected Spodoptera frugiperda cells. Virology.
473 Pearson M.N., et al. (1993). Identification and characterization of a putative origin of DNA replication in the genome of a baculovirus pathogenic for Orgyia pseudotsugata. Virology.
474 Pearson M.N., et al. (1992). The Autographa californica baculovirus genome: Evidence for multiple replication origins. Science.
475 Pearson M.N., Rohrmann G.F. (1995). Lymantria dispar nuclear polyhedrosis virus homologous regions: characterization of their ability to function as replication origins. J. Virol.
476 Choi J., Guarino L.A. (1995). The baculovirus transactivator IE1 binds to viral enhancer elements in the absence of insect cell factors. J. Virol.
477 Leisy D.J., et al. (1995). The Autographa californica nuclear polyhedrosis virus homologous region 1a: Identical sequences are essential for DNA replication activity and transcriptional enhancer function. Virology.
478 Rodems S.M., Friesen P.D. (1993). The hr5 transcriptional enhancer stimulates early expression from the Autographa californica nuclear polyhedrosis virus genome but is not required for virus replication. J. Virol.
479 Nagamine T., et al. (2005). Focal Distribution of Baculovirus IE1 Triggered by Its Binding to the hr DNA Elements. J.Virol.
480 Landais I., et al. (2006). Functional analysis of evolutionary conserved clustering of bZIP binding sites in the baculovirus homologous regions (hrs) suggests a cooperativity between host and viral transcription factors. Virology.
481 Carstens E.B., Wu Y. (2007). No single homologous repeat region is essential for DNA replication of the baculovirus Autographa californica multiple nucleopolyhedrovirus. J Gen Virol.