# 8 Host resistance, susceptibility and the effect of viral infection on host molecular biology

Viruses are dependent on a variety of cellular functions to successfully infect an organism. For a productive infection, cellular structures and molecular pathways must be compatible with the virus for all the major events in virus replication including attachment, entry, uncoating, replication, assembly and exit. Insects, like many other organisms, have evolved methods to inhibit or block virus infections. Several methods by which organisms inhibit virus infection are summarized below. For a recent, more detailed review of some of the topics in this chapter, see (1).

## The insect immune system: hemocytes, melanization and encapsulation

Although lacking an adaptive immune system similar to vertebrates, insects have a variety of methods to resist infection by pathogens. Many of these defense mechanisms are similar to those of higher organisms and include physical barriers along with local and systemic responses. The latter includes the production of antimicrobial peptides and highly specialized cells called hemocytes. Hemocytes are circulating cells found in the hemolymph of insects and other arthropods that are similar to neutrophils and carry out roles in immunity such as phagocytosis, encapsulation and melanization as a first line of defense after injury or invasion by microorganisms. Although not employed by mammals, melanization causes a blackening of a wound site, which results from the synthesis and deposition of melanin. It is an important defense against infections because it can encapsulate and isolate pathogens similar to the blood clotting system in vertebrates. In addition, the intermediates of the melanization reaction can involve the production of reactive oxygen species that can be directly toxic to pathogenic microbes. In arthropods, an inactive form of phenoloxidase (prophenoloxidase) is synthesized and secreted into the hemolymph. Melanization is regulated by a cascade of serine proteases that cleave and activate prophenoloxidase (to phenoloxidase) that is then able to catalyze the oxidation of phenols (e.g., tyrosine) to non-aromatic ring compounds called quinones, which then polymerize and form melanin (2). It has been suggested that phenol oxidase may have an antiviral effect in the plasma of insects in addition to its role in encapsulation (3). The Toll pathway is another component of the innate immune response in many organisms. It acts by the recognition of structurally conserved molecules associated with pathogens such as viruses that are not present in the host organism. This recognition activates a cellular immune response. In Drosophila, melanization requires activation of the Toll pathway and is dependent on the removal of a serine protease inhibitor (Serpin27A), thereby allowing the cleavage of prophenoloxidase. The Toll pathway has been shown to be required for the efficient inhibition of Drosophila X virus. Inactivation of this system led to rapid death of infected insects and elevated virus titers (4).

A sequence related to lepidopteran serpins was found in the genome of a baculovirus of Hemileuca sp.(HespNPV). Serpins, ([underlined: ser]ine [underlined: p]rotease [underlined: in]hibitors), were named because of their ability to inhibit chymotrypsin-like serine proteases. In cowpox virus, a serpin, crmA, has been implicated in mitigating both the inflammatory and apoptotic responses. Although CrmA is a member of the serpin group, in contrast to other serpins, it is capable of inhibiting cysteine caspases (5). Similar to serpins, crmA binds the active caspases as a pseudosubstrate and has been shown to irreversibly bind to caspase-1 and is also capable of inhibiting caspases 4, 5, 9 and 10, reviewed in (6). The HespNPV serpin ortholog shows about 24% amino acid sequence identity to crmA (2e-16) over 377 amino acids. A possible role for this baculovirus serpin in subverting apoptosis or melanization remains to be determined.

Although most of the characterization of components of insect immune systems has been described from Drosophila, investigations have been conducted on baculovirus infection of Lepidoptera that suggest that they have similar defense systems. Heliothis virescens (tobacco bud worm) and Helicoverpa zea (corn earworm) are both members of the Noctuidae, but H. zea is 1,000-fold less susceptible to AcMNPV infection than H. virescens. Larvae of the two species are similar in their susceptibility to primary infection of the midgut and secondary infections of the tracheal epidermis. However, in H. zea, the foci infections in the tracheal epidermis become melanized and encapsulated, and hemocytes appear to be resistant to infection and are capable of removing the virus from the hemolymph. Therefore, AcMNPV infection of H. zea appears to be able to activate host melanization and encapsulation responses that reduce viral titers in the hemolymph and inhibit the progression of the infection. In contrast, in H. virescens this pathway appears to be much less active (7). Spodoptera littoralis is also highly resistance to AcMNPV infection and has been shown to be capable of efficiently encapsulating the virus in tracheoblast cells that serve the midgut columnar cells. These viral foci were removed during molting thereby eliminating the infection (8).

## The reaction of host cells to baculovirus infection: evidence from proteomics, microarrays, and expression analyses

AcMNPV was found to induce several host proteins during permissive infections of Helicoverpa virescens (Hv-AM1) cells (9). These included DNA supercoiling factors that are involved in transcriptional regulation in other systems. Calriticulum was also up regulated. It is involved in maintaining homostasis of the endoplasmic reticulum and also can be involved as a chaperone in the folding of nascent glycoproteins. These would be important functions for the virus to maintain. Two heat shock proteins (HSPs) were also up regulated. They also serve as chaperones in protein folding. Similarly, HSPs were also up regulated during AcMNPV infections of S. frugiperda cells, and inhibition of these proteins significantly reduced the rate of DNA synthesis (20-fold reduction) and BV production (10-fold reduction) in infected cells (10). In another investigation of AcMNPV infection of S. frugiperda cells, most host genes were down-regulated with the exception of heat shock 70 proteins. Proteins involved in protein expression and trafficking in the ER and golgi were down-regulated by 12 h p.i. (11). The up-regulation of hsp70 was also observed in larvae of Helicoverpa zea infected with HzSNPV (12). It has also been demonstrated that an inhibitor of inducible HSPs reduced the rate of viral DNA synthesis and suppressed the release of BV. Proteomic analysis of HSPs induced by baculovirus infection demonstrated the induction of 5 and the presence of 3 other HSPs (10, 13). It was also observed that AcMNPV infection was correlated with the accumulation of ubiquitinated proteins and aggresomes. When proteosome function was inhibited, the amount of ubiquitinated proteins increased indicating the proteosomal role in detoxification. In addition, under inhibition viral DNA replication was delayed suggesting a role for proteosome activity early in infection (14). Microarray analysis of BmNPV infections of B. mori cells identified elevated mRNA for transcription factors of the ETS family, a matrix metalloproteinase, a toll family gene, ATP binding cassette (ABC) transporter, an alkaline nuclease, and several potential cell surface receptors (15). Other investigations on the effects of BmNPV infection have identified certain mitogen activated protein kinases (MAPKs) that appear to be required for BmNPV gene expression. Inhibition of the expression of some of these genes results in reduced virus production (16). A comparison of cell lines derived from resistant and susceptible strains of B. mori found that two proteins, beta-N-acetylglucosaminidase 2 and aminoacylase were up regulated in the resistant cell line (17). Beta-N-acetylglucosaminidase 2 is involved in processing carbohydrates of glycoproteins, and it was suggested that it might be involved in resistance by altering the N-linked glycans of the viral GP64 envelope fusion protein and thereby reduce its ability to infect cells. Aminoacylase belongs to a group of enzymes that hydrolyze N-acetylated proteins. N-terminal acetylation of proteins is common and GP64 has been reported to be acylated (18). Therefore the aminoacylase could also interfere with GP64 function (17). Another study comparing resistance in B. mori identified eight genes that were up regulated in the midgut of resistant strains following BmNPV infection. These included genes encoding two antibacterial peptides, a serine protease (serpin) that might function in prophenol oxidase activation, cathepsin B, a cysteine proteinase, and actin A3 thought to be involved in the host immune response (19). A comparison of gene expression of AcMNPV and BmNPV in resistant cell lines indicated that most of the AcMNPV genes were expressed in BmN cells; however, their expression was delayed and very late gene expression was dramatically reduced. In contrast, in BmNPV-infected S. frugiperda cells, the expression of almost all viral genes was severely restricted (20). When S. exigua larvae were infected with AcMNPV, it was found that about 200 host genes were significantly up-regulated and a similar number were down regulated. The down regulated included antimicrobial peptides (see below) and hormones involved in juvenile hormone regulation (21). Microarray analysis of mRNA expression during the infection of Helicoverpa zea cells with the H. armigera NPV (HearNPV) showed the expected decline in host mRNA with a concomitant increase in viral mRNA with total mRNA 10.5 fold higher at 48 hpi. This was reflected in a 70% increase in total mRNA from 0 hpi. Although most insect genes (about 98%) were down-regulated, about 2% were up-regulated during the infection. There were 200-300 genes that were up-regulated over the time course and about 50 of the genes showed over a 5 fold increase with a few showing an increase of 20 fold or more. Some of the up-regulated genes included those encoding heat shock proteins, antimicrobial peptides, proteins involved in translation, intracellular transport, and those with ubiquitin protein ligase activity. Whereas categories down-regulated included DNA polymerase, regulation of the cell cycle, and negative regulation of apoptosis. It was also calculated that the 131,000 viral genomes were synthesized/cell by 24 hpi and the DNA mass of the cell was 20 times higher than during the diploid stage (22).

## Other pathways that modulate virus infection

RNA interference. RNA interference (RNAi) has the potential to inhibit the infection of insects by some RNA viruses. In Drosophila, evidence suggests that virus-specific dsRNA replication intermediates of RNA viruses are released upon cell lysis and taken up and processed by other cells, thereby generating systemic virus-specific RNAi based interference (23). However, some viruses can also interfere with this response. In one well-studied example, Flock house virus encodes a protein called B2 that suppresses RNAi by inhibiting the ability of Dicer to cleave long dsRNAs, thereby preventing the generation of siRNAs. In addition, by binding to siRNAs, B2 prevents their incorporation into the RISC complex that is dependent on their incorporation to identify and cleave homologous RNA sequences, thereby blocking the cleavage of target RNAs (24). Although it was originally thought that flies were not able to generate a systemic RNAi response, it was recently shown that an uptake pathway for dsRNA exists in Drosophila. This pathway is essential for antiviral immunity in adult flies. Mutants defective for this system had up to a 100-fold increase in viral titers (23).

Two different components of RNA interference pathways have been demonstrated to suppress the activity of endogenous retroviruses in Drosophila. These include the PIWI RNAs (piRNA) in germline cells (25) and siRNAs in both germline and somatic cells (26) (27) (see Chapter 11). Although RNAi has been used to experimentally manipulate baculovirus infection of cells, AcMNPV replication does not appear to be affected by this system in permissive cells. However, this does not rule out that the host range of other baculovirus-insect combinations can be affected by this system. In addition, the expression of miRNAs by large DNA viruses has been documented (28), and it remains to be determined if baculoviruses employ such systems to regulate the expression of their host or their own genes.

Similar to other viruses, baculoviruses likely encode microRNAs (28) that are involved in the regulation of both host and viral genes. In one study, four miRNAs were predicted from analyses of the BmNPV genome (29). The data suggested that they were targeted against 8 viral and 64 cellular genes. The viral targets included genes involved in replication, transcription (e.g., dbp), DNA polymerase, and lef-8. Two different bro genes, chitinase, and several other genes were also identified. Some of the cellular targets involved host defense pathways that are likely involved in resisting the virus infection. These include prophenoloxidase, which is integrally involved in the melanization response described above. Hemolin, another antiviral compound, also was predicted to be targeted. It is involved in pattern recognition, hemocyte aggregation, and phagocytosis. Several proteins involved in the pre-miRNA response and mRNA initiation were also identified. In another investigation of host and viral miRNAs of BmNPV and B. mori, it was found that BmNPV encodes a miRNA (miR-1) that down regulates the host GTP-binding protein RAN. RAN is an essential component of the Exportin-5 mediated transport machinery that is involved in the transport of small RNA molecules from the nucleus to the cytoplasm. Blocking BmNPV miR-1 results in elevated expression of RAN and a decrease in BmNPV replication. In contrast blocking a host miRNA (bmo-miR-8) that is targeted at BmNPV IE-1 transcripts resulted in a 3 fold increase in ie-1 transcripts and an about 8 fold increase of BmNPV DNA accumulation in fat body tissue (30). In another report it would found that miRNAs appeared to be conserved between S.frugiperda and B. mori and were down regulated during baculovirus infection (31). In contrast to the implication of small RNAs in host cell defense, in Helicoverpa armigera larvae infected with HaSNPV a large population of small RNAs were found that mapped to a variety of structural and replication genes. The authors suggest that the down regulation of these genes may be make the infection more efficient by preventing the over replication and premature death of the cell (32). It has been found in AcMNPV that the open reading frame of ODV-E25 (Ac94) encodes a miRNA that down regulates ODV-E25 expression. Evidence suggested that this miRNA causes a reduction in infectious virus production and may be involved in the shift from budded virus to occluded virus production (33).

Antimicrobial peptides. Antimicrobial peptides have also been implicated in protection against viral infection. One of these, gloverin, a cationic protein with antibacterial properties was found to be induced by AcMNPV infection. The addition of gloverin to infected cells was found to reduce AcMNPV BV production to 8 to 27% of untreated samples (34). However, when cDNA sequences were examined in infected cells, it was found that AcMNPV infection of Spodoptera exigua larvae down regulated three forms of gloverin along with attacin, another antimicrobial peptide (21).

Developmental resistance. It was also observed that H. virescens larvae demonstrate increasing resistance to fatal AcMNPV infections as they age. In one investigation it was found that the progression of infection is much slower in fifth- compared to fourth-instar larvae that had been orally infected. It was suggested that resistance was caused by different physiology of the midgut or tracheal cells. In particular, it was noted that midgut cells might undergo major changes since their composition is altered late in the fifth instar as the gut develops as part of metamorphosis to adult cell types. It was also suggested that midgut cells may be sloughed at a higher rate in later larval instars (35). Similar patterns of resistance to baculovirus infection has been observed in Lymantria dispar. Newly molted fourth-instar larvae showed lower LD_50_ titers compared to larvae infected at 2–3 days post molting. Also the 2–3-day post-molt insects showed a higher number of foci of infection that had been melanized and a reduced number of infected haemocytes (36, 37).

Inactivation of superoxides, Ac31, superoxide dismutase (SOD). Insect hemocytes are phagocytic cells (see above) and can destroy invading pathogens by the production of reactive oxygen such as superoxide (38). SOD can inactivate superoxide by converting it to hydrogen peroxide, which is also toxic, but can itself be inactivated with catalase to yield water and O_2_. Many baculoviruses may infect hemocytes and in this manner can spread an infection throughout an insect. Orthologs of SOD are found in the genomes of almost all lepidopteran baculovirus genomes. Ac31 (SOD) is closely related to SOD from a variety of insects including B. mori (E = 8E-49). The expression of viral SOD might mitigate the effects of superoxide production by hemocytes. However, AcMNPV deleted for sod replicated normally in cultured cells and insect larvae. The sod-deleted viruses showed no reduction in replication when grown in the presence of paraquat, a superoxide anion inducer (39). Whereas these data suggest that SOD of baculoviruses may be involved in some other role in virus biology, it could also indicate the conditions used to investigate its activity were not sensitive enough to determine its role. In contrast to AcMNPV, in BmNPV it was found that sod (Bm23) was essential for replication in BmN cells (40).

Other inhibitors of viral replication. In field populations of Cydia pomonella exposed to the granulovirus (CpGV), populations have been observed some with up 10,000-fold resistance. Using several approaches, changes in the innate immune systems, and altered peritrophic membranes and midgut receptors were ruled out as causing resistance. Using Q-PCR to examine viral replication in different tissues, no viral DNA was detected in the fat body, hemocytes or midgut cells of the tissues of resistant insects suggesting that the virus was unable to replicate in these cells. Furthermore, resistance could not be conferred by the transfusion of hemolymph from a resistant to a susceptible insect. This led the authors to conclude that resistance occurs within cells and must inhibit a very early step in viral replication (41).

## Host resistance to baculovirus infection in the midgut

The peritrophic matrix (PM). In addition to protection from external invasion by pathogens that is provided by the chitin-containing exoskeleton, an example of another physical barrier unique to insects that might influence resistance to viral infection is the PM. The ability of a virus to access the midgut epithelium would be one of the first problems confronting a virus when it is initiating infection. In some insects that are resistant to infection it was found that differing features of the PM can influence the susceptibility of an insect to viral infection. In Anticarsia gemmatalis, it was observed that insects that were more resistant to infection had a relatively thicker PM, a higher chitin content, and bound wheat germ agglutinin more intensely than the more susceptible insects (42) (43).

Midgut interactions. It has also been demonstrated that the oral infectivity of a virus could be influenced by the ability of the ODV to bind to the midgut of insects. It was observed that compared to SfMNPV, AcMNPV ODV had a reduced affinity for midgut cells of S. frugiperda larvae. Evidence was also presented suggesting that SfMNPV might bind to a different receptor(s) on columnar epithelial cells and this could contribute to the efficiency of its ability to initiate infection (44).

## Other factors influencing Baculovirus host range

A variety of phenomena that govern the selective infectivity of baculoviruses has been covered previously and there is little to add to their review (45). However, there have been recent contributions to understanding specific genes that have been observed to affect host range in insects. Most investigations on the molecular basis or host range specificity of baculoviruses have been done using BmNPV, AcMNPV, and LdMNPV. All of these viruses can be grown in cell culture and BmNPV and AcMNPV are closely related with homologous orfs showing ~90% nt and ~93% aa sequence identity (46). In contrast, LdMNPV is a member of the Group II baculoviruses and its orfs show about 41% aa identity with their AcMNPV homologs (47). Despite the similarity of AcMNPV and BmNPV, AcMNPV infects a much more diverse set of insects and insect cell lines than BmNPV (48). Whereas some of the limits on host range that were initially observed in cultured cells extend through to infection of the host insects, other host range effects are limited to a cell line and are not as restrictive in other cell lines from the same insects or in insect larvae of the species from which the cell lines were derived. This section will focus on investigations of host range in AcMNPV and BmNPV.

## Investigations on BmNPV and AcMNPV host range in B. mori and S. frugiperda cells

The baculoviruses of BmNPV and AcMNPV are closely related, showing on average orf amino acid sequence identities of about 93% (46). Despite their similarity, they differ significantly in their infectivity spectrum. For example, BmNPV replicates in B. mori (BmN) cells, but not S. frugiperda (Sf) cells. Conversely, AcMNPV replicates in Sf, but not BmN cells. Although the two viruses do not appear to productively infect the heterologous cell line, their patterns of gene expression differ in the nonpermissive cell lines. For example, almost all of the AcMNPV genes were found to be expressed in both BmN and Sf9 cells, although peak levels were delayed by about 12 hr in the nonpermissive BmN cells and polyhedrin and p10 expression were substantially reduced. In contrast, although almost all of the BmNPV genes were expressed in BmN cells, their expression in Sf9 cells was greatly reduced (20). Several different laboratories have investigated the factors responsible for the inability of these viruses to replicate in the heterologous cells. Some of these studies are summarized below.

Implication of DNA helicase in specifying host range in BmNPV and AcMNPV. By characterizing mixed infections of BmNPV and AcMNPV, a variant of BmNPV was isolated that was able to replicate in both BmN and Sf-21 cells. A 572 bp fragment of the BmNPV DNA helicase gene was found to be responsible for this altered host range (49). Further characterization of this region identified a single amino acid in the helicase orf (Asn564Ser) responsible for this change (50). Using a similar approach, other investigators found that altering three closely spaced amino acids in the AcMNPV helicase gene with the amino acids from BmNPV located at these positions, i.e., Val556Leu, Ser564Asn, Phe577Leu, allowed AcMNPV to replicate in B. mori cells (51). When AcMNPV mutants selected for their ability to replicate in BmN cells were passed through B. mori larvae, two amino acid changes (Ser564Asn, Phe577Leu) were found to be required to cause death of the larvae (52). It is unclear what role helicase plays in governing the inability of the virus to replicate in the heterologous cell lines. However, co-infection of BmN cells with wt AcMNPV and wt BmNPV causes premature cessation of both viral and host protein synthesis, although viral transcription appears to be normal. This effect is not observed when BmN cells are infected with both the recombinant AcMNPV and wt BmNPV. It has been suggested that since these few changes in the helicase gene have such a major effect on infection in BmN cells, the wt AcMNPV helicase gene may be toxic to the cell by eliciting an antiviral defense mechanism, by interacting with a host cell protein or nucleic acid, or by interfering with the translational apparatus (53). A wild silkworm, B. mandarina was found that had a host range allowing it to replicate in Bm5, Sf9, and T. ni cells. The BoMANPV helicase exhibited two mutations Asp291Asn and Asp300Asn. However, due a variety of other differences in many other genes, the significance of these changes remains to be determined (54).

BmNPV may be infectious for Sf-9 and other cells, but the level is low. In contrast to the reports described above, other laboratories using viral constructs expressing reporter genes have detected replication of BmNPV and AcMNPV in heterologous cell lines. In one study, a BmNPV construct expressing the LacZ gene under the polyhedrin promoter in Sf-9, Sf-21 and Hi-5 cells was examined. Compared with BmNPV infection in Bm5 cells, the BmNPV infections in the other cell lines were delayed with DNA replication detectable 3 to 5 days after being observed in BmN cells. In addition, the viral titers were much lower, varying from 0.7 to 7% (10^6^ to 10^7^ pfu/ml) the level in BmN cells (55). Since this report utilized LacZ expression to trace the virus, it may be more sensitive than previous studies that utilized the visualization of polyhedron production to monitor viral replication. Indeed, these authors detected either very few or no polyhedra in the heterologous infections using a wt BmNPV with an intact polyhedrin gene. In another investigation, using an AcMNPV construct that expressed the firefly luciferase gene under the Drosophila heat shock promoter, luciferase activity was detected in both virus infected larvae and in larvae of the next generation (56). Therefore, both these studies indicate that viral replication is occurring in the heterologous cell lines. Another report described AcMNPV DNA replication in BmN cells, but budded virions were not produced. In contrast, BmNPV DNA replication and BV production only occurred in Sf cells when they were superinfected with AcMNPV (57).

Implication of a host factor in specifying host range in BmNPV and AcMNPV (58). In studies conducted by the intrahemocoelic injection of AcMNPV into 31 different strains of B. mori larvae, 14 permissive insect strains were identified. A series of genetic crosses implicated a dominant host gene or set of linked genes that prevented AcMNPV infection in the resistant insects, but that are not present or do not interact with the virus in a negative manner in the susceptible insects.

GP64: an AcMNPV and BmNPV host range determinant. The one study that is difficult to reconcile with the investigations described above examined the replication of BmNPV in Sf-9 and Tn-5 (Hi-5) cells. Their investigations suggested that the barrier to infection was caused by the inability of BmNPV to be translocated to the nuclei of the Sf-9 or Tn-5 cells. It was found that BmNPV constructs that lacked the BmNPV gp64 envelope fusion protein gene, but contained the AcMNPV gp64 gene, were able to be translocated to nuclei. Although this process resulted in a productive infection in Hi-5 cells, replication in Sf-9 cells was still compromised. There are 22 codons that are different between these two genes. There is also the potential that the BmNPV gp64 orf may encode 19 additional amino acids at the N-terminus in transcripts initiated from late promoter elements (48). This study indicated that abortive replication was caused by the inability of BmNPV GP64 to facilitate fusion with the endosomal membrane. This would suggest that BmNPV GP64 has a major difference in biological properties compared to AcMNPV GP64, which has been demonstrated to allow entry into a wide array of vertebrate cells (59). Recent evidence suggests that a single amino is the host range determinant in AcMNPV GP64. It is HIS155 and the equivalent amino acid in BmNPV is TYR153. Changing AcMNPV gp64 to HIS155TYR and that of BmNPV to TYR153HIS decreased and increased the replication and cell spread of the respective viruses (60).

One possible difference between GP64 expression in the two viruses is the observation that, in contrast to the AcMNPV gp64 gene, which is shut off late in infection of Sf9 cells, in BmNPV infected BmN cells, gp64 is not shut off late in infection (61).

Global protein synthesis shutdown.

Global protein synthesis shutdown has been observed in a variety of combinations of baculoviruses and cell types, reviewed in (62) and can involve either transcriptional or translational shut down. This phenomenon appears to be a host response to viral infection in some cell lines and consequently viruses have developed mechanisms to counteract it. Helicase has been implicated in this process (see above), but there are also several other genes that act as host range factors because they allow the virus to replicate in certain cells that otherwise would be able to shut down the virus infection. Several such genes are described below.

Host cell-specific factor-1 (hcf-1, Ac70): AcMNPV specificity for T. ni cells. The AcMNPV gene host cell-specific factor-1 (hcf-1, Ac70) has been implicated in global protein synthesis shutdown. Homologs of hcf-1 are present in only three other baculoviruses. Two are close relatives of AcMNPV and their HCF-1 orfs are 99% (PlxyNPV) and 84% (RoMNPV) identical to that of AcMNPV, whereas the homolog in ClbiNPV is more distantly related (21% identical). HCF-1 was found to be required for transient expression of a late promoter-reporter gene by a late expression factor library in Tn368 cells, but not SF-21 cells (63). AcMNPV with null mutations of hcf-1 appeared to replicate normally in both Sf-21 cells and S. frugiperda larvae. However, in Tn-368 cells replication was impaired, including defects in DNA replication, late gene transcription, and virus production. This was reflected in the global shutdown of both host and viral protein synthesis. Such severe effects were not observed in another T. ni cell line. In T. ni larvae the oral infectivity of the null mutant was relatively normal, although the insects died more slowly than when infected with wt (64). This would suggest that HCF-1 is required for the productive infection of some, but not all cell types in T. ni larvae. Therefore, whereas AcMNPV deleted for hcf-1 was unable to replicate in cells similar to Tn-368, it can replicate in other types of T. ni cells, thereby allowing infection of larvae that contain a variety of different cell types.

Host range factor-1 (hrf-1): An LdMNPV gene that allows AcMNPV to replicate in L. dispar cells and insects. The Ld652Y cell line is semi-permissive for AcMNPV replication and all categories of viral genes are transcribed, but both viral and host mRNA translation is blocked late in infection (65). Cotransfection of LdMNPV and AcMNPV DNA into Ld652Y cells results in the production of budded virus that can replicate in Sf cells, suggesting that AcMNPV had been altered such that it could replicate in Ld652Y cells. To determine the LdMNPV gene responsible for this change, AcMNPV DNA was co-transfected with cloned segments of the LdMNPV genome, and an LdMNPV gene was identified, hrf-1, that permitted AcMNPV to replicate in Ld652Y cells (66). This recombinant AcMNPV was also able to infect L. dispar larvae in concentrations similar to wt AcMNPV in permissive insects (67). It was found that wt AcMNPV infection of L. dispar cells resulted in a shutdown of protein synthesis late in the infection (68). This protein synthesis inhibition was at the level of mRNA translation and could be rescued with tRNA from uninfected cells. This suggested that infection of L. dispar cells with wt AcMNPV results in the depletion or blockage of tRNA synthesis (69). It was also found that AcMNPV, lacking the apoptotic inhibitor p35 did not cause translational arrest, suggesting that the inhibition of apoptosis, which normally prevents cell death, in this case induces translational arrest (70). It was found that HRF-1 facilitated the replication of two other viruses in L. dispar cells (71).

Apoptosis and the specificity of baculovirus infections. Insect cells have different abilities to detect the presence of a virus infection and initiate an apoptotic program. In some cells virus infection will induce apoptosis, whereas in others, virus replication is unaffected. In addition, baculoviruses are able to interfere with apoptosis by the expression of apoptotic inhibitors. This has led to advances in understanding of apoptotic pathways and to the identification of baculovirus proteins that can block this process. It has also led to an understanding of the role apoptosis can play in determining the host range of a virus. An overview of apoptosis with relation to baculoviruses is included in Chapter 7.

## References

1 Thiem S.M. (2009). Baculovirus genes affecting host function. In Vitro Cell Dev Biol Anim.
2 Lemaitre B., Hoffmann J. (2007). The host defense of Drosophila melanogaster. Annu Rev Immunol.
3 Popham H.J., et al. (2004). Potent virucidal activity in larval Heliothis virescens plasma against Helicoverpa zea single capsid nucleopolyhedrovirus. J Gen Virol.
4 Zambon R.A., et al. (2005). The Toll pathway is important for an antiviral response in Drosophila. Proc Natl Acad Sci U S A.
5 Ekert P.G., Silke J., Vaux D.L. (1999). Caspase inhibitors. Cell Death Differ.
6 Turner S., Kenshole B., Ruby J. (1999). Viral modulation of the host response via crmA/SPI-2 expression. Immunol Cell Biol.
7 Trudeau D., Washburn J.O., Volkman L.E. (2001). Central role of hemocytes in Autographa californica M nucleopolyhedrovirus pathogenesis in Heliothis virescens and Helicoverpa zea. J Virol.
8 Rivkin H., et al. (2006). Response of immunocompetent and immunosuppressed Spodoptera littoralis larvae to baculovirus infection. J Gen Virol.
9 Popham H.J., et al. (2010). Baculovirus infection influences host protein expression in two established insect cell lines. J Insect Physiol.
10 Lyupina Y.V., et al. (2010). An important role of the heat shock response in infected cells for replication of baculoviruses. Virology.
11 Salem T.Z., et al. (2011). Comprehensive analysis of host gene expression in Autographa californica nucleopolyhedrovirus-infected Spodoptera frugiperda cells. Virology.
12 Breitenbach J.E., Shelby K.S., Popham H.J.R. (2011). Baculovirus Induced Transcripts in Hemocytes from the Larvae of Heliothis virescens. Viruses.
13 Lyupina Y.V., et al. (2011). New insights into the induction of the heat shock proteins in baculovirus infected insect cells. Virology.
14 Lyupina Y.V., et al. (2013). Proteotoxic stress induced by Autographa californica nucleopolyhedrovirus infection of Spodoptera frugiperda Sf9 cells. Virology.
15 Sagisaka A., et al. Genome-wide analysis of host gene expression in the silkworm cells infected with Bombyx mori nucleopolyhedrovirus. Virus Res.
16 Katsuma S., Mita K., Shimada T. (2007). ERK- and JNK-dependent signaling pathways contribute to Bombyx mori nucleopolyhedrovirus infection. J Virol.
17 Liu X., et al. (2010). Proteomic analysis of nucleopolyhedrovirus infection resistance in silkworm, Bombyx mori (Lepidoptera: Bombycidae). J Invertebr Pathol.
18 Roberts T.E., Faulkner P. (1989). Fatty acid acylation of the 67K envelope glycoprotein of a baculovirus: Autographa californica nuclear polyhedrosis virus. Virology.
19 Bao Y.Y., et al. (2009). Gene expression profiling of resistant and susceptible Bombyx mori strains reveals nucleopolyhedrovirus-associated variations in host gene transcript levels. Genomics.
20 Iwanaga M., et al. (2004). Expression profiling of baculovirus genes in permissive and nonpermissive cell lines. Biochem Biophys Res Commun.
21 Choi J.Y., et al. (2012). Analysis of genes expression of Spodoptera exigua larvae upon AcMNPV infection. PLoS One.
22 Nguyen Q., et al. (2013). Genome scale analysis of differential mRNA expression of Helicoverpa zea insect cells infected with a H. armigera baculovirus. Virology.
23 Saleh M.C., et al. (2009). Antiviral immunity in Drosophila requires systemic RNA interference spread. Nature.
24 Venter P.A., Schneemann A. (2008). Recent insights into the biology and biomedical applications of Flock House virus. Cell Mol Life Sci.
25 Brennecke J., et al. (2007). Discrete small RNA-generating loci as master regulators of transposon activity in Drosophila. Cell.
26 Kawamura Y., et al. (2008). Drosophila endogenous small RNAs bind to Argonaute 2 in somatic cells. Nature.
27 Czech B., et al. (2008). An endogenous small interfering RNA pathway in Drosophila. Nature.
28 Grassmann R., Jeang K.T. (2008). The roles of microRNAs in mammalian virus infection. Biochim Biophys Acta.
29 Singh J., et al. (2010). Discovering microRNAs from Bombyx mori nucleopolyhedrosis virus. Virology.
30 Singh C.P., Singh J., Nagaraju J. (2012). A baculovirus-encoded MicroRNA (miRNA) suppresses its host miRNA biogenesis by regulating the exportin-5 cofactor Ran. J Virol.
31 Mehrabadi M., Hussain M., Asgari S. (2013). MicroRNAome of Spodoptera frugiperda cells (Sf9) and its alteration following baculovirus infection. J Gen Virol.
32 Jayachandran B., Hussain M., Asgari S. (2012). RNA interference as a cellular defense mechanism against the DNA virus baculovirus. J Virol.
33 Zhu M., et al. (2013). A MicroRNA Encoded by Autographa californica Nucleopolyhedrovirus Regulates Expression of Viral Gene ODV-E25. J Virol.
34 Moreno-Habel D.A., et al. (2012). Inactivation of the budded virus of Autographa californica M nucleopolyhedrovirus by gloverin. J Invertebr Pathol.
35 Kirkpatrick B.A., Washburn J.O., Volkman L.E. (1998). AcMNPV pathogenesis and developmental resistance in fifth instar Heliothis virescens. J Invertebr Pathol.
36 McNeil J., et al. (2010). Contributions of immune responses to developmental resistance in Lymantria dispar challenged with baculovirus. J Insect Physiol.
37 McNeil J., et al. (2010). Pathogenesis of Lymantria dispar multiple nucleopolyhedrovirus in L. dispar and mechanisms of developmental resistance. J Gen Virol.
38 Bergin D., et al. (2005). Superoxide production in Galleria mellonella hemocytes: identification of proteins homologous to the NADPH oxidase complex of human neutrophils. Infect Immun.
39 Tomalski M.D., Eldridge R., Miller L.K. (1991). A baculovirus homolog of a Cu/Zn superoxide dismutase gene. Virology.
40 Katsuma S., et al. (2008). Genome-wide survey for baculoviral host homologs using the Bombyx genome sequence. Insect Biochem Mol Biol.
41 Asser-Kaiser S., et al. (2011). Baculovirus resistance in codling moth (Cydia pomonella L.) caused by early block of virus replication. Virology.
42 Levy S.M., et al. (2007). Susceptibility/resistance of Anticarsia gemmatalis larvae to its nucleopolyhedrovirus (AgMNPV): Structural study of the peritrophic membrane. J Invertebr Pathol.
43 Levy S.M., et al. (2012). The role of peritrophic membrane in the resistance of Anticarsia gemmatalis larvae (Lepidoptera: Noctuidae) during the infection by its nucleopolyhedrovirus (AgMNPV). Arthropod Struct Dev.
44 Haas-Stapleton E.J., Washburn J.O., Volkman L.E. (2005). Spodoptera frugiperda resistance to oral infection by Autographa californica multiple nucleopolyhedrovirus linked to aberrant occlusion-derived virus binding in the midgut. J Gen Virol.
45 Miller, L.K. and A. Lu, The molecular basis of baculovirus host range, in The Baculoviruses, L.K. Miller, Editor 1997, Plenum: New York.
46 Gomi S., Majima K., Maeda S. (1999). Sequence analysis of the genome of Bombyx mori nucleopolyhedrovirus. J Gen Virol.
47 Kuzio J., et al. (1999). Sequence and analysis of the genome of a baculovirus pathogenic for Lymantria dispar. Virology.
48 Katou Y., Ikeda M., Kobayashi M. (2006). Abortive replication of Bombyx mori nucleopolyhedrovirus in Sf9 and High Five cells: defective nuclear transport of the virions. Virology.
49 Maeda S., Kamita S.G., Kondo A. (1993). Host range expansion of Autographa californica nuclear polyhedrosis virus (NPV) following recombination of a 0.6-kilobase-pair DNA fragment originating from Bombyx mori NPV. J. Virol.
50 Kamita S.G., Maeda S. (1997). Sequencing of the putative DNA helicase-encoding gene of the Bombyx mori nuclear polyhedrosis virus and fine-mapping of a region involved in host range expansion. Gene.
51 Croizier G., et al. (1994). Extension of Autographa californica nuclear polyhedrosis virus host range by interspecific replacement of a short DNA sequence in the p143 helicase gene. Proc. Natl. Acad. Sc. USA.
52 Argaud O., et al. (1998). Two key mutations in the host-range specificity domain of the p143 gene of Autographa californica nucleopolyhedrovirus are required to kill Bombyx mori larvae. J Gen Virol.
53 Kamita S.G., Maeda S. (1993). Inhibition of Bombyx mori nuclear polyhedrosis virus (NPV) replication by the putative DNA helicase gene of Autographa californica NPV. J. Virol.
54 Xu Y.P., et al. (2012). A baculovirus isolated from the wild silkworm encompasses the host ranges of Bombyx mori NPV and Autographa californica MNPV in cultured cells. J Gen Virol.
55 Woo S.D., et al. (2007). Propagation of Bombyx mori Nucleopolyhedrovirus in nonpermissive insect cell lines. J Microbiol.
56 Mori H., et al. (1995). Transovarian transmission of a foreign gene in the silkworm, Bombyx mori, by Autographa californica nuclear polyhedrosis virus. Biotechnology (N Y).
57 Rahman M.M., Gopinathan K.P. (2003). Analysis of host specificity of two closely related baculoviruses in permissive and nonpermissive cell lines. Virus Res.
58 Guo T., et al. (2005). Productive infection of Autographa californica nucleopolyhedrovirus in silkworm Bombyx mori strain Haoyue due to the absence of a host antiviral factor. Virology.
59 Hofmann C., et al. (1995). Efficient gene transfer into human hepatocytes by baculovirus vectors. Proc Natl Acad Sci U S A.
60 Katou Y., et al. (2010). A single amino acid substitution modulates low-pH-triggered membrane fusion of GP64 protein in Autographa californica and Bombyx mori nucleopolyhedroviruses. Virology.
61 Rahman M.M., Gopinathan K.P. (2003). Characterization of the gene encoding the envelope fusion glycoprotein GP64 from Bombyx mori nucleopolyhedrovirus. Virus Res.
62 Ikeda M., et al. (2013). Baculovirus genes modulating intracellular innate antiviral immunity of lepidopteran insect cells. Virology.
63 Lu A., Miller L.K. (1995). Differential requirements for baculovirus late expression factor genes in two cell lines. J. Virol.
64 Lu A., Miller L.K. (1996). Species-specific effects of the hcf-1 gene on baculovirus virulence. J Virol.
65 Guzo D., et al. (1992). Viral and host cellular transcription in Autographa californica nuclear polyhedrosis virus-infected gypsy moth cell lines. J Virol.
66 Thiem S.M., et al. (1996). Identification of a baculovirus gene that promotes Autographa californica nuclear polyhedrosis virus replication in a nonpermissive insect cell line. J. Virol.
67 Chen C.J., et al. (1998). Lymantria dispar nucleopolyhedrovirus hrf-1 expands the larval host range of Autographa californica nucleopolyhedrovirus. J. Virol.
68 Du X., Thiem S.M. (1997). Responses of insect cells to baculovirus infection: protein synthesis shutdown and apoptosis. J. Virol.
69 Mazzacano C.A., Du X., Thiem S.M. (1999). Global protein synthesis shutdown in Autographa californica nucleopolyhedrovirus-infected Ld652Y cells is rescued by tRNA from uninfected cells. Virology.
70 Thiem S.M., Chejanovsky N. (2004). The role of baculovirus apoptotic suppressors in AcMNPV-mediated translation arrest in Ld652Y cells. Virology.
71 Ishikawa H., et al. (2004). Host range factor 1 from Lymantria dispar Nucleopolyhedrovirus (NPV) is an essential viral factor required for productive infection of NPVs in IPLB-Ld652Y cells derived from L. dispar. J Virol.