# 3 The baculovirus replication cycle: Effects on cells and insects

The baculovirus replication cycle is complex and involves two types of virions. One is occluded and is adapted for stability outside the host insect and for infection of midgut cells. In contrast, budded virions are not occluded and spread the infection from cell to cell within the insect. The major events in systemic infections are illustrated in Figure 1.

To initiate an infection, the occluded virions must infect midgut cells, and much of the evolution of this type of virion has focused on adaptations to this environment.

## The insect midgut

To understand the baculovirus infection cycle, a brief overview of the insect gastrointestinal tract is necessary, since this is the site of the initial infection and several major features of baculovirus biology have evolved to accommodate and exploit this unique environment (1). The insect gastrointestinal tract is composed of three sections: the fore-, mid- and hindgut. In Lepidoptera, the foregut is involved in facilitating the uptake, storage, and physical processing of food. It is lined with a chitin-containing cuticle that is part of the insect exoskeleton. A valve separates the foregut and midgut. The midgut is the major site of digestion of food and lacks a cuticle, but is lined with the peritrophic matrix (PM) (Figure 2). The PM is composed of chitin, mucopolysaccharides, and proteins, and it separates ingested vegetation from the midgut epithelium (2). It is thought that it protects the gut surface from damage caused by abrasive food material and limits the access of microorganisms. It also allows the transfer of liquid and digested substances to the midgut epithelial cells, but prevents the passage of larger food particles. It is worn away by the passage of food and is regenerated from the epithelial cells. The most common midgut epithelial cells are columnar cells with a brush border that is adjacent to the gut lumen. Regenerative cells are present at the base of the epithelium and replenish the columnar epithelial cells that become damaged and are sloughed into the lumen. Goblet cells are also present and may be involved in ion transport that regulates pH (Figure 2). The midgut is involved in enzyme secretion and absorption of digested food and has a gradient of pH values. At the entry and exit of the midgut, the pH is near 7.0, but in the central region it can vary from 10.0 to as high as 12.0, depending on the lepidopteran species (Figure 3) (3). These are among the highest pH values found in biological systems. Another valve separates the midgut and the hindgut. The hindgut is lined with a cuticle similar to the foregut and is involved in uptake of digested material, although to a lesser extent than the midgut.

## Two types of virions

Baculoviruses have evolved to initiate infection in the insect midgut. This has led to two major features of baculoviruses: the environmentally stable but alkali-soluble occlusion body, and occluded virions that have an envelope and associated proteins that allow survival and infection in the harsh alkaline midgut environment that contains a variety of digestive enzymes. In contrast, the environment encountered within the insect has a near-neutral pH, and therefore is more benign. Upon release from occlusion bodies, the virions are called occlusion-derived virus (ODV) (see below). The other virus type, budded virions (BV) have an envelope distinct from ODV that facilitates systemic infection. These types of virions differ in their efficiencies of infection for different tissues; ODV infect midgut epithelial cells up to 10,000-fold more efficiently than BV, whereas BV are up to 1,000-fold more efficient at infecting cultured cells than ODV (4, 5).

## From occlusion bodies to susceptible midgut cells

A common feature of the life cycle of all baculoviruses is the presence of virions embedded in occlusion bodies that are produced in the final stage of the replication cycle and are released upon the death and disintegration of the insect. Occlusion bodies serve to stabilize the virus in the environment and are normally only dissolved under alkaline conditions. High pH environments are rarely, if ever, encountered in most ecosystems and normally are only found in the midguts of some susceptible insects. Upon ingestion, the alkaline conditions of the midgut of larvae cause the dissolution of the occlusion bodies and the release of the ODV (Figure 2, and see Chapter 2, Figure 3). The polyhedron envelope/calyx structure that surrounds the polyhedra is likely degraded by proteinases present in the gut or associated with the polyhedra (see Chapter 2). After their release from occlusion bodies, the first barrier that the viruses encounter in the insect midgut is the peritrophic matrix (PM) (Figure 2). As described in the previous chapter, polyhedra are nonspecifically contaminated by bacterial proteinases that function under alkaline conditions. Also some baculoviruses encode endopeptidases (metalloproteinases) that contain divalent cations as integral components of their structure. One category of metalloproteinases, called enhancins, is concentrated in occlusion bodies. It is thought that enhancins specifically digest mucin, a PM component, thereby allowing virus access to the epithelial cell surface (6) (7). Enhancins are only encoded by a limited number of baculoviruses and it is unclear how viruses that lack this enzyme pass through the PM. However, some are highly infectious (e.g., AcMNPV) and do not appear to be inhibited by the PM, suggesting that there must be alternate or parallel mechanisms, such as the contaminating bacterial proteinases described above that are involved in breeching the PM (8). The following is an overview of the pathogenesis of AcMNPV and related viruses that cause systemic infections. These viruses, after initial replication in the midgut, spread throughout the organism. In contrast, a variety of less well-characterized viruses limit their replication to midgut cells. At the end of this section, the pathogenesis of viruses that are confined to the midgut and do not cause systemic infections will be reviewed.

### Infection of midgut epithelial cells; per os infectivity factors

AcMNPV ODV normally initiate the replication cycle by infecting columnar epithelial cells that are a major cell type lining the midgut, and regenerative cells in T. ni (9) or S. exigua larvae (10) (Figure 4). There are a combination of factors that appear to be involved in the initiation of midgut infections. These include factors that facilitate binding to the cells, cell receptors to which the virions bind, and virion envelope proteins that may have enzymatic activities that allow viral access to midgut cells or that fuse with the host cell membrane thereby permitting viral entry. A set of gene products called per os infectivity factors (11) are required for infection of midgut cells (Figure 4). They are specific to ODV and are not found associated with BV. They can be deleted from a viral genome without affecting the ability of the virus to infect cells in culture. However, such deletions reduce the ability of the virus to infect midgut epithelial cells. In AcMNPV, 7-10 such genes have been identified (see Chapter 2) including p74-pif (Ac138), Ac 22 (pif-2), Ac68 (pif-6), Ac83, Ac96 (pif-4), Ac115 (pif-3), Ac119 (pif-1), and Ac148 (pif-5). Homologs of these genes are conserved in all sequenced baculovirus genomes. This provides further evidence for a related pathway of infection for all members of this virus family. P74, PIF-1, PIF-2, PIF-4, and PIF-5 have been implicated as ODV envelope-associated proteins (11-15) and several have been shown to mediate specific binding of occlusion derived virus to midgut cells, suggesting that they are directly involved in virus-cell interaction as an initial step in infection (16) (Figure 4). Although PIF-3 appears to be an ODV-associated protein (17), it is apparently not involved in specific binding and its function is not known. PIF1, PIF2, PIF3, and Ac83 appear to be part of stable complexes located on the surface of virions and p74 also might be associated with this complex (18). It has been suggested that ODV binds to proteinase sensitive receptors (19) and once bound, the ODV envelope fuses with the epithelial cell membrane releasing the nucleocapsid into the cell cytoplasm.

### Chitin binding proteins

Two other proteins, Ac145 and Ac150, have properties similar to PIF proteins and are described in Chapter 2. Both Ac145 and Ac150 are predicted to encode chitin binding domains (20). In addition, Ac83 (VP91), a virion structural protein, is also predicted to encode a chitin binding domain. When the domain was deleted, viruses were unable to infect larvae via the midgut indicating that Ac83 is a per os infectivity factor and that chitin binding plays a major role in the ability of the virus to initiate midgut infection (21). There are two possible interactions involving chitin binding that might occur during midgut infection (Figure 2 and Figure 4). One would involve binding to the peritrophic matrix (PM) possibly to facilitate movement through the membrane. However, if the PM is extensively degraded during infection, this binding might be counterproductive. The chitin component of the PM is produced by chitin synthase, an enzyme that is located at the apical tips of brush border microvilli. The enzyme is also found associated with tracheal cells (22, 23). Therefore, an affinity for chitin could facilitate the interaction of the virion with these cells, first to initiate infection of midgut cells (e.g., Ac145 and Ac150) and subsequently to interact with tracheal cells (VP91). Another protein, GP37 (Ac64) has been shown to bind to chitin (24). Although GP37 has not been shown to be a structural protein, it may play a role in the infection of cells that synthesize chitin.

### ODV envelope proteins

Some ODV envelope proteins have been identified in addition to the PIF proteins. These are described in detail in Chapter 2 (see Chapter 2, Figure 5) (also see Figure 4). It is assumed that they facilitate fusion with the membrane of insect midgut cells (25); however, the pathway used by ODV to enter these cells has not been delineated. One such protein ODV-E66 (Ac46) (Figure 4) is capable of digesting chondroitin and to a lesser extent hyaluronan, polysaccharides that are major cellular components (26) (27). Chondroitin glycosaminoglycans have been found to localize to the the apical midgut microvilli of Anopheles gambiae (28) suggesting that if Lepidoptera are similar, this enzyme could facilitate recognition or entry into midgut cells.

## Entry into nuclei

After cell entry, NPV nucleocapsids are transported to the nuclear membrane in a process that involves actin polymerization (29) (30). Several lines of evidence suggest that the nucleocapsids are then transported through nuclear pores (Figure 5). Empty nucleocapsids were originally observed in nuclei of cells early in infection (25). In human cells exposed to AcMNPV at high moi, at 4 hr p.i. about 8% of the nucleocapsids that entered cells were localized to the cytoplasmic side of nuclear pores. When mitosis was blocked, and the nuclear membrane was intact, nucleocapsids were observed in nuclei, suggesting that they do not need dividing cells and the corresponding nuclear membrane breakdown to enter nuclei. Because of their localization to the cytoplasmic side of nuclear pores and their presence in nuclei of cells treated with mitotic inhibitors that prevent the breakdown of the nuclear membrane that occurs during mitosis, these authors concluded that nucleocapsids enter directly through nuclear pores (31). However, electron microscopic investigations have suggested that some baculoviruses inject their DNA through nuclear pores, reviewed in (32). Subsequently, using a virus encoding both a fluorescent tag fused to the vp39 capsid protein in addition to the wt vp39 protein, it was observed that the nucleocapsids localized to nuclear pore complexes and fluorescence was observed within nuclei (30) (Figure 6). This suggests that the nucleocapsids dock with and are transported through the nuclear pore complex. Nuclear pore complexes have been recently characterized and have been calculated to have a channel of 38 - 78 nm (33). Baculovirus virions have been calculated to have dimensions of 30-60 nm in diameter (34) indicating that they should be capable of moving through the pores. Recent evidence suggests that AcMNPV nucleocapsids injected into Xenopus oocytes cause nuclear pores in that system to undergo significant reorganization in order to accommodate the transit of the nucleocapsids (35). Once in the nucleus, the transcriptional cascade is initiated that eventually results in the production of nucleocapsids.

## Exiting the cell to form BV

With nucleocapsids injected into Xenopus oocytes, the virions appear to both be capable to enter and exit via nuclear pores (35). Whether this reflect the case in insects cells remains to be determined. Investigations with colchicine treatment that disrupts microtubule formation results in a major reduction in BV production suggesting that this structure might play a role in the movement of virions out of the cell. In addition, GFP tagged virions were observed in close association with microtubules. Kinesin, is a motor protein that is involved in transporting cargo to the cell periphery. It was found that a conserved sequence present on kinesin 1 interacts with VP39 and EXON0. These data suggests that BV interact with kinesin which then transports them along microtubules to the cell membrane (36) (Figure 5).

## Viruses that cause systemic infections

(For virus infections restricted to the midgut, see below.)

After nucleocapsids are replicated in the nucleus of midgut epithelial cells, they need to exit the cell to spread the infection. It has been suggested that they bud out of the nucleus and in this process obtain an envelope from the nuclear membrane (25) (Figure 5). The envelope may contain at least one viral protein, GP16 (37). This envelope is lost during transit through the cytoplasm. Concentrations or patches of envelope proteins accumulate at the plasma membrane (Figure 5). For group I NPVs, these include both GP64 (Ac128) and the F protein (Ac23) (38, 39) (See Figure 5). In other viruses, e.g., members of Group II NPVs that lack gp64, this membrane is likely modified by homologs of the F protein (40). The modification of the host cell membrane by GP64 is required for virus budding and consequently for secondary infections (41, 42). The distribution of GP64 in the initially infected midgut cells of T. ni larvae infected with AcMNPV is directed toward the basal and lateral regions of the cell (9). This targets the virions to bud away from the gut lumen and toward other susceptible tissues, including neighboring cells (43). This polar distribution of GP64 apparently does not occur in other tissues where targeting the infection in a specific direction would not be critical for spreading the infection (9).

### Transiting the basal lamina

The initiation of systemic infections may differ based on the insect host. In particular, the pathway that viruses use to transit the basal lamina has been examined. The basal lamina is a structure composed of a fibrous matrix of glycoproteins that surrounds the midgut epithelium and is thought to be a barrier to systemic infection. Movement of AcMNPV has been examined using viruses expressing a lacZ reporter gene so the infection of single cells can be traced. In T. ni larvae, secondary infections appeared initially in tracheoblasts and tracheal epidermal cells. It has been reported that in some insects, tracheal cells have projections that penetrate through the basal lamina (44) (reviewed in (45)). Such projections could provide access to the tracheal system and allow the virions to move past the basal lamina leading to a systemic infection (43). Further evidence for the ability of trachea to spread infections systemically was the observation that infections could be initiated by exposure of insects to BV through their spiracles. Such infections spread throughout the insect following tracheal tracts (46). However, investigations of AcMNPV using a different insect, S. exigua, indicated that rather than the secondary infection specifically localizing to tracheoblasts, other tissues, such as midgut muscle and hemocytes showed simultaneous infection, suggesting that transit through the basal lamina might not have been dependent solely upon tracheoblast infection (10). Surprisingly, it was noted in one of these studies that in most T. ni larvae the midgut infection appeared to be transient and although the infection had become systemic, it had been cleared from the midgut (43). This was attributed to sloughing and regeneration of the midgut epithelium, possibly as a response to the infection.

Recently it has been suggested that a viral encoded ortholog of fibroblast growth factor (FGF) may be involved in movement of the virus across the basal lamina (see below).

### Fibroblast growth factor (FGF), (Ac32) a possible factor in basal lamina transit

Ac32 has homology to fibroblast growth factor (fgf) and is termed vfgf. Homologs are found in the genomes of all lepidopteran baculoviruses (NPVs and GVs) and may reflect several independent lineages. AcMNPV fgf is closely related to a gene in D. melanogaster called branchless, whereas a Group II fgf ortholog from LdMNPV is less closely related to the insect homologs, and the GV orthologs show only limited similarity to NPV fgf orthologs. In BmNPV, FGF is glycosylated which is essential for its secretion (47, 48) and binds to an insect receptor called breathless (49). AcMNPV FGF has been demonstrated to stimulate insect cell motility (50). Although AcMNPV with a deletion of the vfgf gene showed no differences from wt in cultured cells (51), the time of death was delayed when it was fed to larvae (52). Similar results were observed for a BmNPV vfgf deletion (53). Recent evidence suggests that vFGF initiates a cascade of events that may accelerate the establishment of systemic infections. This involves two processes. vFGF from virus-infected midgut cells diffuse through the basal lamina and attract tracheal cells so that they are adjacent to infected midgut cells but separated by the basal lamina. vFGF then activates FGF receptors located on the tips of tracheal cells. This leads to the activation of matrix metalloproteases located in the same subcellular region via a MAP kinase or NFkB pathway. Matrix metalloproteases subsequently activate effector caspases that move extracellularly so that they are positioned for the degradation of the basal lamina by digestion of the laminin component. The delaminated tracheal cells are then susceptible to virus infection. This allows the transit of the virus through tracheal cells to other tissues and results in the systemic infection (54). This theory is supported by evidence for the activation of matrix metalloproteinases, the activation of effector caspases, and the degradation of laminin after the per os infection of midgut cells.

### Transiting midgut cells without replication

It has been suggested that under some circumstances nucleocapsids can transit through gut cells, bypassing replication, and bud directly into the hemolymph (25), or tracheal cells (55). This may be a mechanism for accelerating systemic infection and avoiding replication in gut cells that may be sloughed and eliminated from the insect. Genomes of all sequenced Group I viruses have both early and late promoter consensus sequences upstream of their gp64 envelope fusion protein genes. Expression of gp64 from the early promoter may prepare cell membranes for budding such that some nucleocapsids might directly transit the cell and bud without undergoing replication. When the early promoter was eliminated in the regulatory region of the AcMNPV gp64 gene, a delay in the time course of infections initiated by oral, but not intrahemocelic inoculation of insects was observed (56, 57). In addition, when T. ni cells are infected at high moi (200), many virions appear to become associated with the plasma membrane from within the cell (30). This theory is applicable only to the MNPV type of virus, because it is dependent upon a cluster of connected nucleocapsids simultaneously infecting single cells, after which they would have to become separated in the cytoplasm with some entering the nucleus to undergo conventional replication. These replicating virions would direct the early synthesis of GP64 to prepare the cell membrane for budding of the nonreplicated nucleocapsids that transit directly through the cell possibly facilitated by the vFGF pathway described above. The theory is complicated by a lack of understanding of the MNPV type of virion morphology because it appears to lack a genetic determinant (see Chapter 1). A similar combination of early and late promoters is also present upstream of almost all of the F genes of Group II viruses, suggesting that these two types of envelope fusion proteins (F and GP64) may be regulated in a similar manner. Whereas most of the Group I viruses are of the MNPV type (BmNPV may be an exception since single nucleocapsids predominate (58)), Group II viruses can be either MNPV or SNPV. For SNPVs, it is difficult to link the regulation of the fusion protein to the transit of the virus, because it would require extremely high levels of virus to ensure infection of single cells with more than one virion so that both transit and fusion protein synthesis could occur in the same cell. In contrast to the regulatory region of the F gene in Group II viruses, the regulatory region of the F gene orthologs in nine sequenced granulovirus genomes examined lack conventional early promoter consensus sequences (TATA + CAGT) in the proper context, and only 3 (AdorGV, AgseGV, CrleGV) have late promoter elements within 200 nt upstream of the ATG.

### Secondary infection, cell entry (Figure 1 and Figure 5)

As described in Chapter 2, either GP64 or an active form of the F protein is required for secondary infection, depending on the virus lineage. GP64 is an envelope fusion protein that, in addition to being required for exit from cells, is involved in initiating infection of other cells. It may also be an attachment factor, although the receptors it interacts with have not been defined. However, investigations have suggested that macropinocytosis, dynamin- and clathrin-dependent endocytosis, and cholesterol in the plasma membrane, all may be involved in the entry of AcMNPV into mammalian cells (59). It has also been suggested that transient forms of GP64 embed hydrophobic side chains into cell membranes triggering endocytosis independent of specific receptor molecules (60). This lack of specific receptors and the affinity of GP64 for cell membranes may explain its ability to facilitate the entry of AcMNPV into a wide variety of different cell types encountered during a systemic infection.

Since AcMNPV is capable of entering many types of cells, including those of vertebrates, receptors may be common molecules such as phospholipids (61). In both insect and vertebrate cells, entry is mediated by GP64 via clathrin-mediated endocytosis (62) (Figure 5). In this process, clathrin becomes concentrated in indentations or pits on the surface of plasma membranes. These structures are involved in the selective uptake of proteins into eukaryotic cells. Viruses commonly attach to receptors located on the surface of these clathrin-coated structures. The receptors contain internalization signals and upon binding to a viral attachment protein are stimulated to cause the pit to invaginate into the cytoplasm of the cell. This internalized vesicle is called an endosome or endocytic vesicle. It subsequently becomes acidified which causes the viral fusion protein to change conformation resulting in the merging of the viral envelope with the endosome membrane. This provides an opening or pore through which the nucleocapsid can enter the cell cytoplasm. It then moves to the nucleus and appears to enter through nuclear pores (see above) (25). Once they have entered the nucleus, the DNA can be uncoated and the secondary replication can commence. It has also been demonstrated that AcMNPV can enter cells at low pH (pH 4.8) by apparently fusing directly with the cell membrane independent of endocytosis (63). However, it is not clear the cells and virus would encounter a pH this low under normal conditions.

The importance of the host cell ESCRT (endosomal sorting complex required for transport) complex in AcMNPV entry and egress has been demonstrated (64). It was observed that dominant negative mutations of VPS4, a regulator of ESCRTIII, inhibited both virus entry and egress.

### The virogenic stroma

A novel structure characteristic of NPV-infected cells is the virogenic stroma (Figure 1 and Figure 5). It is an electron-dense, chromatin-like structure surrounding multiple less dense spaces that is found near the center of nuclei of infected cells. It is thought to be a molecular scaffold that is produced for the orderly and coordinated transcription and replication of viral DNA and the subsequent packaging of DNA and assembly of nucleocapsids. The structure of the virogenic stroma is not well understood, but it appears to be composed of RNA and protein with discrete concentrations of DNA that border intrastromal spaces, the sites of virion assembly (65, 66). In one study, it was observed that AcMNPV bacmids deleted for the single-stranded DNA binding protein, DBP (Ac25), failed to produce a virogenic stroma and also failed to produce normal-appearing nucleocapsids (67). PP31 (Ac36) also appears to be associated with the virogenic stroma (68), and deletion of Ac36 results in a decrease in the level of transcription of some, if not all, late genes (69). Late in the infection, virions may move from the virogenic stroma to a peripheral area where they become occluded (70), however, very late in infection, occlusion bodies can completely fill the nuclei. For a discussion of the virogenic stroma in relation to DNA replication, see Chapter 5.

## Viral proteins involved in the infection cycle

The replication cycle described above for BV is repeated, resulting in the amplification and spread of the virus throughout the insect (Figure 1 and Figure 5). There are some viral-encoded proteins that have been identified that facilitate this process. Several that have been characterized will be discussed here.

### Reorganization of the cytoskeleton, the role of PP78/83 (Ac9) a WASP-like protein, and P10

After AcMNPV infection of TN-368 cells, actin moves into nuclei and subsequently is polymerized from G- into F-actin. G-actin is a globular monomeric form of actin, and polymerizes into filamentous, or F-actin. This is a reversible reaction requiring ATP hydrolysis for polymerization. Eventually, during AcMNPV infection, most of the cellular actin is concentrated in nuclei. A cellular complex of up to 7 proteins is called the Arp2/3 complex. It is comprised of two [underlined: a]ctin [underlined: r]elated [underlined: p]roteins (Arp) that resemble the structure of monomeric actin. This complex is involved in nucleating the formation of F-actin filaments. Activators are required for this process and they bind both monomeric G actin and the Arp2/3 complex. One category of such activators is called Wiskott-Aldrich syndrome protein (WASP), and an ortholog of WASP (PP78/83) (AcMNPV orf9) is encoded by all lepidopteran NPV genomes. A purified truncated version of AcMNPV PP78/83 containing the critical activation domains was found to be capable of stimulating actin polymerization in combination with the Arp2/3 complex in vitro. Studies of AcMNPV with mutations of PP78/83 suggested nuclear actin polymerization is required for the coordination of nucleocapsid development including the proper association of ODV with envelopes (29). It was subsequently shown that nucleocapsids are propelled through the cytoplasm via actin polymerization that result in ‘actin comet tails’ trailing behind the nucleocapsid (30) (Figure 7). In addition, a point mutation in the arp2/3 binding region of PP78/83 results in partially defective actin polymerization with reduced actin tails and erratic paths of movement that frequently changed direction. The use of actin polymerization for transport of intracellular pathogen has been observed for poxviruses (71) and certain bacteria, such as Listeria monocytogenes (http://en.wikipedia.org/wiki/Listeria_monocytogenes) (72). However, in contrast to these pathogens that employ actin polymerization after replication, AcMNPV uses it immediately upon infection before viral replication (30). Evidence suggests that a capsid associated protein, BV/ODV-C42 (Ac101), binds to PP78/83 and transports it into nuclei. Mutant bacmids lacking Ac101 fail to demonstrate polymerization of actin in nuclei (73). In addition, a predicted pocket binding protein site was identified on Ac101 that is essential for actin polymerization (74).

A major feature of infection by lepidopteran NPVs is the massive reorganization of nuclei in which they expand to such an extent that they fill most of a cell's volume. It has been calculated that the diameter of Sf-9 cells may increase up to 1.45-fold during infection (75). The movement and concentration of actin may contribute significantly to this key feature of these infections (29). P10 also may contribute to cytoskeletal reorganization as it interacts with tubulin and may be involved in modifying microtubules (76, 77).

### EGT, (Ac15)

Another viral protein that can affect the course of an infection is an enzyme, ecdysteroid UDP-glucosyltransferase (78). Egt homologs are found in all lepidopteran NPV (I and II) and all but two GV (XcGV and SpliGV) genomes, but not in other lineages (as of 2008). Because of its role in insect steroid metabolism, the likely source of a gene encoding this enzyme would be from a host insect, and closely related orthologs of egt are found in a variety of insects such as B. mori. The function of the viral EGT is to block molting and pupation in infected larvae by catalyzing the transfer of glucose from UDP-glucose to ecdysteroids, thereby inactivating these insect molting hormones (79, 80). Molting can cause severe physiological stress on infected insects and many do not survive this transition. Therefore, the full productivity of the virus infection may not be realized. Evidence suggests that viral EGT prevents this stress by blocking molting. It also prolongs the feeding stage of infected larvae, thereby allowing the virus to replicate over a longer period of time in larger larvae, resulting in a higher yield of virus. The yield of occlusion bodies is increased about 30% in larva infected with wt virus compared to infection by virus lacking the egt gene (81, 82). A remarkable feature of NPV infection is that in some instances the insects can grow and continue feeding right up until they die. They appear healthy, yet when examined are heavily infected with high concentrations of occlusion bodies in their cells and hemolymph. EGT likely contributes to this effect. A common method to reduce the time that a virus takes to kill its host is to delete the egt gene. Larvae infected with these mutants are smaller and die sooner than wt, thereby reducing the damage caused to crops after the infection.

## Budded versus cell-associated virus — is there a transition?

A major transition during baculovirus infections is the shift from BV production to the retention of nucleocapsids in the nucleus and their incorporation into occlusion bodies. In a study examining the kinetics of AcMNPV replication in cultured cells, the proportions of BV and cell-associated virus were analyzed using quantitative PCR to measure the number of viral genomes (83) (Table 3.1). The virus used in this study expressed lacZ in place of the polyhedrin gene and did not produce occlusion bodies It was found that viral DNA doubled every 1.7 hr starting at 6 hr postinfection until DNA replication ceased at about 20 hpi, which was correlated with the onset of budding. At this time point, under optimal conditions, virion-associated DNA reached a plateau at about 84,000 genomes per cell. In contrast, only about 2,000 genome equivalents per cell were released into the medium. This suggests that about 2.3% of the viral DNA is budded out of an infected cell. At the cell concentration employed (>3 × 10^6^/ml), this would be equivalent to 6 × 10^9^ BV/ml. Since baculovirus titers of about 5 × 10^8^ pfu/ml are commonly achieved, this would suggest that about 10% of the BV were able to form plaques — not an unreasonable number. The possible inhibition of BV production late in infection could be the result of physical changes in the organization of the nucleus that limit nucleocapsid transit to the cytoplasm, or to the depletion of a component required for transit through the cytoplasm. It also is possible that as the infection progresses, ODV envelope proteins accumulate in the nucleus, and once the nucleocapsids become enveloped they can no longer exit the nucleus. It has been reported that ODV-E25 (Ac94) localizes to the periphery of replication foci, whereas vp39 was found within these structures (84). It has also been demonstrated that if ODV-E25 is expressed as an early gene under the IE-1 promoter, that budded virus production is inhibited and ODV-E25 appears to mostly concentrate in the cytoplasm around the nucleus, rather than localizing to the nucleus (85) (86). Subsequently it was found that the open reading frame of ODV-E25 encodes a microRNA and that this miRNA down regulates ODV-E25 expression. Evidence was shown that this miRNA causes a reduction in budded virus production and may be involved in the shift to occluded virus production (87).

The numbers measured in the study by Rosinski et al. (83) also provide information on the viral DNA generated per cell during an infection. If, for example, 84,000 genomes are produced per cell, this would be equivalent to 10^10^ bp/cell using 133,000 bp as the AcMNPV genome size. If the DNA content of a diploid Bombyx mori cell is ~10^9^ bp (88), this would suggest that 10 times more viral DNA was generated during the infection than was present in the cell genome. Although this may seem high, it could be reflected in the expansion that nuclei undergo during the infection. Also, if much of this DNA is packaged into virions, it might be considerably more compact than cellular DNA. In addition, much of this DNA may remain unpackaged, and this could be a factor underlying the ability of baculoviruses to hyperexpress late genes. Under these conditions, high levels of gene expression could be dependent on high gene copy number (see Chapter 5 for more detailed discussion). In an investigation of Helicoverpa zea cells infected with the H. armigera NPV (HearNPV), it was calculated that about 131,000 viral genomes were produced per cell and the mass of viral DNA was 20 times that of an uninfected diploid cell. They also estimated that extracellular viral genomes from both BV and ODV of about 5,600 and 29,000 at 24 and 48 hpi, respectively (89).

Table 1.

DNA produced in AcMNPV infected cells (from (83))

Cells infected (moi = ~20) | AcMNPV genomes/cell | BV genomes/cell (% total genomes) | Host DNA (bp)/cell (88) | Viral DNA (bp)/cell
3 × 10^6^/ml | 84,000 | 2000 (2.3%) | ~10^9^ | ~10^10^
5 × 10^6^/ml | 39,500 | 1750 (4.5%) | ~10^9^ | ~5 × 10^9^

## Occlusion, the final stage in virus infection

As described above, most of the assembled nucleocapsids appear to be destined to remain in the nucleus and become occluded. Cell type seems to govern the production of occlusion bodies. For some viruses, midgut cells do not appear to support occlusion body production. However, for other viruses, this is the only locale where occlusion occurs (see below). The reason for this specificity is not clear.

In lepidopteran NPV infections, virions that remain in nuclei appear to obtain a membrane from microvesicles that may be derived from the inner nuclear membranes that have been modified with virally encoded ODV-specific envelope proteins (90). A hypothetical model for this process is shown in Figure 8. A feature of the final stage of baculovirus replication that takes place after most DNA replication has occurred is the hyperexpression of very late genes resulting in the production of high levels of polyhedrin and p10. Polyhedrin accumulates in nuclei and at some point crystallizes into a lattice that surrounds virions. It is not clear whether virion occlusion is a concentration-dependent, random event, or if virions serve to enucleate the formation of occlusion bodies. At least one protein (Ac68) may be involved in this process because when the ortholog was deleted from BmNPV (Bm56), the virions produced were not incorporated into the occlusion bodies (91). Also, very late in infection, high levels of P10 are expressed. It forms tube-like structures that penetrate both the nucleus and cytoplasm (77, 92). As occlusion bodies mature, P10 fibrils align with the surface of the polyhedra and appear to be intimately involved with the assembly of the polyhedron envelope on the occlusion body surface (see Chapter 2, Figure 2). The final polyhedron product has a smooth, even surface (see Chapter 1, Figure 1). As discussed previously, if the polyhedron envelope gene is deleted, the polyhedra produced have an uneven surface and virions appear to be prone to becoming dislodged (see Chapter 2, Figure 3).

## Virus dispersal

Many newly hatched lepidopteran larvae remain as concentrated populations near the egg mass from which they emerged. Dispersal is largely dependent upon access to food supplies that are rapidly consumed near the egg mass. However, during the final larval stages many Lepidoptera disperse (wander) probably as an evolutionary mechanism to spread the population, reduce predation, and also to find a suitable place to pupate. In Manduca sexta, wandering is induced by a limited rise in the ecdysteroid titer in the hemolymph, and is associated with the cessation of feeding and the commitment to begin pupation ((93) and references therein). Baculovirus infection appears to be capable of enhancing this behavior and can cause a terminally infected insect to migrate to a higher elevation on the branch of a tree or plant. This is thought to facilitate dispersal of the occlusion bodies. This condition was noted in Germany in the 1900s and named ‘wipfelkrankeit’ (tree-top disease) (94). In one investigation, this phenomena was examined in cabbage moth larvae (Mamestra brassicae) on diet and cabbage plants infected with MbNPV which is likely a variant of MacoMNPV, a group II baculovirus (95). It was observed that most of the uninfected larvae were located in the heart of cabbage plants, whereas infected third instar larvae were located at the top or edge of the plant. This behavioral difference appeared to be confined to third instar and was not observed in first or fifth instar larvae (96).

A gene (Ac1) encoding a protein tyrosine phosphatase has been implicated in the enhancement of this terminal movement of infected insects. Insects infected with BmNPV deleted for this gene failed to undergo the enhanced wandering behavior induced by wt viral infection (97). How this enzyme can influence wandering behavior is unclear. Protein tyrosine kinases influence a variety of pathways that regulate a number of important physiological processes. Consequently, protein tyrosine phosphatases could have reverse effects on all these pathways (98). However, in one study, mutation of the active site of BmNPV PTP had no effect on the enhanced wandering in B. mori larvae infected with mutant BmNPV (99). In contrast, in another investigation with Spodoptera exigua larvae infected with a similar mutation of AcMNPV ptp caused reduced wandering behavior (100). In addition, there is another type of movement involving larval climbing behavior that has been reported in L. dispar larvae. It was suggested that the egt gene of the LdMNPV (that lacks a ptp gene) is involved in this behavior (101). Because of the broad effects of this enzyme on insect metabolism, it is unclear whether it is directly involved in regulating this activity. In addition, other LdMNPV genes that could influence this behavior were not examined.

Late in infection, after the wandering stage, the insects become torpid and undergo what is termed ‘melting’. Melting refers to the disintegration or liquifaction of the insect and is caused by some, but not all viruses. When on an even surface, the infected insects appear to flatten out and all the tissues appear to melt together and liquefy. Clearly, the disintegration of insects at a higher elevation on a plant and the subsequent contamination of lower vegetation could result in the infection of additional insect hosts, in contrast to simply dying, falling on the ground, and decaying into the soil.

### Enzymes facilitating insect disintegration: Chitinase (Ac126) and cathepsin (Ac127)

Some baculoviruses express enzymes that facilitate the disintegration of infected larvae late in infection. That an insect virus would obtain a chitinase gene to facilitate its dispersal might have been expected because chitin and chitinases are integral components of their host insects. The insect exoskeleton is composed of chitin, and because it is rigid, it must be periodically removed and reconstructed for insect larvae to grow. Therefore, insect larvae pass through various growth stages, or instars. The transition between these stages involves the digestion and absorption of part of the exoskeleton and shedding of the rest. Consequently, viruses infecting insects very likely had ready access to chitinase genes from their host insects. Chitinase genes are present in most lepidopteran Group I and II NPV and several GV genomes. The chitinase of these viruses is phylogenetically clustered with several lepidopteran chitinases, e.g., the AcMNPV (Ac126) and BmNPV (Bm103) proteins show over 60% aa sequence identity to B. mori chitinase. They are also similar (60% identical) to the chitinase of the bacteria, Serratia marcescens (102). Although closely related, the insect and viral enzymes have different properties; the AcMNPV chitinase is retained in the endoplasmic reticulum and functions under alkaline conditions, whereas the host enzyme is secreted and has reduced activity at higher pH (103-105). In conjunction with another enzyme, a viral proteinase (cathepsin, Ac127, see below), chitinase participates in the liquefaction of insects late in infection. Insects infected with viruses in which either the chitinase or the cathepsin gene had been deleted remained intact for several days after death (106). The retention of the viral chitinase in the ER may prevent the premature liquefaction of infected insects, allowing the virus to continue to replicate. The facility with which a virus (AgNPV) can be processed as a biocontrol agent for use against the soybean pest Anticarsia gemmatalis has been attributed to its lack of these two genes, thereby allowing collection of the virus from intact rather than disintegrated insects (107).

Orthologs of the viral cathepsins (Ac127) have a similar distribution to Ac126 (chitinase) and are present in most Group I /II NPV and several GV genomes and they appear to work in concert. As with the viral and insect chitinase genes, the viral cathepsins are closely related to insect cathepsins, e.g., the Ac127 cathepsin is 39% identical to an Apis mellifera cathepsin. To further optimize the role of the viral cathepsin in insect liquifaction, it is synthesized in an inactive form that is activated upon death of the insect (108). Therefore, both chitinase and cathepsin appear to have developed mechanisms to prevent their premature activation, thereby prolonging the infection.

Because of the dramatic and gruesome nature of the final events in some baculovirus infections, it was incorporated into popular fiction by a science writer well before the current bioweapons frenzy. In this novel, a baculovirus is engineered to replicate in human brain cells and the resulting mayhem it causes when released into the human population is the story line (109).

## The cytopathology of GVs

The above descriptions have focused on the replicative cycle of the most well-characterized baculoviruses, namely NPVs of Lepidoptera that can be easily cultivated and genetically manipulated. However, there are a variety of other viruses that cause a more limited infection. Although some GVs have been investigated, understanding their cytopathology has been hindered by the lack of an efficient cell culture system. In one cell culture system that has been described, both infectious hemolymph and BV titers were low (the highest BV titer was 10^6^ TCID_50_/ml) and BV titers decreased with passage (110). These low titers could reflect the insensitivity of the GV cell culture system and has made the generation of recombinant GVs challenging. Although GVs cause systemic infection, most GVs that have been characterized show a different pattern of cytopathology (Figure 9) from the lepidopteran NPVs described above. In addition, it is difficult to generalize regarding pathology because of the variation of gene content in different types of GVs. For example, half the GV genomes characterized lack cathepsin/chitinase genes and some also lack EGT genes. After their initial replication in midgut cells, subsequent infections vary with different GVs (reviewed in (111, 112)). Some GV infections are limited to the midgut, whereas others cause systemic infections and can replicate in a wide variety of tissues similar to NPVs. In addition, others appear to spread to and are limited to replicating only in fat body tissues. The cytopathology that occurs in the different cell types after GV infection, however, appears to be similar for all GVs and differs from NPVs (Figure 9). In infected cultured cells, the nucleus enlarges and the interior becomes clear as electron dense material becomes concentrated at the periphery near the nuclear membrane. At this stage, nucleocapsids that are likely destined to develop into BV are evident in the nuclei, but occlusion bodies are not present. Later in the infection the nuclear membrane appears to disintegrate and the nucleoplasm and cytoplasm merge. After this point, occlusion bodies become evident (110). Similar patterns of pathology have been found in infected insects with some cells showing a well-developed virogenic stroma in nuclei before the disintegration of the nuclear membrane (111).

## Viruses that are confined to the midgut: hymenopteran and dipteran NPVs

In some types of baculoviruses, the infection appears to be confined to the midgut. These viruses include NPVs of Diptera, e.g., mosquitos (CuniNPV) (113), Hymenoptera, and certain types of GVs mentioned above (114). In the mosquito virus, CuniNPV, viral replication appears to proceed from an early production of virions that bud into the cytoplasm and the later development of occluded virions. The role of BV in spreading the infection to other cells is unclear (113). The development of infections by NPVs of Hymenoptera is also not well characterized. Most surprising is the lack of a homolog of either gp64 or the F protein in the three hymenopteran NPV genomes that have been sequenced. Two candidates for genes encoding possible fusion proteins of 217 and 74 aa have been identified (115). However, fusion proteins of such a small size would be unprecedented for baculoviruses. Because of the requirement of fusion proteins for both BV cell egress and entry, it is unclear how infections by these viruses might spread. It is possible that infected cells are sloughed or disintegrate into the midgut lumen and release a mixture of occluded and nonoccluded virions containing an ODV envelope and other proteins that would allow infection of other midgut cells. In this case, ODV envelope and PIF proteins could facilitate this process. Genes predicted to encode homologs of these factors (including all the PIF proteins) have been identified in the genomes of the NPVs of Hymenoptera. These include p74, pif-1,2,3, 4 and odv-e18, -e27, -e56 (pif-5). A feature of at least some of these infections has been described as infectious diarrhea (112). This could be a reflection of extensive cell death. Conserved proteinases that could be involved in this process are described below.

### Possible dissemination strategies for GVs, and hymenopteran and dipteran NPVs

Although chitinase and cathepsin are found in almost all lepidopteran group I and II viruses, chitinase is present in only four and cathepsin in only three of ten sequenced GV genomes (as of 2008), and neither one is found in the genomes of the hymenopteran and dipteran viruses. However, there are other enzymes encoded in these viruses that might compensate for the lack of chitinase and cathepsin, especially when the infection is localized to the midgut. One such enzyme is a metalloproteinase (distinct from enhancin and cathepsin) with homologs present in all sequenced GV genomes. They have about 30% amino acid sequence identity to a catalytic domain in a stromelysin1 metalloproteinase of humans and sea urchins. The GV enzyme may be non-secreted and continuously active because it lacks both a signal peptide and a cysteine switch that maintains the homologous enzymes in an inactive form. The metalloproteinase from XcGV is capable of digesting proteins and is inhibited by metalloproteinase inhibitors (116). The presence of metalloproteinase homologs in GV genomes may be involved in assisting in viral transmission by facilitating the disintegration of cells after the GV replicative cycle is complete. This might be reflected in infection-associated diarrhea reported for some GVs (112). Likewise, although hymenopteran viruses lack homologs of chitinase and cathepsin, they all encode a trypsin-like protein (117) that shows high levels of sequence identity (~50%) to insect trypsin-like orthologs. For baculovirus infections limited to gut tissues such as hymenopteran NPVs (see above), chitinase may not be necessary because chitin is not a major structural component of midgut cells. Therefore, the presence of a trypsin-like protein may facilitate the dispersal of virus from the gut cells, both by releasing the virus into the environment, and also by providing inocula for the infection of other gut cells.

### Viruses with other tissue specificities

In contrast to viruses that are confined to replication in midgut cells, there has been one report of an NPV of a crane fly (Tipula paludosa) that specifically replicates in hemocytes (118) and the virus of the pink shrimp replicates in the hepatopancreas, an organ analogous to the vertebrate liver and insect fat body (119). These viruses have not been further characterized.

## Persistence/latent/covert baculovirus infections

The possible presence of persistent baculoviruses has been suggested based on spontaneous outbreaks in controlled insect colonies, or by induction from exposing insects to factors such as cold stress (120). Such occurrences have been reported for several different baculoviruses (reviewed in (121)). However, it was not until the advent of molecular biological technology including the polymerase chain reaction that methods became available to investigate these observations. The most carefully investigated recent description of a latent baculovirus infection has been reported for some, but not all, cultures of Mamestra brassicae, the cabbage moth. A virus, MbNPV, has been found to persist in most populations of M. brassicae in the United Kingdom (122). The latent virus can be activated when the persistently infected insects are fed either a closely related virus, Panolis flammea (pine beauty moth) NPV (PfNPV), or the more distantly related AcMNPV. PCR amplification identified MbNPV polyhedrin gene sequences in all insect stages including eggs, larvae, pupae, and adults. In the fourth instar larvae, the latent virus was found only in fat body tissue. A cell line was derived from this PCR-positive tissue that contained the latent virus (123) and it was estimated that the cell line contained 13-20 copies of the viral genome per cell (124). In addition, it was found that virus-free M. brassicae larvae died of an MbNPV-like infection when they were fed fat body cells from the latently infected laboratory strain of the insect. In another study, plasmids containing baculovirus late and very late promoters fused to the CAT gene were activated when transfected into latently infected cells. But when these plasmids were transfected into virus-free cells, such activation did not occur. This was interpreted to indicate that low levels of baculovirus genes were expressed in the latently infected cells, and the proteins produced were able to activate the expression of the late promoter constructs (125). Covert infections of laboratory cultures of Spodoptera exigua by S. exigua multinucleopolyhedrovirus (SeMNPV) and Mamestra brassicae NPV (MbNPV) have also been reported (126). Covert infections have also been reported for field collected and laboratory colonies of Choristoneura fumiferana (127) and were found to be induced in false codling moth, Thaumatotibia leucotreta, by overcrowding (128)

In an investigation involving a GV of the Indian meal moth, Plodia interpunctella, it was found that transcripts of the PlinGV granulin were present in 60-80% of the offspring of insects that had survived exposure to a ~10% lethal dose of PlinGV. Inheritance of the virus was also observed in offspring of either exposed males or females mated with naïve insects (129).

It has been reported that persistent baculovirus infections can be caused by the infection of cells with AcMNPV that lacks the p35 anti-apoptosis gene. These cell lines were resistant to subsequent challenge by AcMNPV infection, and some of the cells contained high levels of viral DNA and exhibited early gene expression (130). Under these conditions it would appear that there might be a balance between gene expression and the apoptotic pathway, and replication of viruses that lack p35 selects for virus that do not induce apoptosis, thereby allowing them to persist. It has also been reported that serial undiluted passage of SeMNPV in Se301 cells can yield persistently infected cells that contain a partial SeMNPV genome. Although they grow slower than wt cells, they are somewhat resistant to infection by the homologous virus resulting in reduced yields of polyhedra and an about a 10 fold reduction in BV titers. The replication of the a heterologous virus, AcMNPV appeared to be unaffected (131).

## References

1 Lehane, M.J. and P.F. Billingsley, Biology of the insect midgut, in Biology of the insect midgut, M.J. Lehane and P.F. Billingsley, Editors. 1996, Chapman and Hall: London.
2 Hegedus D., et al. (2009). New insights into peritrophic matrix synthesis, architecture, and function. Annu Rev Entomol.
3 Dow J.A. (1992). pH gradients in lepidopteran midgut. J Exp Biol.
4 Volkman L.E., Summers M.D. (1977). Autographa californica nuclear polyhedrosis virus: Comparitive infectivity of the occluded, alkali-liberated, and nonoccluded forms. J. Invertebr. Pathol.
5 Volkman L.E., Summers M.D., Hsieh C.H. (1976). Occluded and nonoccluded nuclear polyhedrosis virus grown in Trichoplusia ni: comparative neutralization, comparative infectivity, and in vitro growth studies. J. Virol.
6 Wang P., Granados R.R. (1997). An intestinal mucin is the target substrate for a baculovirus enhancin. Proc Natl Acad Sci U S A.
7 Toprak U., et al. (2012). Role of enhancin in Mamestra configurata nucleopolyhedrovirus virulence: selective degradation of host peritrophic matrix proteins. J Gen Virol.
8 Washburn J.O., Kirkpatrick B.A., Volkman L.E. (1995). Comparative pathogenesis of Autographa californica M nuclear polyhedrosis virus in larvae of Trichoplusia ni and Heliothis virescens. Virology.
9 Keddie B.A., Aponte G.W., Volkman L.E. (1989). The pathway of infection of Autographa californica nuclear polyhedrosis virus in an insect host. Science.
10 Flipsen J.T., et al. (1995). Passage of Autographa californica nuclear polyhedrosis virus through the midgut epithelium of Spodoptera exigua larvae. Virology.
11 Kikhno I., et al. (2002). Characterization of pif, a gene required for the per os infectivity of Spodoptera littoralis nucleopolyhedrovirus. J. Gen Virol.
12 Faulkner P., et al. (1997). Analysis of p74, a PDV envelope protein of Autographa californica nucleopolyhedrovirus required for occlusion body infectivity in vivo. J. Gen. Virol.
13 Fang M., et al. (2006). Open reading frame 132 of Helicoverpa armigera nucleopolyhedrovirus encodes a functional per os infectivity factor (PIF-2). J Gen Virol.
14 Harrison R.L., Sparks W.O., Bonning B.C. (2010). Autographa californica multiple nucleopolyhedrovirus ODV-E56 envelope protein is required for oral infectivity and can be substituted functionally by Rachiplusia ou multiple nucleopolyhedrovirus ODV-E56. J Gen Virol.
15 Fang M., et al. (2009). Autographa californica multiple nucleopolyhedrovirus core gene ac96 encodes a per Os infectivity factor (PIF-4). J Virol.
16 Ohkawa T., et al. (2005). Specific binding of Autographa californica M nucleopolyhedrovirus occlusion-derived virus to midgut cells of Heliothis virescens larvae is mediated by products of pif genes Ac119 and Ac022 but not by Ac115. J. Virol.
17 Li X., et al. (2007). The N-terminal hydrophobic sequence of Autographa californica nucleopolyhedrovirus PIF-3 is essential for oral infection. Arch Virol.
18 Peng K., et al. (2010). Baculovirus per os infectivity factors form a complex on the surface of occlusion-derived virus. J Virol.
19 Horton H.M., Burand J.P. (1993). Saturable attachment sites for polyhedron-derived baculovirus on insect cells and evidence for entry via direct membrane fusion. J. Virol.
20 Dall D., Luque T., O'Reilly D.R. (2001). Insect-virus relationships: sifting by informatics. Bioessays.
21 Zhu S., et al. (2013). The baculovirus core gene ac83 is required for nucleocapsid assembly and per os infectivity of Autographa californica nucleopolyhedrovirus. J Virol.
22 Zimoch L., et al. (2005). Regulation of chitin synthesis in the larval midgut of Manduca sexta. Insect Biochem Mol Biol.
23 Broehan G., et al. (2007). A chymotrypsin-like serine protease interacts with the chitin synthase from the midgut of the tobacco hornworm. J Exp Biol.
24 Li Z., et al. (2003). Characterization of a chitin-binding protein GP37 of Spodoptera litura multicapsid nucleopolyhedrovirus. Virus Res.
25 Granados, R.R. and K.A. Lawler, In vivo pathway of Autographa californica baculovirus invasion and infection. Virology, l98l. l08: p. 297-308.
26 Vigdorovich V., Miller A.D., Strong R.K. (2007). Ability of hyaluronidase 2 to degrade extracellular hyaluronan is not required for its function as a receptor for jaagsiekte sheep retrovirus. J Virol.
27 Sugiura N., et al. (2011). Baculovirus envelope protein ODV-E66 is a novel chondroitinase with distinct substrate specificity. J Biol Chem.
28 Dinglasan R.R., et al. (2007). Plasmodium falciparum ookinetes require mosquito midgut chondroitin sulfate proteoglycans for cell invasion. Proc Natl Acad Sci U S A.
29 Goley E.D., et al. (2006). Dynamic nuclear actin assembly by Arp2/3 complex and a baculovirus WASP-like protein. Science.
30 Ohkawa T., Volkman L.E., Welch M.D. (2010). Actin-based motility drives baculovirus transit to the nucleus and cell surface. J Cell Biol.
31 van Loo N.D., et al. (2001). Baculovirus infection of nondividing mammalian cells: mechanisms of entry and nuclear transport of capsids. J Virol.
32 Au S., Wu W., Pante N. (2013). Baculovirus Nuclear Import: Open, Nuclear Pore Complex (NPC) Sesame. Viruses.
33 Alber F., et al. (2007). Determining the architectures of macromolecular assemblies. Nature.
34 Jehle J.A., et al. (2006). On the classification and nomenclature of baculoviruses: a proposal for revision. Arch Virol.
35 Au S., Pante N. (2012). Nuclear transport of baculovirus: revealing the nuclear pore complex passage. J Struct Biol.
36 Danquah J.O., et al. (2012). Direct interaction of baculovirus capsid proteins VP39 and EXON0 with kinesin-1 in insect cells determined by fluorescence resonance energy transfer-fluorescence lifetime imaging microscopy. J Virol.
37 Gross C.H., et al. (1993). A baculovirus encoded 16 kDa glycoprotein localizes near the nuclear membrane of infected cells. Virology.
38 Blissard G.W., Rohrmann G.F. (1989). Location, sequence, transcriptional mapping, and temporal expression of the gp64 envelope glycoprotein gene of the Orgyia pseudotsugata multicapsid nuclear polyhedrosis virus. Virology.
39 Pearson M.N., Russell R., Rohrmann G.F. (2001). Characterization of a baculovirus encoded protein that is associated with infected-cell membranes and budded virions. Virology.
40 Pearson M.N., Groten C., Rohrmann G.F. (2000). Identification of the Lymantria dispar nucleopolyhedrovirus envelope fusion protein provides evidence for a phylogenetic division of the Baculoviridae. J. Virol.
41 Oomens A.G., Blissard G.W. (1999). Requirement for GP64 to drive efficient budding of Autographa californica multicapsid nucleopolyhedrovirus. Virology.
42 Monsma S.A., Oomens A.G.P., Blissard G.W. (1996). The gp64 envelope fusion protein is an essential baculovirus protein required for cell-to-cell transmission of infection. J. Virol.
43 Engelhard E.K., et al. (1994). The insect tracheal system: a conduit for the systemic spread of Autographa californica M nuclear polyhedrosis virus. Proc Natl Acad Sci U S A.
44 Maina J.N. (1989). Scanning and transmission electron microscopic study of the tracheal air sac system in a grasshopper Chrotogonus senegalensis (Kraus)--Orthoptera: Acrididae: Pyrgomorphinae. Anat Rec.
45 Volkman L.E. (2007). Baculovirus infectivity and the actin cytoskeleton. Curr Drug Targets.
46 Kirkpatrick B.A., et al. (1994). Primary infection of insect tracheae by Autographa californica M nuclear polyhedrosis virus. Virology.
47 Katsuma S., Shimada T., Kobayashi M. (2004). Characterization of the baculovirus Bombyx mori nucleopolyhedrovirus gene homologous to the mammalian FGF gene family. Virus Genes.
48 Katsuma S., et al. (2006). N-linked glycans of Bombyx mori nucleopolyhedrovirus fibroblast growth factor are crucial for its secretion. Biochem Biophys Res Commun.
49 Katsuma S., et al. (2006). Lepidopteran ortholog of Drosophila breathless is a receptor for the baculovirus fibroblast growth factor. J Virol.
50 Detvisitsakun C., et al. (2005). Stimulation of cell motility by a viral fibroblast growth factor homolog: proposal for a role in viral pathogenesis. Virology.
51 Detvisitsakun C., et al. (2006). Analysis of a baculovirus lacking a functional viral fibroblast growth factor homolog. Virology.
52 Detvisitsakun C., Cain E.L., Passarelli A.L. (2007). The Autographa californica M nucleopolyhedrovirus fibroblast growth factor accelerates host mortality. Virology.
53 Katsuma S., et al. (2006). In vivo and in vitro analyses of a Bombyx mori nucleopolyhedrovirus mutant lacking functional vfgf. Virology.
54 Means J.C., Passarelli A.L. (2010). Viral fibroblast growth factor, matrix metalloproteases, and caspases are associated with enhancing systemic infection by baculoviruses. Proc Natl Acad Sci U S A.
55 Washburn J.O., et al. (1999). Multiple nucleocapsid packaging of Autographa californica nucleopolyhedrovirus accelerates the onset of systemic infection in Trichoplusia ni. J Virol.
56 Washburn J.O., et al. (2003). Early synthesis of budded virus envelope fusion protein GP64 enhances Autographa californica multicapsid nucleopolyhedrovirus virulence in orally infected Heliothis virescens. J Virol.
57 Zhang J.H., et al. (2004). Autographa californica M nucleopolyhedrovirus early GP64 synthesis mitigates developmental resistance in orally infected noctuid hosts. J Gen Virol.
58 Hukuhara, T. Genetic variation of polyhedrosis viruses of insects. in Proc. Jount U.S.-Japan Seminar on microbial control of insects pests. 1967. Fukuoka.
59 Kataoka C., et al. (2012). Baculovirus GP64-mediated entry into mammalian cells. J Virol.
60 O'Flynn N.M., et al. (2012). Improving promiscuous mammalian cell entry by the baculovirus AcMNPV. Biosci Rep.
61 Tani H., et al. (2001). Characterization of cell-surface determinants important for baculovirus infection. Virology.
62 Long G., et al. (2006). Functional entry of baculovirus into insect and mammalian cells is dependent on clathrin-mediated endocytosis. J Virol.
63 Dong S., et al. (2010). Autographa californica multicapsid nucleopolyhedrovirus efficiently infects Sf9 cells and transduces mammalian cells via direct fusion with the plasma membrane at low pH. J Virol.
64 Li Z., Blissard G.W. (2012). Cellular VPS4 is required for efficient entry and egress of budded virions of Autographa californica multiple nucleopolyhedrovirus. J Virol.
65 Young J.C., MacKinnon E.A., Faulkner P. (1993). The architecture of the virogenic stroma in isolated nuclei of Spodoptera frugiperda cells in vitro infected by Autographa californica nuclear polyhedrosis virus. J. Struct. Biol.
66 Fraser M.J. (1986). Ultrastructural observations of virion maturation in Autographa californica nuclear polyhedrosis virus infected Spodoptera frugiperda cell cultures. J. Ultrastruct. Mol. Struct. Res.
67 Vanarsdall A.L., Mikhailov V.S., Rohrmann G.F. (2007). Characterization of a baculovirus lacking the DBP (DNA-binding protein) gene. Virology.
68 Guarino L.A., et al. (1992). The baculovirus phosphoprotein pp31 is associated with the virogenic stroma. J. Virol.
69 Yamagishi J., et al. (2007). The AcMNPV pp31 gene is not essential for productive AcMNPV replication or late gene transcription but appears to increase levels of most viral transcripts. Virology.
70 Williams, G.V. and P. Faulkner, Cytological changes and viral morphogenesis during baculovirus infection, in The Baculoviruses, L.K. Miller, Editor 1997, Plenum: New York.
71 Cudmore S., et al. (1995). Actin-based motility of vaccinia virus. Nature.
72 Theriot J.A., et al. (1992). The rate of actin-based motility of intracellular Listeria monocytogenes equals the rate of actin polymerization. Nature.
73 Wang Y., et al. (2008). Autographa californica multiple nucleopolyhedrovirus nucleocapsid protein BV/ODV-C42 mediates the nuclear entry of P78/83. J. Virol.
74 Li K., et al. (2010). The putative pocket protein binding site of Autographa californica nucleopolyhedrovirus BV/ODV-C42 is required for virus-induced nuclear actin polymerization. J Virol.
75 Gotoh T., Fukuhara M., Kikuchi K. (2008). Mathematical model for change in diameter distribution of baculovirus-infected Sf-9 insect cells. Biochem. Engin. J.
76 Cheley S., et al. (1992). Phosphorylated baculovirus p10 is a heat-stable microtubule-associated protein associated with process formation in Sf9 cells. J. Cell Sci.
77 Patmanidi A.L., Possee R.D., King L.A. (2003). Formation of P10 tubular structures during AcMNPV infection depends on the integrity of host-cell microtubules. Virology.
78 Wang Y., et al. (1995). Interaction of p53 with its consensus DNA-binding site. Mol Cell Biol.
79 O'Reilly D.R., Miller L.K. (1989). A baculovirus blocks insect molting by producing ecdysteroid UDP-glucosyl transferase. Science.
80 O'Reilly D.R., Miller L.K. (1990). Regulation of expression of a baculovirus ecdysteroid UDPglucosyltransferase gene. J. Virol.
81 O’Reilly D.R., Miller L.K. (1991). Improvement of a baculovirus pesticide by deletion of the egt gene. Bio/Technology.
82 O'Reilly D.R., Hails R.S., Kelly T.J. (1998). The impact of host developmental status on baculovirus replication. J Invertebr Pathol.
83 Rosinski M., Reid S., Nielsen L.K. (2002). Kinetics of baculovirus replication and release using real-time quantitative polymerase chain reaction. Biotechnol Bioeng.
84 Kawasaki Y., Matsumoto S., Nagamine T. (2004). Analysis of baculovirus IE1 in living cells: dynamics and spatial relationships to viral structural proteins. J. Gen. Virol.
85 Luo X.C., et al. (2013). Effects of Early or Overexpression of the Multiple Nucleopolyhedrovirus (ODV-) on Virus Replication. PLoS One.
86 Chen L., et al. (2013). The formation of occlusion-derived virus is affected by the expression level of ODV-E25. Virus Res.
87 Zhu M., et al. (2013). A MicroRNA Encoded by Autographa californica Nucleopolyhedrovirus Regulates Expression of Viral Gene ODV-E25. J Virol.
88 Mita K., et al. (2004). The genome sequence of silkworm, Bombyx mori. DNA Res.
89 Nguyen Q., et al. (2013). Genome scale analysis of differential mRNA expression of Helicoverpa zea insect cells infected with a H. armigera baculovirus. Virology.
90 Braunagel S.C., Summers M.D. (2007). Molecular Biology of the Baculovirus Occlusion-Derived Virus Envelope. Curr Drug Targets.
91 Xu H., et al. (2008). Bombyx mori nucleopolyhedrovirus ORF56 encodes an occlusion-derived virus protein and is not essential for budded virus production. J. Gen. Virol.
92 Carpentier D.C., Griffiths C.M., King L.A. (2008). The baculovirus P10 protein of Autographa californica nucleopolyhedrovirus forms two distinct cytoskeletal-like structures and associates with polyhedral occlusion bodies during infection. Virology.
93 Chamberlin M.E., King M.E. (1998). Changes in Midgut Active Ion Transport and Metabolism During the Fifth Instar of the Tobacco Hornworm (Manduca sexta). J. Exp. Zool.
94 Evans, H.F., Ecology and epizootiology of baculoviruses, in The biology of baculoviruses, R.R. Granados and B.A. Federici, Editors. 1986, CRC Press, Inc.: Boca Raton. p. 89-132.
95 Jehle J.A., et al. (2006). Molecular identification and phylogenetic analysis of baculoviruses from Lepidoptera. Virology.
96 Goulson D. (1997). Wipfelkrankheit : modification of host behaviour during baculoviral infection. Oecologia.
97 Kamita S.G., et al. (2005). A baculovirus-encoded protein tyrosine phosphatase gene induces enhanced locomotory activity in a lepidopteran host. Proc Natl Acad Sci U S A.
98 Tonks N.K. (2005). Redox redux: revisiting PTPs and the control of cell signaling. Cell.
99 Katsuma S., et al. (2012). The baculovirus uses a captured host phosphatase to induce enhanced locomotory activity in host caterpillars. PLoS Pathog.
100 van Houte S., et al. (2012). Protein Tyrosine Phosphatase-Induced Hyperactivity Is a Conserved Strategy of a Subset of BaculoViruses to Manipulate Lepidopteran Host Behavior. PLoS One.
101 Hoover K., et al. (2011). A gene for an extended phenotype. Science.
102 Fukamizo T., et al. (2011). Chitinase from Autographa californica Multiple Nucleopolyhedrovirus: Rapid Purification from Sf-9 Medium and Mode of Action. Biosci Biotechnol Biochem.
103 Daimon T., et al. (2006). Comparative studies of Bombyx mori nucleopolyhedrovirus chitinase and its host ortholog, BmChi-h. Biochem Biophys Res Commun.
104 Thomas C.J., et al. (1998). Localization of a baculovirus-induced chitinase in the insect cell endoplasmic reticulum. J Virol.
105 Saville G.P., et al. (2004). Deletion of the Autographa californica nucleopolyhedrovirus chitinase KDEL motif and in vitro and in vivo analysis of the modified virus. J Gen Virol.
106 Hawtin R.E., et al. (1997). Liquefaction of Autographa californica nucleopolyhedrovirus-infected insects is dependent on the integrity of virus-encoded chitinase and cathepsin genes. Virology.
107 Oliveira J.V., et al. (2006). Genome of the most widely used viral biopesticide: Anticarsia gemmatalis multiple nucleopolyhedrovirus. J Gen Virol.
108 Hom L.G., et al. (2002). Autographa californica M nucleopolyhedrovirus ProV-CATH is activated during infected cell death. Virology.
109 Preston, R., The Cobra Event1997, New York: Ballantine Books.
110 Winstanley D., Crook N.E. (1993). Replication of Cydia pomonella granulosis virus in cell cultures. J Gen Virol.
111 Tanada, Y. and R.T. Hess, Baculoviridae. Granulosis Viruses, in Atlas of invertebrate viruses, J.R. Adams and J.R. Bonami, Editors. 1991, CRC Press, Inc.: Boca Raton.
112 Federici, B.A., Baculovirus pathogenesis, in The Baculoviruses, L.K. Miller, Editor 1997, Plenum: New York.
113 Moser B., et al. (2001). Morphological and molecular evidence that Culex nigripalpus baculovirus is an unusual member of the family Baculoviridae. J Gen Virol.
114 Federici B.A., Stern V.M. (2000). Replication and occlusion of a granulosis virus in larval and adult midgut epithelium of the western grapeleaf skeletonizer, Harrisina brillians. J. Invertebr. Pathol.
115 Duffy S.P., et al. (2006). Sequence analysis and organization of the Neodiprion abietis nucleopolyhedrovirus genome. J Virol.
116 Ko R., Okano K., Maeda S. (2000). Structural and functional analysis of the Xestia c-nigrum granulovirus matrix metalloproteinase. J Virol.
117 Garcia-Maruniak A., et al. (2004). Sequence analysis of the genome of the Neodiprion sertifer nucleopolyhedrovirus. J Virol.
118 Smith K.A. (1955). Intranuclear changes in the polyhedrosis of Tipula paludosa. Nature.
119 Couch J.A. (1974). Free and occluded virus, similar to Baculovirus, in hepatopancreas of pink shrimp. Nature.
120 Biever K.D., Wilkinson J.D. (1978). A stress-induced gruanosis virus of pieris rapae. Environ. Entomol.
121 Kukan B. (1999). Vertical transmission of nucleopolyhedrovirus in insects. J Invertebr Pathol.
122 Burden J.P., et al. (2006). Phenotypic and genotypic characterisation of persistent baculovirus infections in populations of the cabbage moth (Mamestra brassicae) within the British Isles. Arch Virol.
123 Hughes D.S., Possee R.D., King L.A. (1993). Activation and detection of a latent baculovirus resembling Mamestra brassicae nuclear polyhedrosis virus in M. brassicae insects. Virology.
124 Hughes D.S., Possee R.D., King L.A. (1994). Quantification of latent Mamestra brassicae nuclear polyhedrosis virus in M. brassicae insects using a PCR-scintillation proximity assay. J Virol Methods.
125 Hughes D.S., Possee R.D., King L.A. (1997). Evidence for the presence of a low-level, persistent baculovirus infection of Mamestra brassicae insects. J Gen Virol.
126 Murillo R., Hussey M.S., Possee R.D. (2011). Evidence for covert baculovirus infections in a Spodoptera exigua laboratory culture. J Gen Virol.
127 Kemp E.M., Woodward D.T., Cory J.S. (2011). Detection of single and mixed covert baculovirus infections in eastern spruce budworm, Choristoneura fumiferana populations. J Invertebr Pathol.
128 Opoku-Debrah J.K., et al. (2013). Overcrowding of false codling moth, Thaumatotibia leucotreta (Meyrick) leads to the isolation of five new Cryptophlebia leucotreta granulovirus (CrleGV-SA) isolates. J Invertebr Pathol.
129 Burden J.P., et al. (2002). Vertical transmission of sublethal granulovirus infection in the Indian meal moth, Plodia interpunctella. Mol Ecol.
130 Lee J.C., Chen H.H., Chao Y.C. (1998). Persistent baculovirus infection results from deletion of the apoptotic suppressor gene p35. J Virol.
131 Weng Q., et al. (2009). Establishment of an insect cell clone that harbours a partial baculoviral genome and is resistant to homologous virus infection. J Gen Virol.

Figure 1.

A life cycle of a baculovirus causing systemic infection. Occlusion bodies ingested by an insect dissolve in the midgut, and ODV are released which then infect midgut epithelial cells (A). The virion buds out of the cell in a basal direction and initiate a systemic infection (B). Early in the systemic infection more BV are produced which spread the infection throughout the insect (C). Late in infection occluded virions are produced, and the cell then dies releasing the occlusion bodies (D). The virogenic stroma (VS) is indicated.

Figure 2.

The insect midgut and virus infection. The midgut cells generate the peritrophic matrix (PM) by the synthesis and secretion of chitin, muccopolysaccharides and proteins. They also secrete digestive enzymes and ions that regulate the pH. Occlusion bodies are dissolved by the high pH in the midgut lumen, and are further degraded by proteinases associated with occlusion bodies that may also digest the PM. The three major types of midgut cells are indicated: columnar epithelium (CE), goblet cells (G) and regenerative cells (R).

Figure 3.

PH profiles along the gut lumens of two lepidoperan species. The pH of the hemolymph was 6.7. The species shown are Lichnoptera felina (circles) and Manduca sexta (triangles).

Figure 4.

Possible interactions of selected ODV envelope proteins and vp91 (Ac83) with midgut cells. VP91 (Ac83), Ac145 and Ac150 all have chitin binding domains, suggesting that they may interact with chitin synthesizing cells. P74, PIF-1 and -2 bind to midgut cells. The role of PIF-3, 4, 5 and 6 are not known. ODV-E66 has an enzymatic activity (chondroitinase) (27) that may assist in initiating the infection.

Figure 5.

Budded virus infection of a Group I virus. BV attach to receptors located in clathrin coated pits via GP64 and are endocytosed (A). The endocytic vesicle is acidified and this changes the conformation of GP64 and causes the virion envelope to fuse with the endosomal membrane releasing the nucleocapsid into the cytoplasm (B). The nucleocapsid enters the nucleus through a nuclear pore complex (C), genes are transcribed, DNA is replicated and nucleocapsids are assembled in the virogenic stroma (D). In Group I virus, at least two envelope proteins are synthesized, GP64 and F. They are likely translated in association with the endoplasmic reticulum, glycosylated and transported to and incorporated into the cytoplasmic membrane via the Golgi apparatus (E). Nucleocapsids destined to become BV exit the nucleus and are thought to transiently obtain an envelope that is lost (F). Evidence suggests that they exit the cell by association with the motor protein kinesin that moves along microtubules (F) (36). Upon reaching the F- and GP64-modified cytoplasmic membrane, they bud through, and obtain envelopes (G).

Figure 6.

Entry of AcMNPV nucleocapsids through nuclear pores. This shows virus with the capsid protein VP39 fused with the fluorescent label, mCherry. Arrows indicate capsids; bar is 5 mm.

Figure 7.

Actin-based motility of AcMNPV within the cytoplasm of the cell. The virus was detected by capsid protein VP39 fused with the fluorescent label, mCherry (red); actin (green; FITC-phalloidin). Inset bar is 10 mm. Bottom: time series at 5 sec intervals.

Figure 8.

A hypothetical diagram of ODV membrane morphogenesis. In this diagram mRNA encoding ODV envelope proteins are transcribed (A) and exported (B) to the cytoplasm for translation (C) and the proteins are then targeted to the nucleus (D). Some of these proteins may be targeted to the inner nuclear membrane and induce it to invaginate, thereby forming microvesicles (E). The microvesicles may be further modified by the incorporation of additional virally encoded ODV envelope proteins, and virions then become enveloped (F, G). Shown are the outer nuclear membrane, the inner nuclear membrane and nuclear pore complexes (npc).

Figure 9.

A granulovirus life cycle with systemic infection. Many features of a systemic GV infection are likely to be similar to that of NPVs, including the infection of insect midgut and the systemic spread to other tissues (A, B). However, the GV infection leads to the clearing of the nucleus with nuclear material (N) locating to the margins (C) and the virogenic stroma (VS) distributed throughout the nucleus. Later in the infection the nuclear membrane becomes fragmented and the nuclear and cytoplasmic regions merge (D). This figure is interpreted from (110, 111).