# 1 Introduction to the baculoviruses, their taxonomy, and evolution

## The discovery of baculoviruses

The history of the discovery of baculoviruses is intimately related to the development of the silk industry that occurred in China as early as 5000 years ago. The culture of silkworms spread throughout Asia and reached Japan via Korea by about 300 C.E. and arrived in Europe by about 550 C.E. By the 12th century it was established in Italy and Spain and eventually spread to France and England and to Mexico by the 1500s. Silk production has been of major cultural significance in both China and Japan. It was a major item of commerce and in Japan is extensively documented in historic prints (1). Although no longer a major industry, silk production is still practiced symbolically by the Japanese royal family. (For a review of the history of silkworm culture, see (2)). As with any agricultural enterprise, problems were encountered caused by a variety of diseases, and these had to be confronted in order for the industry to flourish. Even before the germ theory of disease was introduced, a variety of different types of illnesses afflicting silkworms had been described, and methods to mitigate the effects of these diseases had been developed. With the advent of light microscopy, a prominent feature of one of the types of diseases was characterized by the presence of highly refractile occlusion bodies that were symptomatic of the affected insects. These were commonly polyhedron shaped (Figure 1) and led to the naming of the diseases associated with these structures as 'polyhedroses' by the mid-1800s. Although the presence of infectious particles within occlusion bodies had been suggested earlier, it was not until the late 1940s that the presence of rod-shaped virions was convincingly demonstrated by electron microscopy (3). This and other investigations also established the crystalline nature of the occlusion body structure. Subsequently, two different types of polyhedrosis diseases were distinguished: those in which the polyhedra developed in nuclei and were called nuclear polyhedroses (NPVs), and those with occlusion bodies present in the cytoplasm (Figure 2). These were called cytoplasmic polyhedroses (CPVs) (4). In contrast to the rod-shaped, DNA-containing NPVs, the CPVs were observed to have icosahedral capsids and were placed in the Reoviridae (genus Cypovirus), a family of viruses with segmented, double-stranded RNA genomes. A second category of baculovirus characterized by the presence of small, granular, ellipsoidal-shaped occlusion bodies was originally reported in the 1920s (5) and was named granulosis viruses (GVs). The division of the baculoviruses into two major groups, the nuclear polyhedrosis viruses (now called nucleopolyhedroviruses (NPV)) (Figure 3) and the granulosis viruses (now called granuloviruses (GVs)) (Figure 4), based on occlusion body morphology defined the major taxonomical divisions of these viruses until the advent of molecular biology.

The terminology for these viruses went through a series of names, and it was not until 1973 that a nomenclature that included Borrelinavirus, Bergoldiavirus, Smithiavirus, Moratorvirus and Vagoiavirus in honor of various historic individuals who had done early research on NPVs and GVs was changed and unified into the Baculoviridae (6). The name baculovirus was proposed by Mauro Martignoni, who because of his Italian-Swiss heritage was a Latin scholar. He suggested that they be named baculoviruses (family Baculoviridae) because of the rod-shape of their virions, which is derived from Latin baculum — cane, walking stick, staff.

The significance of baculoviruses in Nature

Although much of the early interest in baculoviruses was due to the threat they posed to the silk industry, baculoviruses play a major role in the control of natural insect populations. For example, they are a major regulator of gypsy moth populations in North America and in some instances have been shown to be responsible for over 50% of the mortality observed (7). They also are major contributors to the collapse of Douglas-fir tussock moth outbreaks (8). In addition to forest insect populations, they also appear to be important in the natural control of agricultural pests of human food crops, and as a result they may be a substantial contaminant of the human diet. For example, in one study it was found that cabbage purchased from 5 different supermarkets in the Washington D.C. area were all contaminated with baculoviruses to such an extent that each serving (about 100 cm^2^ of leaf material) would contain up to 10^8^ polyhedra of an NPV pathogenic for the cabbage looper, Trichoplusia ni (9)!

## The definition is not in the name: Naming baculoviruses

Baculoviruses are normally named for the initial host from which they were isolated. Consequently, the type NPV species, AcMNPV, was named for its host, the alfalfa looper, Autographa californica (Ac). This naming would be straightforward except that AcMNPV infects a wide variety of lepidopteran insects and its name originated because of its initial association. Consequently, a variety of other virus isolates e.g., Galleria mellonella (GmNPV), Rachiplusia ou (RoNPV), and Plutella xylostella (PlxyNPV), although having unique names, are closely related (~96-98.5% at the amino acid sequence level) variants of AcMNPV. In addition, viruses were originally named by the first letter of the genus and species of their host. However, as more viruses were discovered, some infected different insects that had names with the same first letters. This resulted in different viruses with the same descriptor. Consequently, the first two letters of the genus and species have become the convention, i.e., AcMNPV should really be AucaMNPV. However, since AcMNPV, GmMNPV and RoMNPV have been used so extensively, the original abbreviations have been retained.

## What defines a baculovirus?

### Genomes and nucleocapsids

Baculoviruses are a very diverse group of viruses with double-stranded, circular, supercoiled genomes, with sizes varying from about 80 to over 180 kb, that encode between 90 and 180 genes. Of these genes, a common set of about 30 homologous genes has been identified, and there are probably others that cannot be recognized because of the extent of changes incorporated over time. The genome is packaged in rod-shaped nucleocapsids that are 230–385 nm in length and 40–60 nm in diameter (10, 11). In the most well characterized baculoviruses, the virions are present as two types, occluded virions (ODV) and budded virions (BV). Although these two types of virions are similar in their nucleocapsid structure, they differ in the origin and composition of their envelopes and their roles in the virus life cycle (see Chapter 2).

### Occlusion bodies

Members of the Baculoviridae are characterized by their presence in occlusion bodies called polyhedra for NPVs and granules or capsules for GVs. Polyhedra are about 0.6–2 μM in diameter, whereas granules are oval-shaped with diameters of about 0.2–0.4 μM (10). Occlusion bodies are highly stable and can resist most normal environmental conditions thereby allowing virions to remain infectious indefinitely. Evidence suggests that they can survive passage through the gastrointestinal tract of birds, which can facilitate their dispersal (12, 13). The occlusion body consists of a crystalline matrix composed of a protein called polyhedrin in NPVs and granulin in GVs. Although they have different names, these two proteins are closely related.

Recently, nudiviruses, which may be occluded or non-occluded, have been shown to be related to baculoviruses (14). Therefore, in the future occlusion might not be considered a definitive feature of the Baculoviridae.

### Baculovirus hosts

Over the years, baculoviruses have been reported from a variety of different species of invertebrates. However, the only well-documented hosts are Diptera, Hymenoptera, and Lepidoptera. Convincing documentation has been reported for occluded virions resembling NPVs in a caddis fly (Trichoptera) (15) and a shrimp species (16, 17) (see below). An occluded baculovirus-like virus was also reported for a thysanuran, but it did not appear to affect its host and transmission studies failed (18). Baculoviruses have also been reported from Orthoptera (19), but later these were classified as pox viruses, and from Coleoptera, but these are normally not occluded and were included with the nudiviruses (20). Reports of infection of other insects, e.g., a coleopteran (21) could not be confirmed (Rohrmann, unpublished). In addition, there is a report of a baculovirus infecting a neuropteran (22). However, the infection occurred under laboratory conditions, where neuropterans were fed on lepidoptera that had died of an NPV infection. Consequently, the neuropterans were likely heavily contaminated from their food source, and although they appeared to die of an NPV infection, they were probably exposed to an unusually high virus dose. Naturally infected Neuroptera have not been documented. An example of the distribution of baculoviruses in insects that has been reported in the literature (23) is shown in Table 1. These numbers should be viewed with caution because many of the reports could be of the same virus infecting different species. However, they do give a good general overview of the likely distribution of baculoviruses. Of particular note is that GVs are confined to the Lepidoptera. In addition, all the hymenopteran hosts belong to a suborder called Symphyta that are comprised of sawflies (named because their ovipositor resembles a saw and in some species is used to cut into plants for egg deposition). Sawflies resemble Lepidoptera; they have herbivorous, caterpillar-like larvae and are distinct from the other hymenopteran suborder, Apocrita, which includes bees, ants, and wasps.

Table 1.

Distribution^1^ of baculoviruses in insect orders (23)

Insect orders | NPVs | GVs
Diptera | 27
Hymenoptera (Symphyta) | 30
Lepidoptera | 456 | 148

^1^ Indicates the number of species that have been reported to be infected

### Other defining features of the Baculoviridae: a virus encoded RNA polymerase

In addition to invertebrate hosts, circular, supercoiled double-stranded DNA genomes, rod-shaped enveloped nucleocapsids, and the production of occluded virions, an additional defining feature of baculoviruses is that they encode their own RNA polymerase. The core enzyme is composed of four subunits and functions in the transcription of late promoters that are initiated within a novel sequence element (see Chapter 6). Whereas other DNA viruses of eukaryotes encode their own polymerase, e.g., poxviruses, they replicate in the cytoplasm and therefore do not have access to the host cell transcriptional apparatus located in nuclei. Baculoviruses, in contrast, exploit the host cell transcriptional system for expressing their early genes, but after initiation of DNA replication they are dependent upon their own RNA polymerase for transcription of their late and very late genes.

## Baculovirus Diversity

Phylogenetic analysis suggests that large DNA viruses of insects evolved several million years ago along with the first insects (24) (25) and consequently as different insects evolved and proliferated, so did their associated viruses. The recent proliferation of baculovirus genome sequences has greatly expanded our understanding of their diversity and evolution. This has yielded distinct patterns of virus relatedness (Figure 5) in which virus lineages are associated by the host that they infect. The Baculoviridae are divided into four genera (26). The viruses of Lepidoptera are divided into Alpha- and Betabaculoviruses encompassing the NPVs and GVs, respectively, and those infecting Hymenoptera and Diptera are named Gamma- and Deltabaculoviruses, respectively (Table 2). Such patterns of host-associated virus diversity were first observed for small DNA viruses (papilloma and polyoma viruses) of mammals (27) and suggested for baculoviruses based on N-terminal polyhedrin and granulin sequences (28). In this process, viruses associate with a host, and as their host becomes genetically isolated and speciates, so does the virus in a process called host-dependent evolution. As more sequence data has become available, this process has been more convincingly demonstrated for baculoviruses (29) and is clearly reflected in Figure 5 in which the major lineages are clustered into clades based on the host insect that they infect. In GVs, host-dependent evolution has been suggested at the level of insect families (30). A major division has been observed in the lepidopteran NPVs that has resulted in the separation of this lineage into two major Groups, I and II (31). These two groups differ significantly in gene content, most notably Group I NPVs use GP64 as their budded virus (BV) fusion protein, whereas Group II NPVs lack gp64 and utilize a protein called F (32). There are also 11 other genes in addition to gp64 that appear to be found only in Group I NPVs (Table 3) (33). It has been suggested that the Group I lineage originated when a NPV variant uniquely containing these genes incorporated gp64 which stimulated their evolution as a distinct lineage (34) (35). Although the list of host insects provides information on baculovirus distribution, sequence analysis of common sets of genes from a wide variety of baculoviruses has provided a picture of the actual extent of their diversity (36). From this data, a picture of the lepidopteran viruses has emerged. However, more information on viruses from the other insect orders is needed to complete our understanding of baculovirus evolution.

Table 2.

Genera of the Baculoviridae

Genus | Members
Alphabaculovirus | Lepidopteran NPVs
Betabaculovirus | Lepidopteran GVs
Gammabaculovirus | Hymenopteran NPVs
Deltabaculovirus | Dipteran NPVs

Table 3.

Genes^1^ found in and unique to all sequenced Group I NPV genomes

Ac1 (ptp), Ac5, Ac16 (BV-ODV26), Ac27 (iap-1), Ac30, Ac72, Ac73, Ac114, Ac124, Ac128 (gp64), Ac 132, Ac151 (ie2)

^1^ Genes are designated by their AcMNPV orf number

### Multiple versus single nucleocapsids

A prominent feature of the nucleocapsids within polyhedra is their organization into either single or multiple aggregates of nucleocapsids within an envelope (Figure 3). For example, in some NPVs there can be from 1 to 15 nucleocapsids per envelope, with bundles of 5 to 15 predominating. In contrast, strains defined as having a single nucleocapsid per envelope rarely show more than one nucleocapsid per envelope (10, 37). It has been suggested that the MNPV phenotype may accelerate the ability of the virus to establish the infection because if multiple nucleocapsids infect a cell simultaneously, some could enter the nuclei and begin replication whereas others could transit the cell and spread the infection elsewhere (this is discussed in Chapter 3). Another benefit of groups of nucleocapsids infecting a cell would be that they could repair damaged DNA via recombination. Fatally damaged genomes could recombine to produce a viable molecule. Because this feature is so distinctive and characteristic of specific isolates, it was incorporated into the early nomenclature such that NPVs were categorized as either MNPV or SNPVs (also previously called multiply or singly embedded virions (MEV and SEV)). In addition, whereas MNPVs and SNPVs were both found in lepidopteran viruses, only SNPVs were observed in other insect orders. GVs were also categorized as singly enveloped; however, multiple GVs, although rare, have been described (38). With the accumulation of DNA sequence data that allowed for the determination of definitive phylogenetic relationships, it was found that the MNPV and SNPV division did not conform to the phylogeny of the viruses. For example, at one point BmNPV was considered the type virus for SNPVs because of its production of predominantly single nucleocapsids (39). However, sequence data indicates that BmNPV is closely related to AcMNPV (both belong to Group I), whereas other MNPVs such as LdMNPV and SeMNPV are more distantly related Group II viruses, which also includes SNPV-type viruses. Drawing conclusions regarding the properties of MNPV and SNPV viruses is fraught with difficulty because their genetic content is often so different that it is not possible to attribute characteristics of a virus to its M- or SNPV phenotype.

It was recently observed that AcMNPV deleted for Ac23, a homolog of the F fusion proteins of Group II viruses, shows an elevated percentage of singly enveloped virions (45%) vs. 11–22% for different virus constructs encoding Ac23 (40). Although it is a BV envelope protein, Ac23 has been reported to also be associated with occluded virions (41), although the ortholog from OpMNPV (Op21) did not appear to be ODV-associated (42). It was suggested that these different observations were due to the use of a proteinase inhibitor for the characterization of Ac23 (41). It has also been shown that deletion of Ac92, a gene encoding a sulfhydryl oxidase, results in virions that superficially resemble the SNPV phenotype (43). However, they are not infectious, indicating that they are very different from true SNPVs. It was also observed that point mutations in domains II or III of the AcMNPV DNA polymerase gene caused a dramatic change in the ratios of S- and M- NPV types. For example wt AcMNPV showed about 3% S nucleocapsids in infected cell nuclei, whereas a point mutant in domain III or a double mutant in domains II and III resulted in 61 and 89% single nucleocapsids, respectively (44). Furthermore, in a report describing the isolation of a virus pathogenic for Bombyx mandarina (BomaNPV S2), it was observed that the virus grew in both Bm5 and T. ni cells. In Bm5 cells, the virus was present as an SNPV. However, in the T. ni cells it had an MNPV phenotype (45). Therefore this phenomenon could be influenced by physiology of the cell, or how the cell responds to viral infection. As virion formation begins, there are likely to be few virions that are widely dispersed and therefore the MNPV type may not be present because nucleocapsid aggregates are not formed. This results in the production of BV that are SNPVs in both MNPV and SNPV type viruses. Therefore, all baculovirus have an SNPV stage. Later in infection when replication and virion formation is amplified, with MNPVs the nucleocapsids are assembled in close proximity and something such as gp41 might act as glue to stick them together so that when the envelope begins to form they are co-enveloped. Anything that reduces the nucleocapsid concentration, such as reduced DNA replication caused by an altered DNA polymerase or unknown components of the cell and how they interact with the virus types, might influence whether the virus is predominantly an SNPV or MNPV.

Despite agreement that the MNPV and SNPV designation is not a useful taxonomical trait, it continues to be employed, in part for historical continuity, and also because it can be a convenient method for distinguishing different viruses that are pathogenic for the same host, e.g., OpMNPV and OpSNPV which both infect Orgyia pseudotsugata (Figure 3), but are members of Group I and II, respectively.

### Gene content and organization

Although there are major differences in the sizes of baculovirus genomes, a few patterns are evident (Table 4). The viruses of members of the Hymenoptera contain the smallest genomes at a little over 80 kb. In contrast, the GV genomes vary from 101 kb (PlxyGV) up to 178 kb (XecnGV). Group I NPVs cluster around 130 kb, whereas Group II show a much higher degree of diversity, varying from about 130 to almost 170 kb. The small size of the hymenopteran NPV genomes might be attributed to a restricted life cycle confined to replication in insect gut cells (46). Consequently, unlike other baculoviruses that cause systemic infections, genes required for spread throughout the insect, where the virus encounters and replicates in a variety of tissues, might not be necessary. In contrast, the large size of a Group II NPV (LdMNPV), which at 161 kb is about 30 kb larger than many other NPV genomes, can be attributed to a combination of repetitive genes (16 bro [baculovirus repeated orf] genes) that add about half of the additional 30 kb, while genes not found in smaller genomes add most of the remainder. These additional genes encode ribonucleotide reductase subunits and two enhancin genes (47). In other viruses with large genomes (e.g., XecnGV), repeated genes including 10 bro and 4 enhancin genes, comprise up to 17% (30 kb) of the genome (48). Despite the large difference in gene content in GV genomes as reflected in their size range, their genomes are surprisingly collinear (49). In contrast, NPVs even from the same order (Lepidoptera) show a high degree of variation (50).

### Regulatory content: homologous regions (Hrs)

In addition to containing a set of genes encoding proteins required for productive infection, most baculovirus genomes also contain homologous repeated regions. In AcMNPV, hrs are comprised of repeated units of about 70-bp with an imperfect 30-bp palindrome near their center. Hrs are repeated at eight locations in the genome with 2 to 8 repeats at each site (see Chapter 4). They are highly variable, and although they are closely related within a genome, they may show very limited homology between different viruses. For example, in the CpGV genome, tandem repeated sequences are not evident, although a 75-bp imperfect palindrome is present at 13 different locations on the genome (51). In addition, in the TnSNPV (group II) sequence, hrs were not found (52). Hrs have been implicated as both transcriptional enhancers and origins of DNA replication for some baculoviruses (53-58).

### Conservation of baculovirus genes: core genes

Despite the diversity in gene content present in different baculovirus genomes, a set of about 37 genes that are present in all sequenced baculovirus genomes has been identified (Table 5). Six of these genes were recently discovered by careful comparison of genes from all sequenced baculovirus genomes (59) (60) and there may be more present as it is possible that many shared genes have diverged to such an extent that their relatedness cannot be readily determined. This is particularly true of the dipteran virus that is most distant from the baculoviruses of Lepidoptera and Hymenoptera. Of the conserved genes, about half are virion-associated proteins that are involved in capsid structure, the occlusion-derived virus envelope, and larval infectivity. Most of the others are related to DNA replication or processing, and late or very late transcription. Despite this limited set of genes that baculoviruses share, they do provide insight into some of the major functions required of all baculoviruses such as a common virion structure, the necessity to infect gut cells, and the use of a novel polymerase for the expression of late genes. Furthermore, there are sets of genes specific to, and conserved in, each clade of viruses such as gp64 in Group I NPVs and a number of GV-specific genes (see below). These genes likely reflect major recombination events that altered the properties of the viruses to such an extent that they subsequently developed along distinctive phylogenetic pathways. The observation that different types of NPVs and GVs and other types of DNA viruses (e.g., entomopox, ascovirus, nudivirus) have the potential to simultaneously infect the same insect indicates how via recombination, genes can be transferred between different viruses and between viruses and the host insect.

### Lepidopteran baculovirus (NPV and GV) core genes

In addition to the core genes found in all baculoviruses, lepidopteran baculoviruses encode an additional set of genes that appear to be present in all their genomes, and about half are also found in Gammabaculovirus (hymenopteran virus) genomes (Table 6). Homologs or functional analogs of many of these genes are likely present in all baculoviruses, but the relationships cannot be detected due to the extent of divergence the genes. Since they appear to be so central to the replication of the baculoviruses, the single-stranded DNA binding protein, LEF-3, and the transcriptional activator IE-1 may be examples of gene divergence which prevents their detection in the more distantly related viruses. In contrast, homologs of Ac38, an ADP-ribose phosphatase, belong to a family found in many organisms and would likely be detected outside the lepidopteran baculoviruses, if it were present. It acts as a decapping enzyme in vaccinia virus (61) and its presence suggests that the lepidopteran viruses employ molecular strategies significantly different from the other baculovirus genera. Polyhedrin appears to be an example of possible convergent evolution since the occlusion body protein of the dipteran virus appears to encode a novel protein (62).

A few genes are present in all Alphabaculoviruses but are found in some, but not all, Betabaculoviruses (33). The most well-characterized of these is Ac9 (orf1629), which is a homolog of WASP proteins that are involved in movement of the virus based on actin polymerization (see Chapter 3). This would suggest that other baculoviruses have major differences in their pathogenesis.

### Granulovirus-specific genes

In addition to their occlusion body morphology, the pathology of GV infection differs from NPVs. For example, their replication is not confined to nuclei as the nucleus and cytoplasm appear to merge during GV infections. The presence of GV specific genes may be a reflection of these differences. Granuloviruses encode a number of genes that are found in all GV genomes. Of these GV genes, 19 appear to be specific to GVs (33), whereas others, although found in all GV genomes, are also found in a few other baculoviruses. Examples of the latter are DNA ligase and helicase-2 homologs that, in addition to GV genomes, are also present in one NPV genome (LdMNPV). The helicase-2 homolog is also found in an additional NPV (Maco-B-NPV). There are other GV-specific genes that are found in most, but not all, GV genomes. The only GV specific gene that has been characterized is the XecnGV metalloproteinase. It was found to have proteinase activity and was inhibited by metalloproteinase inhibitors (63).

For additional information or the relatedness of baculovirus genes see (33, 59).

## Related viruses: the nudiviruses

In addition to baculoviruses, there are a number of viruses pathogenic for invertebrates that have large double-stranded DNA genomes. These include nudiviruses, ascoviruses, irridoviruses, and entomopox viruses. However, with the exception of nudiviruses, all these viruses replicate in the cytoplasm or exhibit a combination of both nuclear and cytoplasmic replication (ascoviruses) (reviewed in (64)). In addition, although nudiviruses are an unassigned genus of viruses, they closely resemble baculoviruses and were originally classified as non-occluded baculoviruses, although occlusion bodies have been occasionally reported (e.g., see (65) and below). Their similarity to baculoviruses includes nuclear replication and rod-shaped, enveloped nucleocapsids. They have double-strand, circular DNA genomes varying in size from 97–230 kb (14). They were removed from the Baculoviridae because they are nonoccluded. Hence the etymology of their name (latin nudi = naked, bare, uncovered), because they lack occlusion bodies. They also have a somewhat different host range than baculoviruses, having been characterized not only from Lepidoptera and Diptera (66), but also from Coleoptera (a rhinoceros beetle) and Orthoptera (a cricket) (67).

As more genome sequence data has become available, homologs of baculovirus genes have been found in many different categories of invertebrate viruses. These appear to be the result of lateral transfer, probably during co-infection of the same host (68). However, the nudiviruses share a significant number of the conserved core genes found in all baculoviruses and therefore their presence does not appear to be a result of lateral gene transfer. As shown in Table 5, nudivirus genomes contain homologs of up to 22 of the 37 core conserved baculovirus genes. These include homologs of genes encoding the novel baculovirus RNA polymerase subunits, virion structural proteins, and a set of genes required for infection of gut tissue. In addition, genes such as DNA helicase are present in many large DNA virus genomes, and LEF-8 has homology to RNA polymerase subunits from many organisms. However, homology searches group these genes from baculoviruses and nudiviruses together. Therefore, based on morphology and molecular phylogeny, these two groups of viruses clearly share membership in a distinct viral lineage.

The genome of an occluded virus of a dipteran (crane fly), Tipula oleracea was sequenced and although originally thought to be a member of the Baculoviridae, was found to be more closely related to the nudiviruses (69). Therefore, the characterization of nudiviruses as being non occluded does not appear to apply to all members of this group. The N-terminal sequence of the occlusion body protein of another Tipula virus (T. palludosa) was not related to other polyhedrin/granulin sequences (28).

## An occluded virus of pink shrimp, Penaeus monodon

An occluded baculovirus-like element pathogenic for the pink shrimp P. monodon has been described (16, 17). These viruses produce striking pyramidal-shaped occlusion bodies containing rod-shaped nucleocapsids similar in dimension and appearance to those of baculoviruses (Figure 6). Analysis of several sequences from this virus has indicated that it encodes proteins similar to the baculovirus/nudivirus lineage including LEF-5, LEF-9 and VLF-1 (14, 70) (Figure 7). Completion of the sequence of this genome should definitively clarify its phylogeny.

## Hytrosaviruses

Hytrosaviruses include the salivary gland hypertrophy viruses and have been characterized from several Diptera including the tsetse fly, the vector for sleeping sickness. They are non-occluded and contain large double-stranded DNA genomes and have a virion morphology similar in both size and appearance to baculoviruses. They appear to infect the salivary gland and although not particularly virulent, they can result in a significant reduction in reproductive fitness (71). Genomes of several hytrosaviruses have been sequenced and have been found to encode homologs of four baculovirus/nudivirus genes involved in per os infectivity including pifs 1-3 and p74 (14). In addition, they also appear to encode orthologs of baculovirus RNA polymerase subunits including LEF-4, -8, -9, but not p47 along with LEF-5 and VLF-1 (72), suggesting that they belong to the baculovirus/nudivirus lineage.

## A polydnavirus connection

Polydnaviruses are not true viruses because they do not contain genetic material for their own replication. They are produced in the ovaries of parasitic wasps, and the virion-like particles contain genetic material from the wasp and are injected into host lepidopteran larvae along with the wasp eggs. They are named because they contain multiple circular double-stranded DNA molecules ([underlined: poly]dispersed [underlined: DNA]) encompassing up to 560 kb that encode gene products that compromise the target host immune system and other processes and are essential for the successful development of the wasp egg. There are two lineages of parasitic wasps that employ these elements; the braconid and ichneumonids, producing bracovirus and ichnovirus polydnavirus elements, respectively. When cDNAs produced from RNA associated with polydnavirus production in braconid ovaries were analyzed, a number were found to exhibit sequence homology to genes encoded by nudiviruses and baculoviruses (73, 74). Additional such genes were identified by deep sequencing (75) (Figure 5). The genes identified included per os infectivity factors that are involved in infection of mid-gut cells by baculoviruses. Another group of factors are related to subunits of the baculovirus RNA polymerase and a very late transcription factor, VLF-1. When the structural proteins of the polydnavirus virions were analyzed, proteins related to per os infectivity factors were also identified. The presence of homologs of these factors suggests that they may be involved in a similar role to that played in baculoviruses by delivering the bracovirus DNA into cells of the parasitized larvae. The knockdown using RNAi of the expression of the lef-9 and lef-4 subunits of the RNA polymerase in female wasps, reduced both the levels of vp39 and p74 transcripts and also the amount packaged DNA suggesting that the baculovirus-like RNA polymerase may be expressed by the wasp and was involved in expressing structural proteins involved in packaging polydnavirus genomes. Likewise, the knockdown of orthologs of per os infectivity factors (p74 and PIF-1) resulted in a reduction in host cells that incorporated a polydnavirus gene, suggesting these factors were involved in cell entry similar to their role in baculovirus infectivity (76). These data suggest that a parasitic wasp was infected by a nudivirus and all or part of the nudivirus genome was incorporated into the wasp genome. Some of these genes are used for the expression of polydnavirus proteins involved in packaging of the polydnavirus DNA, thereby facilitating their transmission into the host larvae.

A similar analysis of an ichnovirus found that polydnavirion-associated proteins did not show relatedness to known proteins. However, because the genes encoding these products were found clustered in specific locations and are amplified along with the DNA that is packaged in the ichnovirus virions, it was suggested that they are derived from a hitherto unknown virus that integrated into the host genome similar to the nudivirus-like element that is present in the genomes of braconid wasps (77).

A phylogenetic tree of VLF-1 from representative baculovirus, nudivirus, polydnavirus (bracovirus) host (Cotesia inanitus), and two nudiviruses is shown in Figure 7. Although there appear to be two distinct lineages with the baculovirus comprising one and the other including the nudiviruses, shrimp virus, and bracovirus host (Cotesia), the latter branch is not well supported, and therefore, it is difficult to draw conclusions regarding the relationships of the non-baculovirus lineages.

## A Whispovirus

The genus Whispovirus includes the white spot syndrome virus (WSSV) that causes severe disease outbreaks in cultured penaeid shrimp, particularly in Asia. It is the only member of the Nimaviridae. It is a non-occluded, enveloped, rod-shaped virus with a double-stranded DNA genome of up to 300 kb. It is a highly virulent virus and causes major tissue damage; the infection results in white spots of calcium deposited in the shell (78). Although the genome of WSSV encodes homologs of four baculovirus/nudivirus genes involved in per os infectivity including pifs 1-3 and p74 (14), it is unclear if this represents a direct phylogenetic relatedness to the baculovirus/nudivirus lineage, or whether this is an example of a set of genes important in oral infectivity that was transferred between viruses. The lack of RNA polymerase subunits suggests that their molecular biology may be significantly different from the baculovirus/nudivirus lineage.

## Related References

1 Aoki, D., E. Owashi, and S. Yazaki, Ukiyoe VR-Museum. 2001. http://www.biblio.tuat.ac.jp/vr-museum/ukiyoeEng.htm.
2 Steinhaus, E.A., Disease in a minor chord. 1975, Columbus, Ohio: Ohio State University Press. 488.
3 Bergold G.H. (1947). Die isolierung des polyeder-virus and die natur der polyeder. Z. Naturforsch.
4 Xeros N. (1952). Cytoplasmic polyhedral virus diseases. Nature.
5 Paillot A. (1926). Sur une nouvelle maladie du noyau au grasserie des chenilles de P. brassicae et un nouveau groupe de microoganismes parasites. Compt. Rend.
6 Vago C., et al. (1974). Editorial: Present status of the nomenclature and classification of invertebrate viruses. J Invertebr Pathol.
7 Podgwaite, J.D., Natural disease within dense gypsy moth populations, in The Gypsy Moth: Research Towards Integrated Pest Management, C.C. Doane and M.L. McManus, Editors. 1981, U.S. Dept. of Agriculture: Washington, D.C.
8 Thompson, C.G., Nuclear polyhedrosis epizootiology, in The Douglas-fir tussock moth: a synthesis, M.H. Brookes, R.W. Stark, and R.W. Campbell, Editors. 1978, U.S. Department of Agriculture: Washington, D.C.
9 Heimpel A.M., et al. (1973). The presence of nuclear polyhedrosis virus of Trichoplusia ni on cabbage from the market shelf. Environ. Entomol.
10 Akermann H.-W., Smirnoff W.A. (1983). A morphological investigation of 23 baculoviruses. J. Invertebr. Pathol.
11 Federici, B.A., Ultrastructure of baculoviruses, in The biology of baculoviruses, R.R. Granados and B.A. Federici, Editors. 1986, CRC Press: Boca Raton. p. 61-88.
12 Entwistle P.F., Adams P.H., Evans H.F. (1978). Epizootiology of a nuclear polyhedrosis virus in European spruce sawfly (Gilpinia hercyniae): the rate of passage of infective virus through the gut of birds during cage tests. J Invertebr Pathol.
13 Hostetter, D.L. and M.R. Bell, Natural dispersal of baculoviruses in the envirionment, in Virol Insecticides for biological control, K. Maramorosch and K.E. Sherman, Editors. 1985, Academic Press. p. 249-284.
14 Wang Y., Jehle J.A. (2009). Nudiviruses and other large, double-stranded circular DNA viruses of invertebrates: New insights on an old topic. J Invertebr Pathol.
15 Hall D.W., Hazard E.I. (1973). A nuclear polyhedrosis virus of a caddisfly, Neophylax sp. J. Invertebr. Pathol.
16 Couch J.A. (1974). An enzootic nuclear polyhedrosis virus of pink shrimp: ultrastructure, prevalence, and enhancement. J. Invertebrate Pathol.
17 Couch J.A. (1974). Free and occluded virus, similar to Baculovirus, in hepatopancreas of pink shrimp. Nature.
18 Larsson R. (1984). Insect pathological investigations on Swedish Thysaura: A nuclear polyhedrosis virus of the bristletail Dilta hibernica. J. Invertebr. Pathol.
19 Henry J.E., Jutila J.W. (1966). The isolation of a polyhedrosis virus from a a grasshopper. J. Invertebr. Pathol.
20 Wang Y., et al. (2008). Sequencing of the large dsDNA genome of Oryctes rhinoceros nudivirus using multiple displacement amplification of nanogram amounts of virus DNA. J Virol Methods.
21 Ryel R.B., Cline G.B. (1970). Isolation and characterization of a nuclear polyhedral inclusion body from the boll weevil, Athonomas grandis. J. Alabama Acad. Sci.
22 Smith K.M., Hills G.J., Rivers C.F. (1959). Polyhedroses in neuropterous insects. J. Insect Pathol.
23 Martignoni, M.E. and P.J. Iwai, A catalog of viral diseases of insects, mites, and ticks. Fourth ed. 1986: USDA Forest Service PNW-195.
24 Theze J., et al. (2011). Paleozoic origin of insect large dsDNA viruses. Proc Natl Acad Sci U S A.
25 Wu G.A., et al. (2009). Whole-proteome phylogeny of large dsDNA virus families by an alignment-free method. Proc Natl Acad Sci U S A.
26 Jehle J.A., et al. (2006). On the classification and nomenclature of baculoviruses: a proposal for revision. Arch Virol.
27 Soeda E., et al. (1980). Host-dependent evolution of three papova viruses. Nature.
28 Rohrmann G., et al. (1981). N-terminal polyhedrin sequences and occluded Baculovirus evolution. J Mol Evol.
29 Herniou E.A., et al. (2004). Ancient coevolution of baculoviruses and their insect hosts. J. Virol.
30 Bideshi D.K., Bigot Y., Federici B.A. (2000). Molecular characterization and phylogenetic analysis of the Harrisina brillians granulovirus granulin gene. Arch Virol.
31 Zanotto P., Kessing B., Maruniak J. (1993). Phylogenetic interrelationships among baculoviruses: evolutionary rates and host associations. J Invertebr Pathol.
32 Pearson M.N., Rohrmann G.F. (2002). Transfer, incorporation, and substitution of envelope fusion proteins among members of the Baculoviridae, Orthomyxoviridae, and Metaviridae (insect retrovirus) families. J. Virol.
33 Miele S.A., et al. (2011). Baculovirus: molecular insights on their diversity and conservation. Int J Evol Biol.
34 Herniou E.A., et al. (2001). Use of whole genome sequence data to infer baculovirus phylogeny. J Virol.
35 Jiang Y., et al. (2009). Evidence of a major role of GP64 in group I alphabaculovirus evolution. Virus Res.
36 Jehle J.A., et al. (2006). Molecular identification and phylogenetic analysis of baculoviruses from Lepidoptera. Virology.
37 Hughes K.M., Addison R.B. (1970). Two nuclear polyhedrosis viruses of the Douglas-fir tussock moth. J. Invertebr. Pathol.
38 Falcon L.A., Hess R.T. (1985). Electron microscope observations of multiple occluded virions in the granulosis virus of the codling moth, Cydia pomonella. J. Invertebr. Pathol.
39 Hukuhara, T. Genetic variation of polyhedrosis viruses of insects. in Proc. Jount U.S.-Japan Seminar on microbial control of insects pests. 1967. Fukuoka.
40 Yu I.L., et al. (2009). Autographa californica multiple nucleopolyhedrovirus ORF 23 null mutant produces occlusion-derived virions with fewer nucleocapsids. J Gen Virol.
41 Braunagel S.C., et al. (2003). Determination of the protein composition of the occlusion-derived virus of Autographa californica nucleopolyhedrovirus. Proc Natl Acad Sci U S A.
42 Pearson M.N., Russell R., Rohrmann G.F. (2001). Characterization of a baculovirus encoded protein that is associated with infected-cell membranes and budded virions. Virology.
43 Wu W., Passarelli A.L. (2010). Autographa californica M nucleopolyhedrovirus Ac92 (ORF92, P33) is required for budded virus production and multiply-enveloped occlusion-derived virus formation. J. Virol.
44 Feng G., et al. (2012). Selection and Characterization of Autographa californica Multiple Nucleopolyhedrovirus (AcMNPV) DNA Polymerase Mutations. J Virol.
45 Xu Y.P., et al. (2012). A baculovirus isolated from the wild silkworm encompasses the host ranges of Bombyx mori NPV and Autographa californica MNPV in cultured cells. J Gen Virol.
46 Lauzon H.A., et al. (2006). Genomic comparison of Neodiprion sertifer and Neodiprion lecontei nucleopolyhedroviruses and identification of potential hymenopteran baculovirus-specific open reading frames. J Gen Virol.
47 Kuzio J., et al. (1999). Sequence and analysis of the genome of a baculovirus pathogenic for Lymantria dispar. Virology.
48 Hayakawa T., et al. (1999). Sequence analysis of the Xestia c-nigrum granulovirus genome. Virology.
49 Lange M., Jehle J.A. (2003). The genome of the Cryptophlebia leucotreta granulovirus. Virology.
50 Hayakawa T., Rohrmann G.F., Hashimoto Y. (2000). Patterns of genome organization and content in lepidopteran baculoviruses. Virology.
51 Luque T., et al. (2001). The complete sequence of the Cydia pomonella granulovirus genome. J Gen Virol.
52 Willis L.G., et al. (2005). Sequence analysis of the complete genome of Trichoplusia ni single nucleopolyhedrovirus and the identification of a baculoviral photolyase gene. Virology.
53 Guarino L.A., Gonzalez M.A., Summers M.D. (1986). Complete sequence and enhancer function of the homologous DNA regions of Autographa californica nuclear polyhedrosis virus. J. Virol.
54 Guarino L.A., Summers M.D. (1986). Interspersed homologous DNA of Autographa californica nuclear polyhedrosis virus enhances delayed-early gene expression. J. Virol.
55 Leisy D.J., Rohrmann G.F. (1993). Characterization of the replication of plasmids containing hr sequences in baculovirus-infected Spodoptera frugiperda cells. Virology.
56 Pearson M.N., et al. (1992). The Autographa californica baculovirus genome: Evidence for multiple replication origins. Science.
57 Pearson M.N., et al. (1993). Identification and characterization of a putative origin of DNA replication in the genome of a baculovirus pathogenic for Orgyia pseudotsugata. Virology.
58 Pearson M.N., Rohrmann G.F. (1995). Lymantria dispar nuclear polyhedrosis virus homologous regions: characterization of their ability to function as replication origins. J. Virol.
59 Garavaglia M.J., et al. (2012). Ac53, ac78, ac101 and ac103 are newly discovered core genes in the family Baculoviridae. J Virol.
60 Yuan M., et al. (2011). Identification of Autographa californica nucleopolyhedrovirus ac93 as a core gene and its requirement for intranuclear microvesicle formation and nuclear egress of nucleocapsids. J Virol.
61 Parrish S., Resch W., Moss B. (2007). Vaccinia virus D10 protein has mRNA decapping activity, providing a mechanism for control of host and viral gene expression. Proc Natl Acad Sci U S A.
62 Perera O., et al. (2007). Proteins associated with Culex nigripalpus nucleopolyhedrovirus occluded virions. J Virol.
63 Ko R., Okano K., Maeda S. (2000). Structural and functional analysis of the Xestia c-nigrum granulovirus matrix metalloproteinase. J Virol.
64 Cheng X., et al. (2007). Ascovirus and its evolution. Virolog. Sinica.
65 Huger, A.M. and A. Krieg, Baculoviridae: Nonoccluded Baculovirus, in Atlas of Invertebrate Viruses, J.R. Adams and J.R. Bonami, Editors. 1991, CRC Press, Inc.: Boca Raton. p. 287-319.
66 Unckless R.L. (2011). A DNA virus of Drosophila. PLoS One.
67 Wang Y., et al. (2007). The genome of Gryllus bimaculatus nudivirus indicates an ancient diversification of baculovirus-related nonoccluded nudiviruses of insects. J Virol.
68 Iyer L.M., et al. (2006). Evolutionary genomics of nucleo-cytoplasmic large DNA viruses. Virus Res.
69 Bezier, A., et al., Nucleopolyhedrovirus causing virus from the crane fly Tipula oleracea, in 45th annual meeting of the Society for invertebrate pathology. . 2012: Buenos Aires, Argentina.
70 Mari J., et al. (1993). Preliminary characterization and partial cloning of the genome of a baculovirus from Penaeus monodon (PmSNPV=MBV). Dis. Aquat. Org.
71 Abd-Alla A.M., et al. (2009). Hytrosaviridae: a proposal for classification and nomenclature of a new insect virus family. Arch Virol.
72 Jehle J.A., Abd-Alla A.M., Wang Y. (2012). Phylogeny and evolution of Hytrosaviridae. J Invertebr Pathol.
73 Bezier A., et al. (2009). Polydnaviruses of braconid wasps derive from an ancestral nudivirus. Science.
74 Bezier A., et al. (2009). Polydnavirus hidden face: the genes producing virus particles of parasitic wasps. J Invertebr Pathol.
75 Burke G.R., Strand M.R. (2012). Deep sequencing identifies viral and wasp genes with potential roles in replication of Microplitis demolitor Bracovirus. J Virol.
76 Burke G.R., et al. (2013). Mutualistic polydnaviruses share essential replication gene functions with pathogenic ancestors. PLoS Pathog.
77 Volkoff A.N., et al. (2010). Analysis of virion structural components reveals vestiges of the ancestral ichnovirus genome. PLoS Pathog.
78 Leu J.H., et al. (2009). Whispovirus. Curr Top Microbiol Immunol.
79 Volkman L.E., Summers M.D. (1975). Nuclear polyhedrosis virus detection: relative capabilities of clones developed from Trichoplusia ni ovarian cell line TN-368 to serve as indicator cells in a plaque assay. J Virol.
80 Arnott H.J., Smith K.M. (1967). An ultrastructural study of the development of a granulosis virus in the cells of the moth Plodia interpunctella (Hbn.). J Ultrastruct Res.
81 Hyink O., et al. (2002). Whole genome analysis of the Epiphyas postvittana nucleopolyhedrovirus. J Gen Virol.
82 Fan Q., et al. (2007). The genome sequence of the multinucleocapsid nucleopolyhedrovirus of the Chinese oak silkworm Antheraea pernyi. Virology.
83 Ayres M.D., et al. (1994). The complete DNA sequence of Autographa californica nuclear polyhedrosis virus. Virology.
84 Nakai M., et al. (2003). Genome sequence and organization of a nucleopolyhedrovirus isolated from the smaller tea tortrix, Adoxophyes honmai. Virology.
85 Ijkel W.F.J., et al. (1999). Sequence and organization of the Spodoptera exigua multicapsid nucleopolyhedrovirus genome. J. Gen. Virol.
86 Jakubowska A.K., et al. (2006). Genome sequence of an enhancin gene-rich nucleopolyhedrovirus (NPV) from Agrotis segetum: collinearity with Spodoptera exigua multiple NPV. J Gen Virol.
87 Xiao H., Qi Y. (2007). Genome sequence of Leucania seperata nucleopolyhedrovirus. Virus Genes.
88 Wormleaton S., Kuzio J., Winstanley D. (2003). The complete sequence of the Adoxophyes orana granulovirus genome. Virology.
89 Lauzon H.A., et al. (2005). Gene organization and sequencing of the Choristoneura fumiferana defective nucleopolyhedrovirus genome. J Gen Virol.
90 Duffy S.P., et al. (2006). Sequence analysis and organization of the Neodiprion abietis nucleopolyhedrovirus genome. J Virol.
91 Garcia-Maruniak A., et al. (2004). Sequence analysis of the genome of the Neodiprion sertifer nucleopolyhedrovirus. J Virol.
92 Afonso C.L., et al. (2001). Genome sequence of a baculovirus pathogenic for Culex nigripalpus. J Virol.

Figure 1.

Baculovirus occlusion bodies. Scanning EM by K. Hughes and R. B. Addison.

Figure 2.

Comparison of cells infected with a cypovirus (CPV – Reoviridae) and a baculovirus. Left panel: CPV of Orgyia pseudotsugata. Photo by G. S. Beaudreau. Right Panel: AcMNPV infected T. ni cells. From Volkman and Summers (79).

Figure 3.

Two nucleopolyhedroviruses pathogenic for Orgyia pseudotsugata showing single (top panel) and multiple (bottom panel) nucleocapsids/envelope. Top panel: OpSNPV. Bottom panel: OpMNPV. From Hughes and Addison (37).

Figure 4.

Cross section of a granulovirus of Plodia interpunctella. From Arnott and Smith (80).

Figure 5.

Phylogenetic relatedness of LEF8 from selected baculoviruses. Neighbor joining; bootstrap analysis (1000 reps).

Figure 6.

Polyhedral inclusion body of a virus of the pink shrimp, Penaeus monodon. Arrows indicated nucleocapsids. From Couch (16).

Figure 7.

Phylogenetic relatedness of VLF-1 from selected viruses and a braconid wasp. Neighbor joining Best Tree; Numbers in bold indicate Bootstrap values (1000 reps) over 50%. Abbreviations: PemoNPV, Penaeus monodon (shrimp); Cotesia inanitus (braconid wasp); Hz1NV and OrNV, nudiviruses.

Table 4.

Genome size and predicted ORF content* of selected baculoviruses

Virus type | Name of Virus | Size (kb) | Orfs (>50 aa)
Group I (13 members)** | EppoMNPV (81) | 119 | 136
| AnpeNPV (82) | 126 | 145
| AcMNPV (83) | 134 | ~150
Group II (20 members) | AdhoNPV (84) | 113 | 125
| SeMNPV(85) | 136 | 139
| AgseNPV (86) | 148 | 153
| LdMNPV(47) | 161 | 163
| LeseNPV (87) | 168 | 169
GV (12 members) | AdorGV (88) | 100 | 119
| CrleGV (49) | 111 | 124
| CpGV (51) | 124 | 143
| XecnGV (48) | 179 | 181
Hymenopt. NPV (3 members) | NeleNPV (89) | 82 | 89
| NeabNPV (90) | 84 | 93
| NeseNPV (91) | 86 | 90
Dipteran NPV (1 member) | CuniNPV (92) | 108 | 109

* Selected from over 50 genome sequences (2010)

**The numbers in brackets indicate the total number of genomes in the category.

Table 5.

Conserved genes^1^ in baculoviruses, nudiviruses, hytrosaviruses, and polydnaviruses

Conserved in baculoviruses | Conserved in Nudiviruses | Conserved in Hytrosaviruses | Present in polydnavirus (bracovirus)
DNA Replication/processing
Ac6 Lef2 primase assoc.
Ac14 Lef1 primase
Ac65 DNA polymerase | + | + | +
Ac95 DNA helicase | + | +
Ac133 Alkaline nuclease
Transcription/RNA polymerase
Ac50 LEF-8 | + | + | +
Ac62 LEF9 | + | + | +
Ac40 p47 | + | | +
Ac90 LEF-4 | + | | +
Ac77 VLF-1 | + | | +
Ac99 LEF-5 | + | + | +
Structure
Ac54 vp1054 | +
Ac66
Ac80 gp41 tegument | +
Ac83 VP91 | + | | +
Ac89 VP39 capsid | + | | +
Ac100 p6.9
Ac94 ODV-E25
Ac109 | | | +
Ac142
Ac143 odv-E18 | | | +
Ac144
Per os infectivity factors/ODV structure
Ac22 PIF2 | + | + | +
Ac68 PIF6 | + | | +
Ac96 PIF4 | + | | +
Ac115 PIF-3 | + | + | +
Ac119 PIF-1 | + | + | +
Ac138 p74 (PIF-0) | + | + | +
Ac148 odv-e56 (pIF 5) | + | | +
Predicted Enzymes
Ac53 ubiquitin ligase | + | +
Ac92 sulfhydryl oxidase | + | +
Ac98 38K phosphatase | + | | +
Other
Ac78
Ac81 | +
Ac93
Ac101
Ac103

^1^ For more details see Chapter 12

Table 6.

Additional Core genes present in all Lepidopteran (Alpha- and Beta-) and some Gammabaculoviruses

AcMNPV orf | Name/function | Presence in Gamma-
Ac8 | polyhedrin | _+_
Ac10 | pk-1
Ac13
Ac23 | related to fusion; F protein
Ac25 | DNA binding protein, dbp | _+_
Ac28 | lef-6
Ac29
Ac32 | fgf
Ac36 | Pp31/39K
Ac37 | LEF-11 | _+_
Ac46 | Odv-E66
Ac38 | ADP-ribose phosphatase, nudix
Ac53a | LEF-10
Ac61 | Few polyhedra, fp
Ac67 | LEF-3
Ac75 | | _+_
Ac76 | | _+_
Ac82 | Telokin-like
Ac102
Ac106/107 | | _+_
Ac110
Ac139 | ME53
Ac145 | | _+_
Ac146 | Ie-1
Ac147 | Ie-0