# Medicare Part D Enrollee Vaccine Use After Elimination of Cost Sharing for Recommended Vaccines in 2023

Data Point

Effective January 1, 2023, the Inflation Reduction Act (IRA) eliminated cost sharing and deductibles for adult vaccines recommended by the Advisory Committee on Immunization Practices (ACIP) covered under Medicare Part D. In 2023, 10.3 million Medicare Part D enrollees received a recommended vaccine free of charge, which saved enrollees more than $400 million in out-of-pocket costs. The majority of those enrollees who received vaccines did so for the prevention of respiratory syncytial virus (RSV), followed by shingles.

Effective January 1, 2023, the Inflation Reduction Act (IRA) eliminated cost sharing and deductibles for adult vaccines recommended by the Advisory Committee on Immunization Practices (ACIP) covered under Medicare Part D. In 2023, 10.3 million Medicare Part D enrollees received a recommended vaccine free of charge, which saved enrollees more than $400 million in out-of-pocket costs.

## KEY POINTS

- The IRA established that, effective January 1, 2023, o deductible or cost sharing shall apply for adult vaccines recommended by ACIP and covered under Medicare Part D.
- Our findings show that in 2023, 10.3 million Medicare Part D enrollees received a recommended Part D covered vaccine with no cost sharing, which represents about 20 percent of the total Part D population.
- Among enrollees who received at least one Part D covered vaccine at no cost, the majority received the respiratory syncytial virus (RSV) vaccine (63 percent), followed by the shingles vaccine (38 percent) and the Tdap vaccine (14 percent), which protects against tetanus, diphtheria, and pertussis.
- If the IRA vaccine provision had not been in effect, enrollees who received vaccines with no cost sharing in 2023 would have paid approximately $400 million in out-of-pocket costs for these vaccines * in 2023 (excluding the new RSV vaccine). ^†^
- In 2021, 3.4 million people received vaccines, most of which were for shingles (2.7 million), under Part D and paid a total of $234 million in out-of-pocket costs for these vaccines. In 2023, 3.9 million enrollees received a shingles vaccine, which is an increase of about 42 percent from 2021.^‡^
- Nearly 1.5 million enrollees received the Tdap vaccine in 2023, which is an increase of about 114 percent from 2021.
- In 2023, 6.5 million enrollees received the recently licensed RSV vaccine free of charge under the IRA’s vaccine provision.
- Estimates show that California, Florida, and Texas had the highest absolute number of enrollees who received a vaccine under Part D with no cost sharing.
- Colorado, Nebraska, and Washington had the highest share of enrollees accessing a Part D covered vaccine with no cost sharing at 27 percent each.

## BACKGROUND

Vaccines help to reduce the spread of disease, prevent serious illness, and limit severe health complications. Access to vaccines for older Americans, most of whom are covered by Medicare, is particularly important because changes in the immune system in older age can increase susceptibility to infectious diseases and increase the risk of more severe infections.^1^ In 2023, about 51.9 million Medicare beneficiaries were enrolled in Medicare Part D, with the majority (88 percent) of enrollees ages 65 or older.

Vaccines covered under Medicare Part D include all commercially available vaccines not covered under Medicare Part B. * Part D coverage includes vaccines to protect against respiratory syncytial virus (RSV), shingles, tetanus, diphtheria, pertussis, and other infectious diseases. Unlike vaccines covered under Part B, which include vaccines for COVID-19, influenza, and pneumonia, Part D vaccine coverage historically could include cost sharing requirements. ^†^ However, as of January 1, 2023, the Inflation Reduction Act (IRA) established that no deductible or cost sharing shall apply for enrollees receiving Part D covered adult vaccines recommended by the Advisory Committee on Immunization Practices (ACIP). ^2^ Appendix Table A1 presents a description of the infectious diseases and ACIP recommendations for older adults for the more commonly used vaccines covered under Part D.

In this Data Point, we examine the use of all vaccines covered under Medicare Part D with no cost sharing in 2023, after the IRA vaccine provision eliminated out-of-pocket spending for ACIP-recommended adult vaccines. We pay particular attention to two of the more commonly received Part D covered vaccines —vaccines for RSV and for shingles (which is also known as herpes-zoster). RSV vaccines are new, licensed by the Food and Drug Administration (FDA) in May 2023 and recommended for adults 60 and older by ACIP in June 2023.^‡,3,4^ The Centers for Disease Control and Prevention (CDC) reports that there are up to 160,000 RSV-related hospitalizations and up to 10,000 deaths among older adults due to RSV annually in the United States. ^5^ The direct medical costs of RSV infections range from about $1.7 billion to $3.4 billion among adults ages 60 and older in the United States. ^6^ For shingles, researchers project that among an unvaccinated population, there would be about 1.1 million cases annually, resulting in about $2.4 billion in direct medical spending in the United States. ^7,8^

Existing research finds that vaccine uptake is generally low for adults. Analysis using the National Health Interview Survey (NHIS) shows that less than half of all adults (<45 percent) received age-appropriate recommended vaccines. ^9^ In 2021, shingles vaccination rates were about 41 percent among adults ages 60 and older. ^10,11^ Many factors impact vaccine use, including out-of-pocket costs, which have been identified as a key barrier to vaccine uptake. ^12,13^ Other factors include awareness of vaccine recommendations, access to a primary care physician, access to a routine source of medical care, and other sociodemographic and economic factors. ^14,15^ A previous ASPE study found that 3.4 million Medicare enrollees received a Part D covered vaccine in 2021, however, this was prior to the availability of the RSV vaccine and prior to the IRA’s elimination of cost sharing for certain Part D covered vaccines.^*^,^16^ Both of these factors contributed to the higher 2023 utilization reported in this Data Point.

## METHODS

ASPE worked with the Centers for Medicare & Medicaid Services (CMS) Office of Enterprise Data & Analytics (OEDA) to examine the use of vaccines under Medicare Part D in calendar year 2023. We used the Part D Prescription Drug Event (PDE) files to identify enrollees who received a Part D covered vaccine in 2023 with no cost sharing. National Drug Code (NDC)-11 codes were used to identify each vaccine.

We examined use of vaccines separately depending on whether enrollees receive the Low Income Subsidy (LIS), also referred to as Extra Help. ^†^ Prior to the IRA, enrollees who did not receive LIS had higher out-of-pocket spending for Part D covered vaccines than they do now. Previous ASPE analyses found that non-LIS enrollees paid about $86 on average for Part D covered vaccines in 2021 while LIS enrollees paid about $6 on average for the same vaccines. ^17^ With the IRA’s elimination of cost sharing for Part D covered, ACIP-recommended adult vaccines going into effect in 2023, we would expect an increase in the number of enrollees, especially non-LIS, receiving Part D vaccines.

We present estimates separately for the following vaccines: RSV, shingles, Td, and Tdap. Estimates for the remainder of Part D vaccines are presented as “Others” and include, for example, vaccines for Hepatitis A, Hepatitis B, measles, mumps, rubella (MMR) and other commercially available vaccines that are not covered under Part B but are determined to be reasonable and necessary under the Medicare statute (including vaccines recommended for international travel). We examined demographic characteristics for everyone who received a Part D covered vaccine with no cost sharing overall and for the two more common vaccines: RSV and shingles. We examined the state or territory of residence for enrollees who received any Part D covered vaccine in 2023 with no cost sharing.

There are several limitations of our analyses. First, the estimates presented in this Data Point do not represent rates of vaccine coverage for the Medicare Part D population because our analyses do not capture enrollees who received a Part D covered vaccine prior to 2023. It is possible, for example, that some enrollees obtained the vaccine at the age they first become eligible, in some cases before they enrolled in Medicare (for instance, shingles vaccination is recommended starting at age 50). If so, their vaccine use would only be included in our analyses if they became eligible for and received the Part D covered vaccine in 2023. This limitation does not apply to the RSV vaccine because it became available for the first time in 2023. Second, our estimates do not disentangle how different factors such as income, race or ethnicity, institutional setting, and age contribute to differences in vaccine use. Existing research shows that cost sharing is one factor among other determinants, such as trust in vaccines, access to health care, and awareness of vaccine recommendations, that shape whether individuals obtain a recommended vaccine. ^18,19^ Finally, if an enrollee received a vaccine that was not paid for by Medicare, it would not be included in our estimates. For example, if an enrollee received a Part D covered vaccine in an institutional setting and there was no separate Part D claim for the vaccine because it was bundled with other services, it would not be included in our estimates. This would lead to an undercount of vaccine use.

## FINDINGS

Our findings show that overall, 10.3 million enrollees received a Part D covered vaccine in 2023 with no out-of pocket costs (Table 1), representing about 20 percent of the total Part D population. The majority of these enrollees received a vaccine for RSV (63 percent), followed by shingles (38 percent), followed by Tdap and Td (about 15 percent combined) (Figure 1). The remaining enrollees received other Part D covered vaccines, such as for Hepatitis A, with no cost sharing.

10.3 million Medicare Part D enrollees received a vaccine with no out-of-pocket costs under the IRA’s vaccine provision

Among LIS enrollees, 1.5 million received a vaccine, representing about 11 percent of all LIS enrollees. * The majority of these LIS enrollees received the shingles vaccine (51 percent), followed by the RSV vaccine (46 percent).

Among non-LIS enrollees, about 8.7 million received a Part D covered vaccine with no cost sharing, representing about 23 percent of all non-LIS enrollees.^†^ Among non-LIS enrollees who received a vaccine, a greater share received the RSV vaccine (67 percent), followed by the shingles vaccine (36 percent).

Table 1 Vaccine Use for Medicare Part D Enrollees by LIS Status, 2023

Vaccines | LIS Enrollees | Non-LIS Enrollees | Total Enrollees
RSV | 710,000 | 5,800,000 | 6,500,000
Shingles | 783,000 | 3,111,000 | 3,900,000
Tdap | 287,000 | 1,200,000 | 1,487,000
Td | 11,000 | 49,000 | 59,000
Other Vaccines^*^ | 64,000 | 158,000 | 221,000
Total Number of Enrollees who Received a Part D covered vaccine with no cost sharing^**^ | 1,547,000 | 8,722,000 | 10,269,000

Source: CMS OEDA analysis of the Medicare Prescription Drug Event (PDE) and Medicare enrollment data files.

Notes: This sample is restricted to enrollees who received at least one vaccine at no cost that is covered under Part D.

* Other vaccines include, for example, vaccines to protect against measles, mumps, and rubella (MMR); meningococcal disease; typhoid fever, and others, including vaccines for international travel.

** Total enrollees are those who received any Part D vaccine. The total number of enrollees counts an enrollee only once even if they received more than one vaccine.

RSV = Respiratory Syncytial Virus

Tdap = Tetanus, diphtheria, and acellular pertussis vaccine

Td = Tetanus and diphtheria vaccine

Figure 1. Share of Vaccine Use for Medicare Part D Enrollees by LIS Status, 2023

Notes: Percentages do not add up to 100 percent because some enrollees have received more than one type of vaccine. The denominator is the total number of unique enrollees for each category (total, non-LIS, and LIS) who received any Part D covered vaccine with no cost-sharing in 2023. RSV = Respiratory Syncytial Virus Td = Tetanus and diphtheria vaccine Tdap = Tetanus, diphtheria, and acellular pertussis vaccine

Figure 1 shows a table with three categories (Total, Non-LIS, and LIS) and for each category, four bars that display the percentage of people in the category that have received one of the following five types of vaccines (Td, Tdap, Shingles, RSV, or other vaccines).

### Medicare Part D Enrollee Vaccine Use by Demographic Characteristics

Next, we examined the demographic characteristics of enrollees who received a Part D covered vaccine with no cost sharing, paying specific attention to the two more common vaccines: RSV and shingles. Table 2 presents the percent of enrollees who received these vaccines among the Medicare Part D population for each demographic category in 2023. We also present demographic characteristics of all enrollees who received a Part D covered vaccine with no cost-sharing and compare them to the distribution of all Part D enrollees (Appendix Tables A2 and A3).

A higher share of enrollees over age 65 received a Part D covered vaccine, including for RSV and shingles, than their counterparts under the age of 65. This is likely driven in part by differences in ACIP vaccine recommendations for different age groups. Similar shares of men and women received a Part D covered vaccine, including RSV and shingles vaccines.

Among enrollees whose race and ethnicity information was available, Non-Hispanic White (22 percent) enrollees had the highest share of enrollees accessing a Part D covered vaccine in 2023 compared to other racial and ethnic groups, followed by Asian enrollees (21 percent). Non-Hispanic White enrollees also had higher proportions of enrollees receiving RSV and shingles vaccines than most other racial and ethnic groups, followed by Asian enrollees. Among Black and Hispanic enrollees, 13 percent and 14 percent received a Part D covered vaccine, respectively. Among both groups, about 6 percent each received the RSV vaccine. About 7 percent of Black and 8 percent of Hispanic Medicare Part D enrollees received the shingles vaccine. American Indian and Alaska Native enrollees had the lowest share accessing a Part D covered vaccine, including RSV and shingles (5 percent each), compared to other racial and ethnic groups.

Among all Part D enrollees, a higher share of non-LIS enrollees received a vaccine in 2023 (23 percent) than LIS enrollees (11 percent). Among other factors, differences in age between the two groups may be contributing to this finding. Existing research finds that about 41 percent of LIS enrollees are ages 64 or younger, which means fewer LIS enrollees are eligible for Part D vaccines due to different ACIP recommendations for younger age groups. ^20^

Generally similar shares of urban and rural enrollees received a Part D vaccine, including RSV and shingles.

Table 2 Demographic Characteristics of Enrollees Receiving Any Medicare Part D Covered Vaccine with No Cost Sharing, 2023

Demographic Characteristics | Total Medicare Part D Enrollees | Percent of Part D Enrollees Receiving Vaccines
Demographic Characteristics | Total Medicare Part D Enrollees
Demographic Characteristics | Total Medicare Part D Enrollees | Any^a^ | RSV^a^ | Shingles^a^
Age
Under 65 Years | 6,126,612 | 8% | 2% | 5%
65 Years and Older | 45,797,400 | 21% | 14% | 8%
Gender
Male | 22,559,828 | 19% | 12% | 7%
Female | 29,364,185 | 20% | 13% | 8%
Race^b^
Non-Hispanic White | 37,154,373 | 22% | 14% | 7%
Black | 5,541,317 | 13% | 6% | 7%
Hispanic | 5,406,191 | 14% | 6% | 8%
Asian/Pacific Islander | 2,038,574 | 21% | 11% | 9%
Unknown Race | 1,196,693 | 23% | 16% | 7%
Other Race | 421,551 | 21% | 13% | 8%
American Indian/Alaska Native | 165,314 | 11% | 5% | 5%
LIS Status
LIS | 14,353,221 | 11% | 5% | 5%
Non-LIS | 37,570,791 | 23% | 15% | 8%
Geographic Area
Urban | 43,173,913 | 20% | 13% | 8%
Rural or Unknown | 8,750,099 | 17% | 10% | 7%
Total | 51,924,013 | 20% | 13% | 8%

Source: CMS OEDA analysis of the Medicare Prescription Drug Event (PDE) and Medicare enrollment data files.

Notes: This sample is restricted to enrollees who received at least one vaccine at no cost that is covered under Part D.

a Denominator is total number of Part D enrollees in each demographic category.

b Race and ethnicity are identified using the Research Triangle Institute’s race variable, which is created by taking the beneficiary race code and applying an algorithm to correct for undercounting of some racial and ethnic groups.

### Part D Enrollee Vaccine Use for Each State and Territory

We also examined the number and share of enrollees receiving a Part D covered vaccine with no out-of-pocket costs by state and territory (Table 3). Our estimates show that California, Florida, and Texas had the highest absolute number of enrollees who received a vaccine under Part D with no cost sharing. Based on their total Part D enrollment, Colorado, Nebraska, and Washington had the highest share of enrollees who received a Part D covered vaccine at 27 percent each, followed by Iowa, Minnesota, and South Dakota at 26 percent each.

Table 3 Total Number of Part D Enrollees Receiving a Part D Covered Vaccine with No Cost-Sharing in 2023, by State and Territory

Area of Residence | LIS Enrollees | Non-LIS Enrollees | Total Enrollees | Share of Part D Enrollees in Each State or Territory Receiving Any Part D Covered Vaccine^a^
Alabama | 27,061 | 102,206 | 129,267 | 15%
Alaska | 1,465 | 13,619 | 15,084 | 20%
Arizona | 36,039 | 217,781 | 253,820 | 22%
Arkansas | 16,847 | 70,468 | 87,315 | 17%
California | 207,507 | 736,329 | 943,836 | 17%
Colorado | 27,339 | 185,050 | 212,389 | 27%
Connecticut | 27,308 | 102,605 | 129,913 | 22%
Delaware | 4,542 | 39,272 | 43,814 | 24%
District of Columbia | 3,578 | 7,458 | 11,036 | 18%
Florida | 95,695 | 632,519 | 728,214 | 18%
Georgia | 53,075 | 220,080 | 273,155 | 19%
Hawaii | 7,144 | 40,986 | 48,130 | 22%
Idaho | 6,498 | 51,668 | 58,166 | 20%
Illinois | 53,906 | 354,355 | 408,261 | 22%
Indiana | 33,021 | 199,960 | 232,981 | 21%
Iowa | 15,609 | 126,830 | 142,439 | 26%
Kansas | 11,842 | 97,866 | 109,708 | 25%
Kentucky | 21,560 | 113,227 | 134,787 | 17%
Louisiana | 25,793 | 79,482 | 105,275 | 14%
Maine | 11,496 | 51,939 | 63,435 | 22%
Maryland | 22,651 | 128,296 | 150,947 | 21%
Massachusetts | 42,378 | 223,122 | 265,500 | 23%
Michigan | 48,524 | 380,744 | 429,268 | 23%
Minnesota | 21,422 | 211,109 | 232,531 | 26%
Mississippi | 13,366 | 45,572 | 58,938 | 12%
Missouri | 22,769 | 168,426 | 191,195 | 18%
Montana | 4,174 | 34,828 | 39,002 | 21%
Nebraska | 7,504 | 70,217 | 77,721 | 27%
Nevada | 12,489 | 77,154 | 89,643 | 21%
New Hampshire | 4,936 | 52,804 | 57,740 | 24%
New Jersey | 27,162 | 198,603 | 225,765 | 17%
New Mexico | 16,088 | 66,643 | 82,731 | 24%
New York | 111,891 | 411,151 | 523,042 | 17%
North Carolina | 48,953 | 312,081 | 361,034 | 21%
North Dakota | 3,041 | 19,220 | 22,261 | 21%
Ohio | 50,607 | 356,053 | 406,660 | 20%
Oklahoma | 15,392 | 83,002 | 98,394 | 17%
Oregon | 20,144 | 146,256 | 166,400 | 23%
Pennsylvania | 60,264 | 389,462 | 449,726 | 19%
Rhode Island | 5,398 | 34,391 | 39,789 | 21%
South Carolina | 23,805 | 147,776 | 171,581 | 19%
South Dakota | 4,018 | 32,151 | 36,169 | 26%
Tennessee | 31,408 | 176,697 | 208,105 | 18%
Texas | 126,504 | 593,390 | 719,894 | 20%
Utah | 6,639 | 73,074 | 79,713 | 23%
Vermont | 3,282 | 27,507 | 30,789 | 24%
Virginia | 29,900 | 203,920 | 233,820 | 21%
Washington | 36,215 | 251,716 | 287,931 | 27%
West Virginia | 10,917 | 44,545 | 55,462 | 17%
Wisconsin | 23,932 | 215,773 | 239,705 | 24%
Wyoming | 1,630 | 15,117 | 16,747 | 20%
Puerto Rico | 2,246 | 85,431 | 87,677 | 13%
Virgin Islands | 14 | 870 | 884 | 8%
American Samoa | 18 | 23 | 41 | 6%
Guam | * | * | 153 | 5%
Northern Mariana Islands or Minor Outlying Islands | 0 | 19 | 19 | 5%
Unknown State | * | * | 709 | 7%
Total | 1,547,000 | 8,722,000 | 10,269,000 | 20%

Source: CMS OEDA analysis of the Medicare Prescription Drug Event (PDE) and Medicare enrollment data files.

Notes: This sample is restricted to enrollees who received at least one vaccine at no cost that is covered under Part D.

a Denominator is the total number of Part D enrollees in each state or territory.

* Value suppressed due to <11 beneficiaries receiving a Part D covered vaccine at no cost or to prevent calculation of a value <11.

## DISCUSSION

Findings show that 10.3 million enrollees received a Part D covered vaccine with no cost sharing in 2023. Previously, ASPE examined vaccine use under Part D in 2021 to understand how much enrollees would have saved in out-of-pocket costs if the IRA provisions had been in effect at that time. Our findings showed that in 2021, 3.4 million people received vaccines under Part D, most of which were for shingles (2.7 million), and paid a total of $234 million in out-of-pocket costs for these vaccines. * In 2023, 3.9 million enrollees received a shingles vaccine, which is an increase of about 42 percent from 2021, and nearly 1.5 million enrollees received a Tdap vaccine, which is an increase of 114 percent from 2021. ^†^ Note that the total number of vaccinations in 2021 may have been lower than a more typical year due to the COVID-19 pandemic.

To get a general sense of approximate savings under the IRA’s vaccine provision, we used the average out-of-pocket costs for vaccine users in 2021, updated to 2023 dollars, and applied this estimate to the total number of enrollees receiving vaccines in 2023. Based on this simple method, Part D enrollees who accessed a no cost vaccine would have spent about $300 million in out-of-pocket costs for the shingles vaccine in 2023. * For all enrollees who received vaccines in 2023, excluding the new RSV vaccine, the out-of-pocket costs would have totaled about $400 million if the IRA vaccine provision had not been in effect.

Although we cannot estimate how much enrollees would have paid for the RSV vaccine prior to the IRA if it had been available, 6.5 million enrollees received this vaccine free of charge under the IRA’s vaccine provision.^†^ The number of enrollees receiving this vaccine in under a year is likely driven both by the RSV vaccine awareness campaigns and the elimination of out-of-pocket costs associated with it, among other factors. ^21^ However, there’s concern that awareness of the availability of the vaccine is still low among older adults. ^22,23^ Given that RSV infection has the potential to be severe in older populations who have underlying health conditions, awareness of the RSV vaccine and its availability at no cost is critical to promote its uptake. Receipt of the vaccine has the potential to reduce severe complications, avoidable hospitalizations, and health spending.

Increasing the availability and accessibility of Part D covered vaccines among Medicare enrollees has numerous potential benefits, including limiting the spread of infectious diseases, reducing the severity of disease as well as reducing health care utilization and health spending over time. Although out-of-pocket spending is one factor among many that affects whether individuals receive a recommended vaccine, the elimination of out-of-pocket costs, as the IRA has accomplished for ACIP-recommended adult vaccines covered under Part D, has been cited as a key intervention to improve vaccine uptake. ^24^ Reducing out-of-pocket costs will make it easier for enrollees to access vaccines, which in turn may prevent downstream consequences and serious complications that arise from vaccine preventable diseases.

## APPENDIX

Table A1 Common Vaccine Preventable Conditions and Recommendations for Older Adults for Vaccines Covered under Medicare Part D

Infectious Disease | Description of Infectious Disease | ACIP Vaccine Recommendations for Older Adults^a^
Respiratory Syncytial Virus (RSV) | A respiratory virus that usually causes mild cold-like symptoms, but some populations, including older adults, are at greater risk of severe infection, which can lead to complications such as bronchiolitis and pneumonia.^25^ | A single dose of an RSV vaccine for adults ages 60 and older with shared clinical decision making between individuals and health care providers so that vaccination is targeted to those at the highest risk of severe RSV disease.^26^
Shingles (Herpes Zoster) | A painful and debilitating viral infection that can cause a rash and nerve pain throughout the body. The infection can be especially severe for those at higher risk (for example, immunocompromised individuals).^27^ | Two doses for individuals ages 50 and older.^28^
Tetanus, Diphtheria, and Pertussis | Tetanus is a bacterial, life-threatening infection that can cause nerve pain throughout the body, painful muscle spasms, paralysis, and even death.^29^; Diphtheria is a bacterial infection that can cause severe sore throat, throat swelling, and difficulty breathing; complications can lead to kidney, heart, and nerve damage.^30^; Pertussis, also known as whooping cough, is a bacterial infection that can cause violent bouts of coughing. Complications include pneumonia.^31^ | One dose of Tdap, which provides protection from tetanus, diphtheria, and pertussis, and then Td or Tdap every 10 years.^32^

Source: ASPE review of ACIP Vaccine Recommendations | CDC (https://www.cdc.gov/vaccines/hcp/acip-recs/index.html)

Notes:

a Table does not include additional recommendations for vaccines that are recommended to older adults after potential high-risk exposure to pathogen.

Tdap = Tetanus, diphtheria, and acellular pertussis vaccine

Td = Tetanus and diphtheria vaccine

Table A2 Demographic Characteristics of Enrollees Receiving Any Medicare Part D Covered Vaccine with No Cost Sharing Compared to Medicare Part D Population, 2023

| Total Medicare Part D Enrollees | | Enrollees Receiving Any Part D Vaccine with No Cost Sharing^a^
Demographic Characteristics | N | % | N | %
Overall | 51,924,013 | 100% | 10,268,711 | 100
Age
Under 65 Years | 6,126,612 | 12% | 502,968 | 5%
65 Years and Over | 45,797,400 | 88% | 9,765,743 | 95%
Gender
Male or Unknown | 22,559,828 | 43% | 4,381,489 | 43%
Female | 29,364,185 | 57% | 5,887,222 | 57%
Race^b^
Non-Hispanic White | 37,154,373 | 72% | 7,993,293 | 78%
Black | 5,541,317 | 11% | 706,109 | 7%
Asian/Pacific Islander | 2,038,574 | 4% | 418,143 | 4%
Hispanic | 5,406,191 | 10% | 762,060 | 7%
American Indian/Alaska Native | 165,314 | <1% | 18,291 | <1%
Other Race | 421,551 | 1% | 89,834 | 1%
Unknown Race | 1,196,693 | 2% | 280,981 | 3%
Low-Income Subsidy (LIS) Status
LIS | 14,353,221 | 28% | 1,547,091 | 15%
Non-LIS | 37,570,791 | 72% | 8,721,620 | 85%
Geographic Area
Urban | 43,173,913 | 83% | 8,748,627 | 85%
Rural or Unknown | 8,750,099 | 17% | 1,520,084 | 15%

Source: CMS OEDA analysis of the Medicare Prescription Drug Event (PDE) and Medicare enrollment data files.

Notes: This sample is restricted to enrollees who received at least one vaccine at no cost that is covered under Part D.

a Denominator is total number of enrollees who received a Part D covered vaccine.

b Race and ethnicity are identified using the Research Triangle Institute’s race variable, which is created by taking the beneficiary race code and applying an algorithm to correct for undercounting of some racial and ethnic groups.

Table A3 Demographic Characteristics of Enrollees Receiving the RSV and Shingles Vaccines with No Cost Sharing Compared to Medicare Part D Population, 2023

| Total Medicare Part D Enrollees | | Enrollees Receiving RSV Vaccine with No Cost Sharing^a^ | | Enrollees Receiving a Shingles Vaccine with No Cost Sharing^a^
Demographic Characteristics | N | % | N | % | N | %
Age
Under 65 Years | 6,126,612 | 12% | 135,447 | 2% | 298,794 | 8%
65 Years and Older | 45,797,400 | 88% | 6,380,847 | 98% | 3,596,003 | 92%
Gender
Male | 22,559,828 | 43% | 2,768,858 | 42% | 1,682,433 | 43%
Female | 29,364,185 | 57% | 3,747,436 | 58% | 2,212,364 | 57%
Race and Ethnicity^b^
Non-Hispanic White | 37,154,373 | 72% | 5,383,670 | 83% | 2,778,313 | 71%
Black | 5,541,317 | 11% | 328,602 | 5% | 378,283 | 10%
Asian/Pacific Islander | 2,038,574 | 4% | 229,516 | 4% | 174,886 | 4%
Hispanic | 5,406,191 | 10% | 313,172 | 5% | 434,518 | 11%
American Indian/Alaska Native | 165,314 | <1% | 8,739 | <1% | 8,717 | <1%
Other Race | 421,551 | 1% | 56,808 | 1% | 32,435 | 1%
Unknown Race | 1,196,693 | 2% | 195,787 | 3% | 87,645 | 2%
Low Income Subsidy (LIS) Status
LIS | 14,353,221 | 28% | 709,924 | 11% | 783,329 | 20%
Non-LIS | 37,570,791 | 72% | 5,806,370 | 89% | 3,111,468 | 80%
Geographic Area
Urban | 43,173,913 | 83% | 5,601,115 | 86% | 3,248,582 | 83%
Rural or Unknown | 8,750,099 | 17% | 915,179 | 14% | 646,215 | 17%

Source: CMS OEDA analysis of the Medicare Prescription Drug Event (PDE) and Medicare enrollment data files.

Notes: This sample is restricted to enrollees who received at least one RSV vaccine for the RSV column and one shingles vaccine for the shingles column at no cost under Part D.

RSV = Respiratory Syncytial Virus

a Denominator is total number of enrollees who received the RSV or shingles vaccine, depending on the column.

b Race and ethnicity are identified using the Research Triangle Institute’s race variable, which is created by taking the beneficiary race code and applying an algorithm to correct for undercounting of some racial and ethnic groups.

## REFERENCES

1 Haynes, L. (2020, October 15). Aging of the Immune System: Research Challenges to Enhance the Health Span of Older Adults. Frontiers. Retrieved February 13, 2023, from https://www.frontiersin.org/articles/10.3389/fragi.2020.602108/full
2 Centers for Medicare & Medicaid Services. Retrieved on April 2024 from: 10522-inflation-reduction-act-timeline.pdf (cms.gov)
3 Centers for Disease Control and Prevention. (2024). Respiratory Syncytial Virus. Retrieved April 2024 from: Safety Information for Respiratory Syncytial Virus (RSV) Vaccine | Vaccine Safety | CDC
4 Centers for Disease Control and Prevention. (2024). Vaccine Recommendations and Guidelines of the ACIP. Retrieved April 2024 from https://www.cdc.gov/vaccines/hcp/acip-recs/vacc-specific/rsv.html
5 Centers for Disease Control and Prevention. (2024). Respiratory Syncytial Virus Surveillance and Research. Retrieved April 2024 from: RSV Surveillance and Research | CDC
6 Grace, M., Colosia, A., Wolowacz, S., Panozzo, C., Ghaswalla, P., (2023). Economic burden of respiratory syncytial virus infection in adults: A systematic literature review. Journal of Medical Economics, 26, 1, 742–759.37167068
7 Duff, B.L., (2020). What’s the Cost of Herpes Zoster? Drug Topics. Retrieved April 2024 from What’s the Cost of Herpes Zoster? (drugtopics.com)
8 Meyers, J.L., Candrilli, S.D., Rausch, D.A., Yan, S., Patterson, B.J., Levin, M.J. (2019). Costs of herpes zoster complications in older adults: A cohort study of US claims database, Vaccine, 37, 9.
9 Centers for Disease Control and Prevention. (2022, February 17). Vaccination Coverage among Adults in the United States, National Health Interview Survey, 2019–2020. Centers for Disease Control and Prevention. Retrieved April, 2023, from https://www.cdc.
10 U.S. Government Accountability Office. (2022). Routine vaccinations: Adult rates vary by vaccination type and other factors. Retrieved from: gao-22–105334.pdf
11 Centers for Disease Control & Prevention. (2021). Vaccination Coverage among Adults in the United States, National Health Interview Survey, 2021 | CDC
12 Tao, Z., Li, Y., Stemkowski, S., Johnson, K.D., Acosta, C.J., Zhang, D., Fendrick, A.M. (2018). Impact of Out-of-Pocket Cost on Herpes Zoster Vaccine Uptake: An Observational Study in a Medicare Managed Care Population. Vaccines, 6, 4, 78.30469449
13 Churchill, B. F. & Henkhaus, L.E. (2023). The Roles of Cost and Recommendations in Driving Vaccine Take-Up: Evidence from the Herpes Zoster Vaccine for Shingles Prevention. American Journal of Health Economics, 9, 4.
14 Vogelsang, E. & Polonijo, A.N. (2021). Social Determinants of Shingles Vaccination in the United States | The Journals of Gerontology, 77, 2, 407–412.
15 Draper, M. & Stergiopoulos, S. (2021). Shingles vaccination uptake in Massachusetts adults aged 50 years and older. Vaccine, 39, 46, 6781–6786.34625290
16 Sayed, BA, Finegold, K, Ashok, K, Schutz, S, De Lew, N, Sheingold, S, Sommers, BD. Inflation Reduction Act Research Series: Medicare Part D Enrollee Savings from Elimination of Vaccine Cost-Sharing. (Issue Brief No. HP-2023–05). Office of the Assistant Secretary for Planning and Evaluation, U.S. Department of Health and Human Services. September 2023.
17 Sayed, BA, Finegold, K, Ashok, K, Schutz, S, De Lew, N, Sheingold, S, Sommers, BD. Inflation Reduction Act Research Series: Medicare Part D Enrollee Savings from Elimination of Vaccine Cost-Sharing. (Issue Brief No. HP-2023–05). Office of the Assistant Secretary for Planning and Evaluation, U.S. Department of Health and Human Services. September 2023.
18 Sevin, A.M., Romeo, C., Gagne, B. Factors influencing adults’ immunization practices: a pilot survey study of a diverse, urban community in central Ohio. BMC Public Health 16, 424 (2016). 10.1186/s12889-016-3107-9 27216805
19 Vogelsang, E.M. & Polonijo, A.N. (2022). Social Determinants of Shingles Vaccination in the United States. Journals of Gerontology Series B, Psychological sciences and social sciences, 3, 77 (2), 407–412.33928360
20 Feyman Y, Ruhter J, Finegold K, Buchmueller T, De Lew N, Zuckerman R, Sheingold S. Medicare Enrollees and the Part D Drug Benefit: Improving Financial Protection through the Low Income Subsidy. (Issue Brief No. HP-2024–01). Office of the Assistant Secretary for Planning and Evaluation, U.S. Department of Health and Human Services. February 2024.
21 Business Wire. (2023). GSK Announces the COiMMUNITY Initiative to Help Achieve Higher Adult Vaccination Rates in the US. Retrieved April 2024 from: GSK Announces the COiMMUNITY Initiative to Help Achieve Higher Adult Vaccination Rates in the US | Business Wire
22 Adams, B. (2023). RSV vaccine awareness low among older adults, but majority would ask their doc about new shots: survey | Fierce Pharma. Retrieved April 2024.
23 Haeder, S.F. (2024). US seniors' intention to vaccinate against RSV in fall and winter 2023–2024. Health Affairs Scholar, 2(2).
24 Community Preventive Services Task Force. Vaccination: Reducing Out-of-Pocket Costs | The Community Guide. Retrieved on April 2024 from: https://www.thecommunityguide.org/findings/vaccination-programs-reducing-client-out-pocket-costs.html.
25 Centers for Disease Control and Prevention. (2024). Respiratory Syncytial Virus. Retrieved April 2024 from: Safety Information for Respiratory Syncytial Virus (RSV) Vaccine | Vaccine Safety | CDC
26 Melgar M, Britton A, Roper LE, Use of Respiratory Syncytial Virus Vaccines in Older Adults: Recommendations of the Advisory Committee on Immunization Practices — United States, 2023. MMWR Morb Mortal Wkly Rep 2023;72:793– 801. DOI: 10.15585/mmwr.mm7229a4 37471262
27 Centers for Disease Control & Prevention. (2022). Shingles (Herpes Zoster). Retrieved April 2024 from: Shingles (Herpes Zoster) | CDC
28 Centers for Disease Control & Prevention. (2023). ACIP Zoster Vaccine Recommendations | Shingles | CDC. Retrieved April 2024 from www.cdc.gov
29 Centers for Disease Control & Prevention. (2022). Tetanus Disease (Lockjaw) | CDC. Retrieved April 2024 from www.cdc.gov.
30 Centers for Disease Control & Prevention. (2022). Diphtheria | CDC. Retrieved April 2024 from www.cdc.gov
31 Centers for Disease Control & Prevention. (2022). Whooping Cough (Pertussis) | CDC. Retrieved April 2024 from www.cdc.gov.
32 Centers for Disease Control & Prevention. (2022). ACIP DTaP Vaccine Recommendations | CDC. Retrieved April 2024 from www.cdc.gov.

* This estimate is calculated using the overall average out-of-pocket spending per enrollee for vaccines for shingles, Tdap, Td, and “other vaccines” from previous ASPE analyses, updating to 2023 dollars, and applying the updated estimates to the 2023 estimates of use for each type of vaccine. Please see here (https://aspe.hhs.gov/reports/ira-elimination-vaccine-cost-sharing) for the original estimates of average out-of-pocket spending for each vaccine in 2021.

† We do not have an estimate of out-of-pocket spending for the RSV vaccine because the vaccine became available after the IRA’s vaccine provision went into effect.

‡ About 5.3 percent of the Part D population received a vaccination for shingles in 2021. This increased to about 7.5 percent of the Part D population in 2023. Note that the total number of vaccinations in 2021 may have been lower than a more typical year due to the COVID-19 pandemic. Also, this estimate does not represent rates of vaccine coverage for the Medicare Part D population because it only captures enrollees who received a Part D covered vaccine during the time period examined. Some enrollees may have received a Part D covered vaccine in prior years and would not be eligible for another dose.

* Medicare Part B vaccine coverage includes vaccines to prevent influenza, pneumococcal disease, hepatitis B for beneficiaries who are at medium or high risk, and COVID-19. Congress has on four occasions amended the Medicare statute to cover specific preventive vaccines with no cost sharing under Part B: pneumococcal disease (1981); hepatitis B for patients at medium or high risk (1984); seasonal influenza, recommended annually (1993); and COVID-19 (2020). (See Medicare Payment Advisory Commission (MedPAC), Report to the Congress: Medicare and the Health Care Delivery System (https://www.medpac.gov/wp-content/uploads/import_data/scrape_files/docs/default-source/reports/jun21_medpac_report_to_congress_sec.pdf), June 2021, p. 245.).

† Medicare Part D was enacted as part of the Medicare Prescription Drug, Improvement, and Modernization Act of 2003 (P.L. 108–173). Under Medicare Part D, vaccines determined reasonable and necessary to prevent illness are covered and were subject to cost sharing until January 1, 2023, when the IRA required no cost sharing for ACIP-recommended adult vaccines that are covered under Medicare Part D.

‡ The RSV vaccine is recommended for adults ages 60 and older with shared decision making with their health care provider. There are two RSV vaccines available: 1) Abrysvo (https://www.fda.gov/media/168889/download?attachment), which is indicated for adults ages 60 and older as well as pregnant individuals 32 through 36 weeks gestational age and 2) Arexvy (https://www.fda.gov/media/167805/download?attachment), which is indicated for adults 60 and older only.

* Note that the total number of vaccinations in 2021 may have been lower than a more typical year due to the COVID-19 pandemic. In addition, some Part D enrollees may have received a Part D covered vaccine with no cost sharing prior to the IRA vaccine provision going into effect. See here (https://www.medpac.gov/wp-content/uploads/import_data/scrape_files/docs/default-source/default-document-library/jun21_ch7_medpac_report_to_congress_sec.pdf) for more details.

† For eligible enrollees whose income and resources are limited, the Medicare Prescription Drug, Improvement and Modernization Act of 2003 established the Low-Income Subsidy, also known as Extra Help. Subsidies are paid by the Federal government to drug plans and provide assistance with premiums, deductibles, and co-payments. Under the IRA, beginning in 2024, the LIS program is expanded to individuals with limited financial resources and incomes up to 150 percent of the Federal Poverty Limit (FPL). For more information, please see here (https://www.cms.gov/training-education/partner-outreach-resources/low-income-subsidy-lis#:%7E:text=What%27s%20the%20Low%20Income%20Subsidy,of%20Medicare%20prescription%20drug%20coverage.).

* There were 14.4 million total LIS enrollees in 2023, which means that about 11 percent of these enrollees received a Part D covered vaccine.

† There were 37.5 million total non-LIS enrollees in 2023, which means that about 23 percent of non-LIS enrollees received a Part D covered vaccine.

* Note that some Part D enrollees may have received a Part D covered vaccine with no cost sharing prior to the IRA vaccine provision going into effect. See here (https://www.medpac.gov/wp-content/uploads/import_data/scrape_files/docs/default-source/default-document-library/jun21_ch7_medpac_report_to_congress_sec.pdf) for more details.

† About 5.3 percent of the Part D population received a vaccination for shingles in 2021. This increased to about 7.5 percent of the Part D population in 2023. Note that this estimate does not represent rates of vaccine coverage for the Medicare Part D population because it only captures enrollees who received a Part D covered vaccine during the time period examined. Some enrollees may have received a Part D covered vaccine in prior years and would not be eligible for another dose. See “Methods” for more detail.

* We calculated this figure by using the overall (LIS + non-LIS) average out-of-pocket spending per enrollee for vaccines for shingles, Tdap, and Td from previous ASPE analyses, updating to 2023 dollars, and applying the updated estimates to the 2023 estimates of use for each type of vaccine. For all other vaccines, we used the average out-of-pocket costs for ‘others.’ Please see here for the original estimates of average out-of-pocket spending for each vaccine (Table 4).

† The Kaiser Family Foundation (KFF) reports that the RSV vaccine may cost between $180 to $295 for one dose, but this is not equivalent to out-of-pocket spending per enrollee for this vaccine. Please see here (https://kffhealthnews.org/news/article/timing-cost-vaccines-insurance-flu-covid-rsv/).