# Acknowledgment

We gratefully acknowledge the following individuals for their contributions to this project: staff at Conselara LLC., John Snow, Inc., and SPIRE Communications