# Program Background

## About the Digital Healthcare Research Program

The DHR program’s mission is to determine how the various components of the ever-evolving digital healthcare ecosystem can best come together to positively affect healthcare delivery and create value for patients and their families.

The DHR Program’s vision is that every patient and care team will have ready access to all applicable data and knowledge, supported by advanced analytics and understandable visualizations, to address a patient’s health and healthcare. We want the best information to be available to clinicians and patients at the point of care.

AHRQ’s digital healthcare initiative is part of the Nation’s strategy to put information technology to work in healthcare. By making health information available electronically when and where it is needed, digital healthcare can improve the quality of care, even as it makes healthcare more cost-effective.

To fulfill its mission, the DHR program has invested in research grants and contracts awarded to over 289 distinct institutions in 48 States, the District of Columbia, and Puerto Rico (https://digital.ahrq.gov/ahrq-funded-projects/ahrq-funded-projects-map).

## What We Fund

In 2022, the DHR program managed:

- 108 grants and 7 research contracts
  » At 69 institutions.
  » In 25 states and the District of Columbia.
  » For a total investment of $172.9 million across all project years.
  » For a total 2022 investment of $29 million, including:
    ○ $14.3 million in funding from DHR appropriation.
    ○ $13 million in funding from the Patient-Centered Outcomes Research Trust Fund.
    ○ $1.7 million in funding from General Health Services Research appropriation

The DHR program’s funding opportunities (https://digital.ahrq.gov/ahrq-digital-healthcare-research-funding-opportunities) are designed to fund research that fills knowledge gaps and leads to improvements in the design of digital healthcare systems. The program accomplishes this through grant and contract mechanisms that support different types of health services research, including:

- Exploratory and developmental research grants that support research in the early and conceptual stages of development.
- Pilot and feasibility studies.
- Randomized controlled trials and other studies of technology effectiveness.
- Secondary analyses of existing data.
- Scaling and disseminating evidence-based research.
- Supporting conferences that help to further AHRQ’s mission to produce evidence to make healthcare safer, higher quality, more accessible, equitable, and affordable.
- AHRQ also invests in the next generation of researchers by funding promising new investigators through awards intended to foster their career development in digital healthcare research.

Learn more about the current AHRQ Digital Healthcare Research funding opportunities here (https://digital.ahrq.gov/ahrq-digital-healthcare-research-funding-opportunities).

Recent priority funding from the DHR program has focused on the following focus areas to add to the evidence base of what and how digital healthcare works best for clinicians, patients and their families, and the healthcare system as a whole:

- Testing how digital healthcare interventions can improve quality of care and healthcare service delivery at the point of care. Learn more (https://grants.nih.gov/grants/guide/pa-files/pa-21-164.html).
- How the digital healthcare ecosystem can improve patient safety and how components of it can be safely used and implemented. Learn more (https://grants.nih.gov/grants/guide/notice-files/NOT-HS-22-004.html).
- Innovative and evidence-based interventions that advance the U.S. goal of achieving equity in the delivery of healthcare services, including reducing disparities in quality of care, patient safety, healthcare utilization and access, and ultimately, health outcomes. Learn more (https://grants.nih.gov/grants/guide/notice-files/NOT-HS-21-014.html).

## Learn More

Want to know more? Visit our website at https://digital.ahrq.gov/ to learn more about our team, current funding priorities (https://digital.ahrq.gov/program-overview/directors-corner), funding opportunities (https://digital.ahrq.gov/ahrq-digital-healthcare-research-funding-opportunities), and the findings and impact (https://digital.ahrq.gov/ahrq-funded-projects/search) of the work we fund.

Stay Updated!

Click here (https://www.ahrq.gov/news/newsletters/index.html) to sign up for AHRQ Digital Healthcare Research News and Information.