# References

1 Institute of Medicine Committee on Quality of Health Care in America, Crossing the Quality Chasm: A New Health System for the 21st Century 2001, National Academies Press: Washington, DC.
2 Centers for Medicare & Medicaid Services. Comprehensive Primary Care Plus. Available from: https://innovation.cms.gov/innovation-models/comprehensive-primary-care-plus.
3 Centers for Medicare & Medicaid Services. Participation Options Overview. Available from: https://qpp.cms.gov/mips/overview.
4 Health Care Payment Learning & Action Network, Foundational Resources. Available from: http://hcp-lan.org/workproducts/HCPLAN-Resources.pdf
5 Phillips, R.L., Jr., ., The primary care extension program: a catalyst for change. Annals of family medicine, 2013. 11(2): p. 173–178.23508605
6 McNellis, R.J., J.L. Genevro, and D.S. Meyers, Lessons learned from the study of primary care transformation. Annals of family medicine, 2013. 11 Suppl 1(Suppl 1): p. S1–S5.23690378
7 Scholle, S.H., ., Support and strategies for change among small patient-centered medical home practices. Annals of family medicine, 2013. 11 Suppl 1(Suppl 1): p. S6–S13.23690387
8 Fernald, D., R. Wearner, and W.P. Dickinson, Supporting primary care practices in building capacity to use health information data. EGEMS (Washington, DC), 2014. 2(3): p. 1094–1094.25848621
9 Dickinson WP, M.W., Keller DM, Bitton A, Mold JW,. Practice transformation: suggested areas for prioritized research. in Patient Centered Medical Home Research invitation meeting sponsored by AHRQ, the Veterans Administration, and Commonwealth Foundation. 2013. Washington, DC.
10 Grumbach, K. and J.W. Mold, A Health Care Cooperative Extension Service: Transforming Primary Care and Community Health. JAMA, 2009. 301(24): p. 2589–2591.19549977
11 Ruhe, M.C., ., Facilitating practice change: lessons from the STEP-UP clinical trial. Preventive Medicine, 2005. 40(6): p. 729–734.15850872
12 Dickinson, W.P., ., Practice Facilitation to Improve Diabetes Care in Primary Care: A Report From the EPIC Randomized Clinical Trial. The Annals of Family Medicine, 2014. 12(1): p. 8.24445098
13 Dickinson, W.P., ., A Cluster Randomized Trial Comparing Strategies for Translating Self-Management Support into Primary Care Practices. Journal of the American Board of Family Medicine : JABFM, 2019. 32(3): p. 341–352.31068398
14 Parchman, M.L., ., A randomized trial of practice facilitation to improve the delivery of chronic illness care in primary care: initial and sustained effects. Implementation Science, 2013. 8(1): p. 93.23965255
15 Persell, S., ., Effects of 2 Forms of Practice Facilitation on Cardiovascular Prevention in Primary Care: A Practice-randomized, Comparative Effectiveness Trial. Medical Care, 2019. 58: p. 1.
16 Dickinson, W.P., ., Practice Transformation Support and Patient Engagement to Improve Cardiovascular Care: From EvidenceNOW Southwest (ENSW). Journal of the American Board of Family Medicine : JABFM, 2020. 33(5): p. 675–686.32989062
17 Baskerville, N.B., C. Liddy, and W. Hogg, Systematic Review and Meta-Analysis of Practice Facilitation Within Primary Care Settings. The Annals of Family Medicine, 2012. 10(1): p. 63.22230833
18 Buscaj, E., ., Practice Facilitation for PCMH Implementation in Residency Practices. Family Medicine, 2016. 48: p. 795–800.27875602
19 Bender, B.G., ., The Colorado Asthma Toolkit Program: A Practice Coaching Intervention from the High Plains Research Network. The Journal of the American Board of Family Medicine, 2011. 24(3): p. 240.21551395
20 Nutting, P.A., ., Transforming physician practices to patient-centered medical homes: lessons from the national demonstration project. Health affairs (Project Hope), 2011. 30(3): p. 439–445.21383361
21 Nutting, P.A., ., Effect of Facilitation on Practice Outcomes in the National Demonstration Project Model of the Patient-Centered Medical Home. The Annals of Family Medicine, 2010. 8(Suppl 1): p. S33.20530393
22 Hogg, W., ., Improved preventive care in family practices with outreach facilitation: Understanding success and failure. Journal of health services research & policy, 2002. 7: p. 195–201.12425778
23 Agency for Healthcare Research and Quality. Introduction to the AHRQ Practice Facilitation Training Modules. AHRQ Practice Facilitation Training Modules 2021; Available from: https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation/modules/index.html#introduction.
24 Fernald, D.H., R. Wearner, and W.P. Dickinson, The Journey of Primary Care Practices to Meaningful Use: A Colorado Beacon Consortium Study. The Journal of the American Board of Family Medicine, 2013. 26(5): p. 603.24004712
25 Quesada, S. What in the world is a CHITA? 2018; Available from: https://www.corhio.org/blogs/expertise/2018/3/21/what-in-the-world-is-a-chita.
26 Knierim, K.E., ., Primary Care Practices’ Ability to Report Electronic Clinical Quality Measures in the EvidenceNOW Southwest Initiative to Improve Heart Health. JAMA Netw Open, 2019. 2(8): p. e198569.31390033
27 Jha, A.K., Meaningful Use of Electronic Health Records: The Road Ahead. JAMA, 2010. 304(15): p. 1709–1710.20959581
28 U.S. Department of Health & Human Services. Covered Entities and Business Associates. Available from: https://www.hhs.gov/hipaa/for-professionals/covered-entities/index.html.
29 U.S. Department of Health & Human Services. Disclosures for Emergency Preparedness - A Decision Tool: Data Use Agreement. Available from: https://www.hhs.gov/hipaa/for-professionals/special-topics/emergency-preparedness/data-use-agreement/index.html.
30 Office of the National Coordinator for Health Information Technology. 2015 Edition Health IT Certification Criteria Final Rule. 2015; Available from: https://www.healthit.gov/topic/certification-ehrs/2015-edition.
31 Office of the National Coordinator for Health Information Technology. Certified Health IT Product List | Charts. Available from: https://chpl.healthit.gov/#/charts.
32 Office of the National Coordinator for Health Information Technology ‘Certified Health IT Developers and Editions Reported by Health Care Professionals Participating in the Medicare EHR Incentive Program’. Health IT Quick-Stat #30, 2017.
33 Office of the National Coordinator for Health Information Technology. Certified Health IT Product List Search Tool (CHPL). Available from: https://chpl.healthit.gov/.
34 Office of the National Coordinator for Health Information Technology. eCQI Resource Center. Available from: https://ecqi.healthit.gov/.
35 Office of the National Coordinator for Health Information Technology. United States Core Data for Interoperability (USCDI) Available from: https://www.healthit.gov/isa/united-states-core-data-interoperability-uscdi.
36 Department of Veterans Affairs Office of Information & Technology Product Development, VistAWeb Version 16.1.88.2 User Manual. 2016, Department of Veterans Affairs,. Available from: https://www.va.gov/vdl/documents/Clinical/VistaWeb/vistawebusermanual.pdf.
37 Office of the National Coordinator for Health Information Technology, United States Core Data For Interoperability Draft Version 3 (January 2022). 2022. Available from: https://www.healthit.gov/isa/sites/isa/files/2022-01/Draft-USCDI-Version-3-January-2022-Final.pdf.
38 Agency for Healthcare Research and Quality, Primary Care Practice Facilitation Curriculum. 2015, Agency for Healthcare Research and Quality. Available from: https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation/curriculum/index.html.
39 Agency for Healthcare Research and Quality, Primary Care Practice Facilitation Curriculum. Module 17. 2015, Agency for Healthcare Research and Quality: Rockville, MD. Available from: https://pcmh.ahrq.gov/page/primary-care-practice-facilitation-curriculum.
40 Office of the National Coordinator for Health Information Technology, Capturing High Quality Electronic Health Records Data to Support Performance Improvement: A Learning Guide. 2013. Available from: https://www.healthit.gov/sites/default/files/onc-beacon-lg3-ehr-data-quality-and-perform-impvt.pdf.
41 Oregon Health and Science University. SBIRT Oregon. Available from: http://www.sbirtoregon.org/.
42 The American Health Information Management Association, Information Governance Toolkit 2015, The American Health Information Management Association.
43 U.S. Department of Health and Human Services. The HIPAA Privacy Rule. Available from: https://www.hhs.gov/hipaa/for-professionals/privacy/index.html.
44 Substance Abuse and Mental Health Services Administration. Substance Abuse Confidentiality Regulations Available from: https://www.samhsa.gov/about-us/who-we-are/laws-regulations/confidentiality-regulations-faqs
45 U.S. Department of Education. Family Educational Rights and Privacy Act (FERPA). Available from: https://www2.ed.gov/policy/gen/guid/fpco/ferpa/index.html
46 HL7 International. Welcome to FHIR®. Available from: https://www.hl7.org/fhir/.
47 Barbara H. Gregory, Cheryl Van Horn, and V.S. Kaprielian, Eight Steps to a Chart Audit for Quality. Family Practice Management, 2008.
48 Agency for Healthcare Research and Quality, Primary Care Practice Facilitation Curriculum. Module 14, Appendix 14A. 2015, Agency for Healthcare Research and Quality. Available from: https://www.ahrq.gov/sites/default/files/wysiwyg/ncepcr/tools/PCMH/pcpf-module-14-collecting-performance-data.pdf.
49 Agency for Healthcare Research and Quality, Practice Facilitation Handbook, Module 8 Appendix C. Agency for Healthcare Research and Quality. Available from: https://www.ahrq.gov/ncepcr/tools/pf-handbook/mod8-appendixc.html.
50 Wright, A., ., A Description and Functional Taxonomy of Rule-based Decision Support Content at a Large Integrated Delivery Network. Journal of the American Medical Informatics Association, 2007. 14(4): p. 489–496.17460131
51 Wright, A., ., Development and evaluation of a comprehensive clinical decision support taxonomy: comparison of front-end tools in commercial and internally developed electronic health record systems. J Am Med Inform Assoc, 2011. 18(3): p. 232–42.21415065
52 Sutton, R.T., ., An overview of clinical decision support systems: benefits, risks, and strategies for success. npj Digital Medicine, 2020. 3(1): p. 17.32047862
53 Agency for Healthcare Research and Quality, Integrating Patient-Generated Health Data into Electronic Health Records in Ambulatory Care Settings: A Practical Guide. 2021: Agency for Healthcare Research and Quality. Available from: https://digital.ahrq.gov/sites/default/files/docs/citation/pghd-practical-guide.pdf.
54 The George Washington University Milken Institute School of Public Health, Legal and Ethical Architecture for PCOR Data. Chapter 2: Legal and Ethical Significance of Data for PCOR. 2018, Office of the National Coordinator for Health Information Technology. Available from: https://www.healthit.gov/sites/default/files/page/2018-02/PCOR%20Architecture_Chapter%202_S_ONC%20FINAL.pdf.
55 Deering, M.J., Issue Brief: Patient-Generated Health Data and Health IT. 2013, Office of the National Coordinator for Health Information Technology. Available from: https://www.healthit.gov/sites/default/files/pghd_brief_final122013.pdf.
56 Jim, H.S.L., ., Innovations in research and clinical care using patient-generated health data. CA: A Cancer Journal for Clinicians, 2020. 70(3): p. 182–199.32311776
57 Ethington, J.D., J. Shi, and S. Nelson, Online Patient Center: Expanding Patient Portals by Integrating Patient-Generated Data Directly into a Primary Care Provider’s EHR Workflow. 2014. 1654–8.
58 Snyder, C. and A.W. Wu, eds., Users’ Guide to Integrating Patient-Reported Outcomes in Electronic Health Records. 2017, Johns Hopkins University. Funded by Patient-Centered Outcomes Research Institute (PCORI). Available from: https://www.pcori.org/sites/default/files/PCORI-JHU-Users-Guide-To-Integrating-Patient-Reported-Outcomes-in-Electronic-Health-Records.pdf.
59 Cleeland, C.S., Symptom Burden: Multiple Symptoms and Their Impact as Patient-Reported Outcomes. JNCI Monographs, 2007. 2007(37): p. 16–21.
60 Rodriguez, S., K. Hwang, and J. Wang, Connecting Home-Based Self-Monitoring of Blood Pressure Data Into Electronic Health Records for Hypertension Care: A Qualitative Inquiry With Primary Care Providers. JMIR formative research, 2019. 3(2): p. e10388–e10388.31124468
61 Nittas, V., ., Electronic Patient-Generated Health Data to Facilitate Disease Prevention and Health Promotion: Scoping Review. Journal of medical Internet research, 2019. 21(10): p. e13320–e13320.31613225
62 Fung, C.H. and R.D. Hays, Prospects and challenges in using patient-reported outcomes in clinical practice. Quality of life research : an international journal of quality of life aspects of treatment, care and rehabilitation, 2008. 17(10): p. 1297–1302.18709564
63 Squitieri, L., K.J. Bozic, and A.L. Pusic, The Role of Patient-Reported Outcome Measures in Value-Based Payment Reform. Value in health : the journal of the International Society for Pharmacoeconomics and Outcomes Research, 2017. 20(6): p. 834–836.28577702
64 Healthcare Information and Management Systems Society, The Metro Health System (Cleveland Ohio) Diabetes Davies Award Case Study. 2021. Available from: https://www.himss.org/sites/hde/files/media/file/2021/01/20/metrohealth-davies-diabetes-management-case.pdf.
65 Cebul, R.D., ., Electronic Health Records and Quality of Diabetes Care. New England Journal of Medicine, 2011. 365(9): p. 825–833.21879900
66 Centers for Medicare & Medicaid Services. Quality Performance Category: Traditional MIPS Requirements. Available from: https://qpp.cms.gov/mips/quality-requirements.
67 American Board of Family Medicine Quality Performance Dashboard User Guide. 2019.
68 U.S. Department of Health & Human Services. Preventive Care. Available from: https://health.gov/healthypeople/objectives-and-data/browse-objectives/preventive-care#cit1.
69 Borsky, A., ., Few Americans Receive All High-Priority, Appropriate Clinical Preventive Services. Health Affairs, 2018. 37(6): p. 925–928.29863918
70 U.S. Department of Health & Human Services. Social Determinants of Health. Available from: https://health.gov/healthypeople/objectives-and-data/social-determinants-health
71 Hood, C.M., ., County Health Rankings: Relationships Between Determinant Factors and Health Outcomes. Am J Prev Med, 2016. 50(2): p. 129–35.26526164
72 County Health Rankings & Roadmaps, Determinants of Health from the County Health Rankings Model (2016). Available from: https://www.countyhealthrankings.org/explore-health-rankings/measures-data-sources/county-health-rankings-model
73 The Gravity Project. Available from: https://thegravityproject.net/
74 Hicks, J., The Potential of Claims Data to Support the Measurement of Health Care Quality. 2003, RAND Corporation: Santa Monica, CA. Available from: https://www.rand.org/pubs/rgs_dissertations/RGSD171.html.
75 Centers for Medicare & Medicaid Services, Medicare Claims Synthetic Public Use Files (SynPUFs). Available from: https://www.cms.gov/Research-Statistics-Data-and-Systems/Downloadable-Public-Use-Files/SynPUFs.
76 Stein, J.D., ., Use of health care claims data to study patients with ophthalmologic conditions. Ophthalmology, 2014. 121(5): p. 1134–41.24433971
77 Agency for Healthcare Research and Quality, Inventory and Prioritization of Measures To Support the Growing Effort in Transparency Using All-Payer Claims Databases. 2017. Available from: https://www.ahrq.gov/data/apcd/backgroundrpt/data.html#methods.
78 Solberg, L.I., ., Are claims data accurate enough to identify patients for performance measures or quality improvement? The case of diabetes, heart disease, and depression. Am J Med Qual, 2006. 21(4): p. 238–45.16849780
79 Reid, R.O., ., Waste in the Medicare Program: a National Cross-Sectional Analysis of 2017 Low-Value Service Use and Spending. J Gen Intern Med, 2021. 36(8): p. 2478–2482.32728953
80 Rudrapatna, V.A., ., Accuracy of medical billing data against the electronic health record in the measurement of colorectal cancer screening rates. BMJ open quality, 2020. 9(1): p. e000856.
81 National Committee for Quality Assurance (NCQA). HEDIS and Performance Measurement. Available from: https://www.ncqa.org/hedis/.
82 Centers for Medicare & Medicaid Services. ICD-10. Available from: https://www.cms.gov/Medicare/Coding/ICD10.
83 American Medical Association. CPT®. Available from: https://www.ama-assn.org/practice-management/cpt.
84 Centers for Medicare & Medicaid Services. HCPCS - General Information Available from: https://www.cms.gov/Medicare/Coding/MedHCPCSGenInfo.
85 Health Policy Brief: Pay For Performance, in Health Affairs Blog. 2012. Available from: https://www.healthaffairs.org/do/10.1377/forefront.20121011.024094/full/.
86 National Committee for Quality Assurance (NCQA). HEDIS Measures and Technical Resources. Available from: https://www.ncqa.org/hedis/measures/
87 L.A. Care, CPT Category II Coding Tip Sheet. 2020. Available from: http://www.lacare.org/sites/default/files/la2153_cpt_category_ii_tip_sheet_202001.pdf.
88 BlueCross BlueShield of Illinois. HEDIS Tip Sheets. Available from: https://www.bcbsil.com/provider/clinical/hedis.html.
89 Aetna, Better Health HEDIS Tips 2020 for PCPs. 2020. Available from: https://www.aetnabetterhealth.com/content/dam/aetna/medicaid/kentucky/providers/pdfs/HEDIS%202020%20Tips%20for%20PCPs.pdf.
90 Centers for Medicare & Medicaid Services. Traditional MIPS Overview. Available from: https://qpp.cms.gov/mips/traditional-mips
91 John Kontor, M., J.P. Hazelrigs;, and E. Johnson, Payer-Provider Partnerships: Analytics Key to Value. NEJM Catalyst, 2020.
92 Gerteis, M., ., Uses and Limitations of Claims-based Performance Feedback Reports: Lessons From the Comprehensive Primary Care Initiative. J Healthc Qual, 2018. 40(4): p. 187–193.28837449
93 Agency for Healthcare Research and Quality. Types of Health Care Quality Measures. July 2015; Available from: https://www.ahrq.gov/talkingquality/measures/types.html.
94 National Quality Forum, NQF CQM Database. Available from: https://www.qualityforum.org/QPS/QPSTool.aspx.
95 Office of the National Coordinator for Health Information Technology. Controlling High Blood Pressure. Available from: https://ecqi.healthit.gov/ecqm/ep/2020/cms165v8
96 Centers for Medicare & Medicaid Services Measure Calculations. 2021.
97 Wagner, J., ., Implementing Risk Stratification in Primary Care: Challenges and Strategies. J Am Board Fam Med, 2019. 32(4): p. 585–595.31300579
98 Dom Dera, J., Risk Stratification: A Two-Step Process for Identifying Your Sickest Patients. Fam Pract Manag, 2019. 26(3): p. 21–26.31083868
99 Lavallee, D.C., ., Incorporating Patient-Reported Outcomes Into Health Care To Engage Patients And Enhance Care. Health Aff (Millwood), 2016. 35(4): p. 575–82.27044954
100 Cantor, M.N. and L. Thorpe, Integrating Data On Social Determinants Of Health Into Electronic Health Records. Health Aff (Millwood), 2018. 37(4): p. 585–590.29608369
101 Xu, J., ., A Practical Risk Stratification Approach for Implementing a Primary Care Chronic Disease Management Program in an Underserved Community. J Health Care Poor Underserved, 2018. 29(1): p. 202–213.29503295
102 National Association of Community Health Centers, Population Health Management: Risk Stratification Action Guide. 2021. Available from: https://www.nachc.org/wp-content/uploads/2022/01/PHM_Risk-Stratification-AG-Jan-2022.pdf
103 Health Resources and Services Administration, Uniform Data System 2021 Health Center Data Reporting Tables. 2021. Available from: https://bphc.hrsa.gov/sites/default/files/bphc/datareporting/pdf/2021-uds-manual-tables.pdf.
104 Just, E., Understanding Risk Stratification, Comorbidities, and the Future of Healthcare 2016, Health Catalyst. Available from: https://studyres.com/doc/1492568/understanding-risk-stratification--comorbidities.
105 HL7 International. Introduction to HL7 Standards. Available from: https://www.hl7.org/implement/standards/index.cfm?ref=nav
106 Health Insurance Portability and Accountability Act of 1996, in 110 Stat. 1936. 1996. Available from: https://www.govinfo.gov/content/pkg/PLAW-104publ191/pdf/PLAW-104publ191.pdf.
107 Centers for Medicare & Medicaid Services Health Care Transactions Basics.
108 U.S. Department of Health & Human Services. Summary of the HIPAA Privacy Rule. Available from: https://www.hhs.gov/hipaa/for-professionals/privacy/laws-regulations/index.html
109 Office of the National Coordinator for Health Information Technology. Trusted Exchange Framework and Common Agreement (TEFCA). Available from: https://www.healthit.gov/topic/interoperability/trusted-exchange-framework-and-common-agreement
110 Office of the National Coordinator for Health Information Technology. About ONC’s Cures Act Final Rule. Available from: https://www.healthit.gov/curesrule/overview/about-oncs-cures-act-final-rule
111 Office of the National Coordinator for Health Information Technology, 21st Century Cures Act: Interoperability, Information Blocking, and the ONC Health IT Certification Program Final Rule. 2020. Available from: https://www.healthit.gov/cures/sites/default/files/cures/2020-05/ONC%2021st%20Century%20Cures%20Act%20Final%20Rule%20Overview%20031220.pdf
112 Office of the National Coordinator for Health Information Technology. Information Blocking. Available from: https://www.healthit.gov/topic/information-blocking
113 Office of the National Coordinator for Health Information Technology. 2015 Edition Test Method. Available from: https://www.healthit.gov/topic/certification-ehrs/2015-edition-test-method
114 National Quality Forum. Quality Data Model. Available from: https://www.qualityforum.org/QualityDataModel.aspx
115 HL7 International. Quality Improvement Core (QI-Core) Implementation Guide. Available from: http://hl7.org/fhir/us/qicore/
116 Office of the National Coordinator for Health Information Technology. Value Set. Available from: https://ecqi.healthit.gov/glossary/value-set
117 National Institutes of Health. Value Set Authority Center. Available from: https://vsac.nlm.nih.gov/valueset/2.16.840.1.113762.1.4.1045.39/expansion/Latest
118 National Committee for Quality Assurance. Using HEDIS® Measure Specifications. Available from: https://www.ncqa.org/hedis/using-hedis-measures/
119 Bodenheimer, T., ., The 10 building blocks of high-performing primary care. Annals of family medicine, 2014. 12(2): p. 166–171.24615313
120 Certification Commission for Health Information Technology, A Health IT Framework for Accountable Care. 2013. Available from: https://www.healthit.gov/sites/default/files/facas/a_health_it_framework_for_accountable_care_0.pdf.
121 Visualization: Long-term Care Facilities. Available from: https://gillingscovid19.unc.edu/visualization/long-term-care-facilities.
122 Morgenthaler, T.I., ., Measurement of quality to improve care in sleep medicine. Journal of clinical sleep medicine : JCSM : official publication of the American Academy of Sleep Medicine, 2015. 11(3): p. 279–291.25700883