# Table of Acronyms

Acronym: Full Name or Term
AAFP: American Academy of Family Physicians
ACG: Adjusted clinical groups
ACO: Accountable Care Organization
ADT: Admission, discharge, transfer
AHIMA: American Health Information Managers Association
AHRQ: Agency for Healthcare Research and Quality
AI: Artificial intelligence
AMD: Age-related macular degeneration
AMIA: American Medical Informatics Association
API: Application programming interface
ARRA: American Recovery and Reinvestment Act
AUDIT: Alcohol Use Disorders Identification Test
AUDIT-C: Alcohol Use Disorders Identification Test – Consumption
BAA: Business associate agreement
BMI: Body mass index
BP: Blood pressure
CCC: Chronic comorbidity count
CCD: Continuity of care documents
CCPA: California Consumer Privacy Act
CDC-REC: Centers for Disease Control - Race and ethnicity code set
CDS: Clinical decision support
CDSS: Clinical decision support system
CEHRT: Certified electronic health record technology
CFR: Code of federal regulations
CHPL: Certified health IT products list
CMS: Centers for Medicare & Medicaid Services
COPD: Chronic obstructive pulmonary disease
CPC+: Comprehensive Primary Care Plus
CPOE: Computerized provider order entry
CPT: Current procedural terminology
CQM: Clinical quality measure
CSV: Comma separated value
DHHS: Department of Health and Human Services
DOB: Date of birth
DUA: Data use agreement
EBM: Evidence based medicine
ECG: Electrocardiogram
eCQM: Electronic clinical quality measure
EHR: Electronic health record
EIN: Employment identification number
ERA: Elder risk assessment
ESRD: End stage renal disease
FAQ: Frequently asked question
FERPA: Family Educational Rights and Privacy Act
FHIR: Fast healthcare interoperability resources
FQHC: Federally qualified health center
GDPR: General data protection regulation
GXT: Graded exercise testing
HCC: Hierarchical condition categories
HCPCS: Healthcare common procedure coding system
HEDIS: Healthcare effectiveness data and information set
HIE: Health information exchange
HIMSS: The Healthcare Information and Management Systems Society
HIPAA: Health Insurance Portability and Accountability Act
HIT: Health information technology
HITECH: Health Information Technology for Economic and Clinical Health Act
HRQoL: Health-related quality of life
HRSA: Health Resources and Services Administration
HRSN: Health-related social needs
ICD: International classification of diseases
IID: Individuals with intellectual disabilities
IRB: Institutional review board
IT: Information technology
LOINC: Logical observation identifiers, names, and codes
MACRA: Medicare Access and Children’s Health Insurance Program Reauthorization Act
MEDCs: Major extended diagnostic groups
MHS: Metro Health System
MICH: Maternal, infant, and child health
MIPS: Merit-based incentive payment system
MVP: Minimum viable product
NACHC®: National Association of Community Health Centers
NCQA: National Committee for Quality Assurance
NDC: National drug code
NLM: National Library of Medicine
NLP: Natural language processing
NPI: National provider identifier
NQF: National Quality Forum
ONC: Office of the National Coordinator for Health Information Technology
PDF: Portable document format
PF: Practice facilitator
PGHD: Patient-generated health data
PHI: Protected health information
PHQ: Patient health questionnaire
PHR: Personal health record
PMI: Precision medicine initiative
PRAPARE: Protocol for responding to and assessing patients’ assets, risks, and experiences
PRO: Patient-reported outcomes
PROM: Patient-reported outcome measure
QDC: Quality data codes
QDM: Quality data model
QI: Quality improvement
QPP: Quality payment program
RECs: Regional extension center
ROI: Return on investment
RPM: Remote patient monitoring
SBIRT: Screening and brief intervention and referral to treatment
SBPM: Self-blood pressure monitoring
SDOH: Social determinants of health
SIM: State innovation model
SMART: Specific, measurable, achievable, realistic, and timely
SMBP: Self-measured blood pressure
SNOMED: Systematized nomenclature of medicine
SOAP: Subjective, objective, assessment, and plan
SOGI: Sexual orientation and gender identity
TEFCA: Trusted exchange framework and common agreement
UCUM: Unified code for units of measure
UDS: Uniform data system
USCDI: United States core data for interoperability
USPSTF: United States Preventive Services Task Force
UWPHI: University of Wisconsin Population Health Institute
VA: United States Department of Veterans Affairs
VBP: Value-based payment
VSAC: Value set authority center
VTE: Venous thromboembolism