# Acknowledgements

We would also like to acknowledge the following contributors:

## Editorial Panel

- Brian Cass; Cecil G. Sheps Center at the University of North Carolina at Chapel Hill
- Perry Dickinson, MD; University of Colorado Anschutz Medical Campus
- Ernesto Fana, New York City Department of Health & Mental Hygiene
- David Kendrick, MD; University of Oklahoma School of Community Medicine
- Kyle Knierim, MD; University of Colorado Anschutz Medical Campus
- Alex Krist, MD, MPH; Virginia Commonwealth University
- Theresa Walunas, PhD; Center for Health Information Partnerships, Northwestern University Feinberg School of Medicine

The AHRQ team would like to thank Bob McNellis for proposing the development of this handbook based on his experience with EvidenceNOW: Advancing Heart Health grantee teams working in the field.

## Health IT Advisor/Practice Facilitator Reviewers

- Andrew Bienstock, MHA; University of Colorado Anschutz Medical Campus
- Julie Schmelzer, MetaStar, Inc.

## Abt Team

- Lynn Hoffman, MA, MPH
- Jessie Gerteis, MPH
- Morgan Michaels
- Jared Hite, MBA, MPP

## Agency for Healthcare Research and Quality (AHRQ) Team

- Daniel Miller, MS
- Jan DeLaMare, MPAff
- Jesse Crosson, PhD
- Robert McNellis, MPH, PA