# Section 9 Review of Risk-Stratification in Primary Care

Risk stratification is the process of separating patient populations into high-risk, low-risk, and rising-risk groups. Risk stratification in healthcare settings involves the division of patient panels (patients attributed to a specific provider) into tiers or levels based on health and social factors to identify and address potentially avoidable and expensive adverse health outcomes. Data and factors utilized include, e.g., medical diagnoses, age, healthcare costs, inpatient and emergency room utilization, prescriptions.

A key step in risk stratification is the identification of high-risk patients through these divisions and then referring them to appropriate resources based on their risk levels.

Segmenting patient populations by risk using objective and subjective data to assign patients to risk levels allows primary care teams to identify individuals with specific needs and effectively manage patients with complex medical conditions and socioeconomic issues and/or challenges.[97]

There is a significant opportunity for unconscious and/or conscious bias to arise in this process. Health IT Advisors will want to help practices think through these potential biases to ensure that some populations are not unfairly treated or risk stratified in a way that may lead to poorer access to needed resources. Also, it is important to acknowledge that biases in how data are recorded in the EHR may lead to biases in risk stratification.

A Health IT Advisor will help providers and practice staff understand risk stratification, generate accurate quality reports, and identify patients who require more coordinated care and more frequent visits.

## 9.1 Identification of High-Risk Patients

Data utilized to identify a patient’s risk include diagnosis, inpatient and emergency room utilization, emergency room visits, biometric data (e.g., blood pressure, age), and test results. Patients vary widely in the number of services required based on medical, behavioral, and social complexities. Risk stratification assists providers and support staff by assigning a numeric or categorical (low, high, severe) risk level to better allocate limited resources, anticipate needs, and more proactively manage their patient populations.[98]

SDOH, such as income or educational level, are also risk-stratification factors as they can affect healthcare access and utilization. SDOH include the conditions in which people live, learn, work, and play, which in turn affect a wide range of health and quality-of-life risks and health outcomes.

Depending on a clinic’s EHR and other health IT resources, a Health IT Advisor may be able to leverage the EHR and available tools/instruments to help a clinic do the following, for example:

- Obtain electronic notifications of inpatient and emergency visits and track the numbers of these visits
- Monitor the timeliness of a follow-up visit after hospitalization or an emergency-department encounter and/or prompt the provision of follow-up care with, e.g., appointment reminders
- Assist with workflows to receive data directly from acute care settings (such as lab results, chief complaint, vital signs)
- Capture and use SDOH data in EHRs in a standardized manner.

## 9.2 Health and Social Factors (Social Determinants of Health)

As discussed in Section 6, having clinics seek to manage behavioral and social needs in their EHRs is a relatively new, but growing, part of primary care. Health IT Advisors can assist clinics in creating new workflow processes and helping with EHR configuration to ensure that necessary data are being captured in structured data fields.

Integration of SDOH data into EHRs offers great potential for improved care and health. This includes a better understanding of the influence of community-driven characteristics on health (i.e., the conditions in which people live, learn, work, and play, noted above); improved connections between providers of medical care and community services; and a chance to treat the “whole patient.”[99] Individual health status is affected by inherited diseases and conditions that require medical care, and the prevalence of such conditions may differ by sex, age, race and ethnicity, employment status, and other factors.[99]

Increased utilization of healthcare services may not always correlate to a greater need for care. Many factors affect healthcare utilization independently of need and reflect differences among population groups. Some of these factors relate to biologic or environmental differences among groups, such as disproportionate residence in polluted environments, access to healthful food and adequate housing, and education associated with effective use of healthcare.[100] Others are related to differences in access, such as health insurance coverage or income needed to obtain services, ease of obtaining services, and discriminatory practices of providers.[100]

SDOH may include health literacy, education, employment, functional status (i.e., ability to complete activities of daily living), and even quality of sleep. Sleep deficiency can lead to physical and mental health problems, injuries, loss of productivity, and even a greater risk of death. In practice, it is vital to assess determinants that may help to understand socioeconomic status (and in turn health status). These include transportation availability, medication and food insecurity.[101] Screenings for smoking, depression, substance use, and anxiety are also included in this category. The Health IT Advisor can help practices develop and implement methods and workflows for capturing this important information, and then for utilizing it to improve quality of care.

## 9.3 Diseases and Risk-Stratification

Chronic diseases that influence resource allocation, healthcare costs, and overall outcomes may include cancers, heart disease, chronic obstructive pulmonary disease (COPD), asthma, diabetes, hypertension, obesity, depression, and other mental health conditions. When a patient has more than one disease (multiple comorbidities), risk for adverse health outcomes and elevated costs increases substantially.

A patient’s risk level is in part determined by the number of conditions they have. While practices can have slightly different “cut-offs” for different risk groups, in general, the highly complex group will include patients with six or more chronic conditions. The high-risk group will include patients with condition counts in the range of four-five. The rising-risk group will include those with two-three conditions. Patients with either zero or one selected conditions will comprise the low-risk group[102] (see Exhibit 53). Once the number of patients in each category is calculated, this data can be used to re-allocate patients to other providers to help maintain equitable distribution of higher risk patients in a practice, and/or to help patients in need access higher levels of or more specialized care.

Algorithms and other formula-based tools can risk stratify based on disease severity, functional status, and other factors such as SDOH. Bias can be unintentionally “baked in” to algorithms and related instruments, so it is important to continually seek to identify and eliminate it.

Uniform Data System (UDS) reporting (https://bphc.hrsa.gov/sites/default/files/bphc/datareporting/pdf/2021-uds-manual-tables.pdf) [103] for the Health Resources and Services Administration (HRSA) is used in federally qualified health centers (FQHCs). The National Association of Community Health Centers (NACHC®) uses the groupings of diagnosis codes shown in Exhibit 52 in assigning an individual patient risk level.

Exhibit 52 Uniform Data System Diagnostic Categories and Corresponding ICD-10-CM Codes [102]

Uniform Data System High-Risk Conditions | Applicable ICD 10-CM CODE^1^
Cancer (abnormal cervical findings) | C53-, C79.82, D06-, R87.61, R87.629, R87.810, R87.820
Heart Disease | 101-, 102- (exclude 102.9), 120- through 125-, 127-, 128-, 130- through 152-
Chronic Obstructive Pulmonary Disease | J40- through J44-, J47-
Asthma | J45 codes
Diabetes | E08- through E13- O24- (exclude O24.41-)
Hypertension | I10- through I16-
Obesity | E66-, Z68- (exclude Z68.1, Z68.20 through Z68.24, Z68.51, Z68.52)
Depression | F30- through F39-
Other mental disorders | F01- through F09- (exclude F06.4), F20- through F29-, F43 through F48- (exclude F43.0 and F43.1),; F50- through F99- (exclude F55-, F84.2, F90-, F91-, F93.0, F98-), 099.34 R45.1, R45.2, R45.5, R45.6, R45.7, R45.81, R45.82, R48.0

Table included with permission. © National Association of Community Health Centers, Inc., 2019

As presented in the National Association of Community Health Centers’ Population Health Management: Risk Stratification Action Guide (https://www.nachc.org/wp-content/uploads/2022/01/PHM_Risk-Stratification-AG-Jan-2022.pdf), the following four steps will provide a basic risk-stratification score [102]:

- Step 1: Generate a List of the Provider’s Patient Panel. This list should include not only patients who come in for care, but also patients assigned to the provider from healthcare institutions and payers.
- Step 2: Sort Patients by Condition: You can use the Uniform Data System (UDS) codes in Exhibit 52 to identify high-risk conditions co-morbidities or a custom list that is appropriate to your patient population.
- Step 3: Stratify Patients to Segment the Population into Target Groups: Start by using the method of “condition counts” (the number of conditions per patient) illustrated in Exhibit 53.
- Step 4: Design Care Models and Target Interventions for Each Risk Group: Each cohort (highly complex, high-risk, rising-risk, and low-risk) should be matched to a care model that meets their needs.

Exhibit 53 Example of Condition Counts Used to Establish a Risk Level

Risk Level | Number of Conditions
Highly complex | 6 or more
High-risk | 4-5
Rising-risk | 2-3
Low risk | 0 or 1

A different risk model (https://www.aafp.org/fpm/2019/0500/fpm20190500p21-rt1.pdf) developed by the American Academy of Family Physicians (AAFP) uses both diagnosis codes and healthcare utilization across varied care settings. This can be considered a more complex model and may require additional data not found in an EHR to apply in the clinic (utilization is often derived from payer claims).

Some EHRs (and many population health platforms) offer automated algorithms to assign risk scores, but clinics may use a manual approach or a hybrid method when stratifying their patient population or provider panels. As noted above, if using automated algorithms, transparency is vital as is seeking to ensure that bias is not thereby introduced.

Practices may require assistance from Health IT Advisors for configuring health assessments, scoring algorithms, and incorporating CDS into the EHR.[97] Custom programming requires proficient health IT skills and most likely assistance from the EHR vendor, which may incur additional costs to the provider.

## 9.4 Implementing Risk Stratification in Practices

Daily staff huddles include a review of objective and subjective data for all patients for the current or next day as well as for the coming weeks and months. Huddles promote discussion among team members and promote valuable information for assignment of risk scoring that brings vital patient information to the attention of the care team.

Huddles can include a brief online or paper chart audit as well as review of any inpatient utilization or outpatient referrals in between visits. This can be useful to pre-stratify patients prior to their visit to help the care team assess patient needs according to risk level. Visit efficiency can be improved if care resources and needs are identified prior to the health encounter.

Some tips for supporting clinics in this work include:

- Include the entire team when assigning risk levels
- Use daily huddles and weekly team meetings to discuss patient risk scores
- Adjust risk levels as the patient’s situation changes or based on new information from other sources such as inpatient/ER admissions or patient-reported data; consider whether “missing” patient data could impact assessment of risk level
- Reassess individual risk levels regularly as they tend to change over time
- Document important data in standardized data fields to best utilize EHR-generated data.

There are many risk models that will support a clinic’s efforts to assess and stratify their panels. Health IT Advisors can explore additional methods like the ones shown below to help find the best match for practices they support.

More Risk Stratification Methods

- Health IT Advisors can help practices develop workflows that reinforce patient data entry of health history changes into the patient portal and incorporating new patient-generated data into point of care visits. Workflow changes include asking patients during triage if they have had any ancillary treatments, appointments, or admissions since their last encounter. This self-reported information is then entered into the EHR.
- Hierarchical Condition Categories (HCCs): Part of the Medicare Advantage Program for CMS, HCC (https://www.cms.gov/Medicare/Health-Plans/MedicareAdvtgSpecRateStats/Risk-Adjustors.html) contains 70 condition categories selected from ICD codes and includes expected health expenditures.
- Adjusted Clinical Groups (ACG): Developed at Johns Hopkins University (https://www.hopkinsacg.org/), ACG uses both inpatient and outpatient diagnoses to classify each patient into one of 93 ACG categories. It is commonly used to predict hospital utilization.
- Elder Risk Assessment (ERA): For adults over 60, ERA (https://www.ncbi.nlm.nih.gov/pubmed/21441764) uses age, gender, marital status, number of hospital days over the prior two years, and selected comorbid medical illness to assign an index score to each patient.
- Chronic Comorbidity Count (CCC): Based on the publicly available information from the Agency for Health care Research and Quality (AHRQ)’s Clinical Classification Software, CCC (https://www.ncbi.nlm.nih.gov/pubmed/21473661) is the total sum of selected comorbid conditions grouped into six categories.
- Minnesota Tiering (MN): Based on Major Extended Diagnostic Groups (MEDCs), MN Tiering (https://www.health.state.mn.us/facilities/hchomes/legreport/docs/hch2016report.pdf) groups patients into one of five tiers: Tier 0 (Low: 0 Conditions), Tier 1 (Basic: 1 to 3), Tier 2 (Intermediate: 4 to 6), Tier 3 (Extended: 7 to 9), and Tier 4 (Complex: 10+ Conditions).

[104]

1 “The select list of conditions match HRSA’s UDS 2021 Health Center Data Reporting Requirements (https://bphc.hrsa.gov/sites/default/files/bphc/datareporting/pdf/2021-uds-manual.pdf) for Table 6A, including the diagnostic categories and applicable ICD-10-CM codes on pages 77-78. Selected diagnoses do not represent the full range of diagnoses or services captured in Table 6A, nor offered by a health center, but were selected to represent significant high-cost, high-burden conditions prevalent among health center patients. Using the above as a starting point, health centers can add/subtract conditions based upon local health conditions and clinical priorities.”