# Section 8 Review of Clinical Quality Measures

Clinical quality measures (CQMs) are used to measure and track the quality of healthcare services. They can range from simple metrics devised by an individual clinician to curated collections of related measures. For example, Exhibit 42 includes measure sets used by CMS, Health Resources and Services Administration (HRSA), and commercial payers to assess and compare clinical quality.

An example of a “homegrown” measure is presented at the end of this section and in the Diabetes Case Study presented in Section 6.

Common Quality Measures for Quality Improvement

Standardized CQMs from many sources are used by various stakeholders to compare the quality of providers, calculate reimbursement and incentives in value-based payment, and to rank payers by quality (the HEDIS 5-Star ratings for commercial Medicare Advantage Plans use CQMs to determine performance on a range of measures). Some examples of common CQMs are shown in Exhibit 42, but by are by no means the only options available for QI projects.

Exhibit 42 Examples of Clinical Quality Measures

Clinical Quality Measure | Domains or Examples
CMS Quality Payment Program Measures for Medicare (MIPS); Used by CMS to report quality data for Medicare incentive and value-based payment programs | - Patient and Family Engagement; - Patient Safety; - Care Coordination; - Population/Public Health; - Efficient Use of Healthcare Resources; - Clinical Process/Effectiveness; Link: https://ecqi.healthit.gov/ep-ec?qt-tabs_ep=1
Uniform Data System (UDS); Used by Federally Qualified Health Centers (FQHCs) under the U.S. Health Resources & Services Administration (HRSA) | - Diabetes Control (HbA1C > 9%, D-5.1); - Hypertension BP Control (BP < 140/90, HDS-12); - Access to Prenatal Care (MICH-10); - Childhood Immunizations (IID-8); - Cervical Cancer Screening (C-15); - Colorectal Cancer Screening (C-16); - Dental Sealants for Children (OH-12.2); - Low Birth Weight (MICH-8.1); Link: https://bphc.hrsa.gov/program-opportunities/sac/uds-measures-and-hp-goals
Healthcare Effectiveness Data and Information Set (HEDIS); Used by government and commercial payers to measure clinical quality for value-based payment and comparative provider ratings. | - Effectiveness of Care; - Access/Availability of Care; - Experience of Care; - Utilization and Risk Adjusted Utilization; - Health Plan Descriptive Information; - Measures Reported Using Electronic Clinical Data Systems; Link: https://www.ncqa.org/hedis/

## 8.1 Types of Clinical Quality Measures

Quality measures are generally divided into three types using a quality model first developed by Avedis Donabedian[93]:

- Structural Measures evaluate healthcare providers capacity, systems, and processes to provide quality healthcare. For example:
  ○ The use of a certified electronic medical record
  ○ The number or proportion of board-certified physicians within a healthcare organization
  ○ The ratio of providers to patients
- Process Measures evaluate healthcare providers use of evidence-based processes to maintain or improve health, typically reflecting generally accepted recommendations for clinical practice, such as those developed by the United States Preventive Services Task Force (USPTF). Most healthcare quality measures used for public reporting are process measures. For example:
  ○ The percentage of people receiving preventive services (such as mammograms or immunizations).
  ○ The percentage of people with diabetes who had their blood sugar tested in a timely manner.
- Outcome Measures reflect the impact of the healthcare service or interventions on the health status of patients. For example:
  ○ The percentage of patients who died as a result of surgery (surgical mortality rates).
  ○ The rate of surgical complications or hospital-acquired infections.

## 8.2 Finding Clinical Quality Measures for Use in Quality Improvement

Common CQMs, however, may not include what you need to measure and track quality performance for a given QI project. This leaves two options: find another quality measure or create a custom measure of your own.

For searching a comprehensive database of CQMs, NQF provides a web search tool called the Quality Positioning System (https://www.qualityforum.org/QPS/QPSTool.aspx#qpsPageState=%7B%22TabType%22%3A1,%22TabContentType%22%3A1,%22SearchCriteriaForStandard%22%3A%7B%22TaxonomyIDs%22%3A%5B%5D,%22SelectedTypeAheadFilterOption%22%3Anull,%22Keyword%22%3A%22%22,%22PageSize%22%3A%2225%22,%22OrderType%22%3A3,%22OrderBy%22%3A%22A).

Measures can be searched using multiple criteria and undergo a rigorous review process before they are endorsed by NQF. The measure identifier assigned by NQF is widely used to reference specific quality measures (for example, NQF 0018 measures blood pressure control in patients with hypertension).

Exhibit 43 Search Screen of the NQF CQM Database[94]

Screenshot of the Search screen for the NQF CQM Database.

Note: Learning to find and use standardized CQMs is a core QI skill. To learn more, please see the Module 13: Measure and Benchmarking Clinical Performance (https://www.ahrq.gov/sites/default/files/wysiwyg/ncepcr/tools/PCMH/pcpf-module-13-measuring-and-benchmarking.pdf) in the AHRQ Primary Care Practice Facilitation Curriculum and the Practice Facilitation Training Module Standardized Quality Measures (https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation/modules/index.html#measures).

## 8.3 Anatomy of a Clinical Quality Measure

A CQM uses four parameters to calculate a ratio representing the performance rate: an initial patient population (IPP), a denominator, a numerator, and exclusions/exceptions. The rate is expressed as a percentage, for example: Clinic ABC performed at 89.3% on Controlling Hypertension (CMS 165, NQF 0018)[95] for the measurement period January 1, XXXX to December 31, XXXX.

If you are new to using CQMs, it may be difficult to conceptualize what the performance rate is actually saying about how well (or poorly) a provider or clinic is meeting a structural, process, or outcome metric.

It helps to visualize a CQM as a series of concentric circles. In Exhibit 44, the outer circle defines the total initial patient population of interest. From this group, exclusions and exceptions are subtracted to generate a denominator. The numerator is the inner circle including only patients with (or without) specific characteristics of interest. The CQM performance rate is represented as a percentage from the simple calculation below.

Performance rate (%) = (Numerator)/ (Initial Population - (Exceptions + Exclusions))

Note: A worked-through example of a CQM calculation is shown below in section 8.5.

Exhibit 44 Illustration of the Components of a CQM calculation[96]

This illustration of the components of a clinical quality measure (CQM) calculation shows a blue circle (the numerator) with a hole in it (numerator exclusions showing through to a larger green circle [denominator] underneath). The green circle has two holes in it (denominator exclusions) showing through to an even larger red circle underneath that (initial population).

## 8.4 Clinical Quality Measure Specifications

CQM developers (and there are many) are responsible for clearly and unambiguously defining which individuals fall into each circle by creating detailed specifications. Before choosing a CQM for a QI project, Health IT Advisors should clearly understand what a final performance rate is (and is not) telling you about actual quality by carefully reading through the specifications.

Detailed specifications, lists of code values (value sets), and logic diagrams can be found online in many places, including the NQF Quality Positioning System (described above) and the online eCQM Clearinghouse (https://www.cms.gov/Regulations-and-Guidance/Legislation/EHRIncentivePrograms/eCQM_Library) for the measures used by CMS for MIPS and other programs.

For example, Exhibit 45 shows an excerpt of the CMS specification CQM for Controlling High Blood Pressure (CMS 165v9, NQF0018). This measure could be summarized as follows: “Percentage of patients 18 - 85 years of age who had a diagnosis of hypertension and whose blood pressure was adequately controlled (< 140/90 mmHg) during the measurement period.” It will be important to understand denominator exclusions here (e.g., patients who have not been seen in the last year) to be able to accurately interpret final results.

Exhibit 45 Specification Excerpt for Controlling High Blood Pressure (CMS 165v9)[95]

CQM Component | Specification
Measure Description | Percentage of patients 18-85 years of age who had a diagnosis of hypertension overlapping the measurement period or the year prior to the measurement period, and whose most recent blood pressure was adequately controlled (<140/90mmHG) during the measurement period.
Initial Population | Patients 18-85 years of age who had a visit and diagnosis of essential hypertension overlapping the measurement period or the year prior to the measurement period.
Denominator Statement | Equals initial population
Denominator Exclusions | Patients with evidence of end state renal disease (ESRD), dialysis or renal transplant before or during the measurement period. Also exclude patients with a diagnosis of pregnancy during the measurement period.; Exclude patients whose hospice care overlaps the measurement period.; Exclude patients 66 and older who are living long term in an institution for more than 90 consecutive days during the measurement period.; Exclude patients 66 and older with advanced illness and frailty because it is unlikely that patients will benefit from the services being measured.
Numerator Statement | Patients whose most recent blood pressure is adequately controlled (systolic blood pressure <140mmHg and diastolic blood pressure <90mmHg) during the measurement period.
Numerator Exclusions | Not applicable
Denominator Exceptions | None

## 8.5 Example: Working Through a Clinical Quality Measure

There will be situations where an existing CQM cannot be found or does not meet the needs of a particular project. This example illustrates a hypothetical CQM constructed from the bottom up.

Dr. Chavez wants to answer the question: “What percentage of my patients have high blood pressure?” The following steps show how this clinical question could be converted to a very basic CQM.

Dr. Chavez: “How many of my patients have with a diagnosis of hypertension?”

The denominator for this example will be the total number of individuals in the doctor’s panel. The numerator would be the total number of patients from the denominator found to have a diagnosis of hypertension. Note this assumes that Dr. Chavez was explicit about how “diagnosed with hypertension” will be determined for the new metric (“real” measure specifications include all of these details).

150 patients with hypertension / 3000 patients = 0.05 × 100 = 5.0%

Dr. Chavez: “Ok, but can we just run it for patients I’ve seen in the office in the past year?”

Now, we would adjust the initial population in our specification to include only patients seen by Dr. Chavez within the last year.

110 patients with hypertension / 2000 patients = 0.055 × 100 = 5.5%

Dr. Chavez: “Can we exclude patients with renal disease or pregnancy, two conditions that affect blood pressure?”

In this last step, we will add an exclusion to remove patients with pregnancy and/or renal disease from the denominator. Once again, the numerator may or may not be lower after removing the excluded individuals.

85 patients with hypertension / (2000 patients - 100 excluded patients) = 0.045 × 100 = 4.5%

From the Dr. Chavez example, we can see that, as our asks of the data become more complex, so does the reporting burden. For this reason, there is always the underlying question of whether or not there is an existing quality measure that fits an organization’s needs or is there a need to create a measure and subsequent report.

Continuing this example, a Health IT Advisor might find that Dr. Chavez’s EHR has a CQM called “Controlling Hypertension” (CMS165, NQF 0018) built into its dashboard for MIPS reporting (this CQM is described above).

[underlined: Note:] Clinics are frequently unaware of which measures their EHR may support “out of the box.” In Section 2 we discuss how to search for measures supported by specific EHRs.

## 8.6 Tips for Presenting Clinical Quality Measure Data

Health IT Advisors should not only be adept at finding, extracting, and analyzing data on quality performance, but also skilled at presenting these data to diverse audiences. It is not unusual for a single project to incorporate more than one CQM to establish baseline performance, monitor progress, and evaluate success. (See the AHRQ Practice Facilitation Training Module Presenting Performance Data (https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation/modules/index.html#data)).

Below, we review tips for visually organizing CQM performance rates using tables and graphs and discuss how the best approach will depend on your audience.

### Option 1: Describing CQM data in text

CQM data can be presented in text by describing the measures used, references to standard specifications (if used), the measurement period, and the performance rate. For example:

“…Between January 1, XXXX and December 31, XXXX, Clinic ABC achieved a performance rate of 50.0% on Controlling Hypertension (CMS 165, NQF 0018). The rate was extracted from the clinic’s EHR (DocuWare 4.5) and includes all providers and all payers.”

It is often useful to expand this to include the numerator, denominator, and exceptions/exclusions to provide context to the audience.

“…a performance rate of 50.0% (Initial population 210, Numerator 100, Denominator 200, Exclusions 10) on…”

Finally, you should include a benchmark or target performance rate if it is relevant.

“This compares with the project goal of 60% over the same time period.”

### Option 2: Presenting CQM data in a table

Using text to summarize complex data rapidly becomes cumbersome for both the author and the reader. A second option uses a simple data table to present CQM data like the one shown below.

Exhibit 46 Simple Example of a Data Table Showing CQM Performance

Measure Name | Measure Co.. | Total | Den | Num | Escl | Except | Rate
Controlling High Blood Pressure | CMS165 | 456 | 456 | 350 | 5 | 0 | 77.61%
Diabetes: Hemoglobin A1c (HbA1c) Poor Control (>9%) | CMS122 | 93 | 93 | 25 | 0 | 0 | 26.88%
Preventive Care and Screening: Screening for Depression and Follow | CMS2 | 3,097 | 3,097 | 1,133 | 850 | 0 | 50.42%
Preventive Care and Screening: Tobacco Use: Screening and Cessatio.. | CMS138A | 2,158 | 2,158 | 1,904 | 0 | 0 | 88.23%
Weight Assessment and Counseling for Nutrition and Physical Activity for Children and Adolescents | CMS155A | 668 | 668 | 594 | 0 | 0 | 88.92%
Weight Assessment and Counseling for Nutrition and Physical Activity for Children and Adolescents | CMS155B | 668 | 668 | 536 | 0 | 0 | 80.24%
Weight Assessment and Counseling for Nutrition and Physical Activity for Children and Adolescents | CMS155C | 668 | 668 | 533 | 0 | 0 | 79.79%

Tables are easy to create and allow for some visual flourishes to aid the viewer like ranking the data, color coding, and even links to the raw data files (be careful that these links do not expose PHI).

### Option 3: Using graphs and other data visualizations

Graphs and other data visualizations are often the best way to present CQM data when you want to highlight change over time, differences between groups, or comparison to a benchmark or target performance rate.

The most basic visualization for CQM data is the classic run chart, showing performance over time. Exhibit 47 shows a generic example of a run chart. Note that the timing of specific interventions is highlighted on the timescale showing a possible relationship to improved performance.

Exhibit 47 Generic Example of a CQM Run Chart

Sample CQM Run Chart - line graph shows three process changes over Time.

Exhibits 48 and 49 illustrate a more complex use of a time-oriented visualization from the MHS Diabetes Case Study presented in Section 6. Exhibit 48 shows how a composite performance measure was used to plot changes in the quality of diabetes care. Not only is the trend easy to see, but the difference in performance between MD-centric measures (process) and Patient-centric (outcomes) raises some intriguing questions. Exhibit 49 yields even more information by combining a time series, performance rates for five different CQMs, and highlights the timing of eight specific EHR interventions.

Exhibit 48 CQM Visualization from the MHS Diabetes Case Study (Example 1)[64]

Graphic above included from: https://www.himss.org/sites/hde/files/media/file/2021/01/20/metrohealth-davies-diabetes-management-case.pdf.

Sample line graph of the visualization explained in text above.

Exhibit 49 CQM Visualization from the MHS Diabetes Case Study (Example 1)[64]

Graphic above included from: https://www.himss.org/sites/hde/files/media/file/2021/01/20/metrohealth-davies-diabetes-management-case.pdf.

Sample line graph with timeline explained in text above.

The examples above highlight the time element; however, for straight comparisons between groups or individuals “old school” bar graphs and pie charts may be a good choice for some audiences. Exhibits 50 and 52 show the performance of several CQMs presented in both formats.

Exhibit 50 CQM Performance Presented as Bar Chart

Sample bar chart as explained in text above

Exhibit 51 CQM Performance Presented as Pie Chart

Sample pie chart as explained in text above

## 8.7 Conclusion

CQMs are important tools for measuring and tracking the quality of healthcare services. They can range from simple individual metrics devised by a clinician to curated and broadly applicable collections of related measures. It is also important to keep in mind the fact that CQMs have directionality, which varies among measures: i.e., a “good” score on one CQM will be a high number, while a “good” score on another CQM will be a low number. Also keep in mind that CQMs can change, so be sure when presenting time series data that the same version of the measure is being used. EHR updates may automatically include the most recent version of eCQMs. Choosing the best way to visualize CQM data is an art. Experienced data analysts work from a large palette of techniques and always target data presentations to the audience. For example, a chart created to show providers how they compare to each other would be very different from one created for a scientific publication. We have included a primer for creating data visualizations in Appendix D of this handbook.