# Section 7 Beyond the EHR: Alternative Data Sources for Quality Improvement

EHRs are the most common and obvious source of data for quality improvement projects. However, EHRs may not contain information needed for a specific QI project and Health IT Advisors may need to help practices look beyond their EHR for data.

In this section, we review three alternative sources of QI data:

- Payer claims data
- Databases external to EHRs, often called registries, and the growing number of sophisticated third-party population health platforms that can consume and analyze both EHR and claims data
- Health information exchanges (HIEs) that aggregate clinical data for care coordination across multiple EHRs, clinics, and health systems.

## 7.1 Using Claims Data for Quality Improvement

While the proliferation of EHR software has led to an increase in the use of eCQMs (see Section 8), the use of health insurance claims as a resource for quality measurement, research, and policy analysis is well established.[74–79] Claims data are collected routinely at each encounter for the purpose of reimbursement and include dates of service, demographics, diagnoses, procedures, charges, and more. Every medical practice is therefore generating information with potential value for QI projects during the billing process.

When considering how to leverage claims data for QI, it is important to recognize limitations up front. Relying on information used primarily for reimbursement can introduce measurement bias, [80] as the traditional fee-for-service model was not designed to incentivize comprehensive clinical documentation. Claims data lack the rich contextual information typically present within the patient’s medical record, such as free-text notes, provider orders, problem/medication/allergy lists, and test results. Additionally, practices are often limited to what has been generated internally, as claims data from other providers of care, suppliers, or pharmacies is typically unavailable without special effort.

Despite these limitations, claims data can be valuable alone or as a complement to other data sources for QI. They benefit from being readily available and represented using standard formats and codes that enable reporting on populations meeting specific criteria. For practices without an EHR, claims data can be used to identify patients eligible for measures of interest and calculate performance rates that can be validated through chart audit where appropriate. For practices using EHRs to report eCQM, claims data can fill gaps where preferred measures are unavailable, inaccurate, or unreliable.

Claims data are also central to quality measurement for health plans. The Healthcare Effectiveness Data and Information Set (HEDIS), used by more than 90 percent of payers to assess provider performance, contains over 90 quality measures driven primarily by claims. [81] CMS accepts Quality Data Codes (QDC) to support claims-based reporting of quality actions for programs such MIPS. [66] As payers move forward with value-based contracting, transparency regarding how claims data are used to measure patient outcomes will promote provider accountability and increase the importance of billing and coding best practices.

Health IT Advisors can support the use of claims data in QI initiatives by:

- Understanding what data elements are included in claims
- Recognizing the importance of coding standards in claims-based quality measurement
- Educating practices on how payers use claims data to evaluate quality
- Facilitating the design and implementation of claims-based quality projects

### What Data Elements Are Found in Claims?

Claims for non-institutional providers (i.e., individual professionals and practices) include a number of data points relevant to quality measurement, such as:

- Provider information:
  ○ National Provider Identifier (NPI)
  ○ Location
- Patient and insured’s information:
  ○ Health plan (type, name, ID number, group number)
  ○ Demographics (date of birth, sex)
  ○ Contact information (address, phone number)
  ○ Related hospitalization
- Encounter information:
  ○ Date(s) of service
  ○ Diagnosis code(s)
  ○ Procedure/service code(s)
  ○ Place of service
  ○ Charged amounts

Claims for institutions (e.g., hospitals, skilled nursing facilities, long-term care facilities) include similar provider, patient, and encounter details as well as unique fields such as:

- Admission type and source
- Discharge status
- Condition code(s)
- Occurrence code(s) and spans
- Value code(s)

These data points are sufficient for quality measurement basics such as:

- Establishing populations based on patient and encounter characteristics
- Setting reporting periods based on dates of service
- Identifying patients seen by each provider during the reporting period
- Assessing delivery of recommended services
- Linking of quality measures to cost

However, and importantly, there are several data points that are limited or unavailable from these claims that limit the scope of quality measurement. These include:

- Encounter notes
- Vital signs
- Lab values
- Findings from screening and other procedures
- Drug code(s), name(s), and prescription detail (captured separately on pharmacy claims)
- Social determinants of health

[underlined: Takeaway:] In order to support practices using claims data in QI, Health IT Advisors must first understand what data points are available. Quality measurement projects should be designed around these criteria and their limitations.

### Claims Coding

Effective claims coding is an essential component of healthcare administration and payment. Representing diagnoses, procedures, and services as alphanumeric codes provides the basis for clearinghouses to screen claims data and submit to payers for reimbursement. Insurance contracts define negotiated rates for procedures and treatments and rely on codes to adjudicate claims and authorize payment to providers based on the applicable fee schedule. Adherence to coding best practices offers the secondary benefit of richer claims data for use in QI.

Under HIPAA, DHHS adopted specific code sets for diagnoses and procedures used in all transactions. Key code sets used for medical claims include:

- International Classification of Diseases (ICD-10) for diagnoses [82]
- Current Procedural Terminology (CPT)[83]
- Healthcare Common Procedure Coding System (HCPCS)[84]

Applying these codes for optimal reimbursement does not necessarily result in claims data sufficient for QI. For example, providers may not address all patient diagnoses during an encounter and may deliver services or procedures that are not reimbursable by payers, and providers will document some diagnoses as a prerequisite for ensuring that payers will cover the costs of more complicated exploratory laboratory tests and imaging. While failing to include this information will not impact payment, it can result in missing data otherwise needed to calculate performance metrics of interest.

Addressing this barrier may require expanding both the amount and nature of codes compared to what is required for payment. For diagnoses, comprehensive ICD-10 coding supports stratification of populations based on factors such as comorbidities, severity of illness, or anatomic location. For procedures, including “unbillable” CPT and HCPCS codes (charged at $0.00 or $0.01) allows tracking services relevant to quality measurement regardless of payment.

To the extent claims coding for QI adds burden to clinicians and staff without direct reimbursement from a payer’s fee schedule, practices should select measures recognized as intrinsically valuable to patient care to justify the resource cost. Another factor to consider is which measures have downstream benefit such as rewards in pay-for-performance programs or quality rating systems made publicly available to consumers.[85]

Takeaway: The feasibility of using claims data for QI is dependent on how a practice uses standard code sets for diagnoses and procedures. Health IT Advisors can examine coding practices to assess whether data required for analysis are available and provide education on expanding or enhancing use of codes where necessary.

### Claims Data for Quality Measurement by Payers (HEDIS and CMS)

While payers are expanding the use of clinical data from EHRs, they continue to rely on claims data as a primary source for evaluating practice performance. The Healthcare Effectiveness Data and Information Set (HEDIS) is one of the most widely used performance improvement tools, with 191 million people enrolled in health plans that report results primarily by way of claims analysis. The National Committee for Quality Assurance (NCQA) collects HEDIS measures from health plans across six domains of care:

- Effectiveness of Care
- Access/Availability of Care
- Experience of Care
- Utilization and Risk Adjusted Utilization
- Health Plan Descriptive Information
- Measures Reported Using Electronic Clinical Data Systems

Many HEDIS measures are reported entirely through claims and depend on accurate coding of diagnoses and procedures.[86] Health plan tip sheets, which can be a useful tool for educating providers on the link between claims and quality measurement, may be publicly available on the internet or upon request.[87–89] Exhibit 38 is an example excerpted from an educational resource created by Aetna, which identifies coding tips for the Breast Cancer Screening measure along with definitions and tips for providers seeking to improve their performance. [86–89]

Exhibit 38 Example Health Plan Tip Sheet [89]

HEDIS Measure Definitions | What You Can Do | Coding Tips
BCS - Breast Cancer Screening; Women 52-74 years of age with one or more mammograms within the last 2 years (starting at age 50). | Educate women regarding the benefit of early detection of breast cancer through routine mammograms; Encourage mammography to all women who are within measure age group.; Submit the appropriate mastectomy code to exclude women from this measure if it is part of their history | Breast Cancer Screening Codes; CPT Codes: 77055-77057, 77061-77067; HCPCS G0202, G0204, G0206 UB Rev Codes 0401, 0403; Exclusions:; Bilateral Mastectomy; ICD-10CM : Z90.13 (history of bilateral mastectomy); * See exclusion note on last page

CMS’s MIPS, a participation path within Medicare’s Quality Payment Program (QPP), is another national payer program that relies in part on claims to assess provider quality. [90] While Medicare has proposed to phase out MIPS claims reporting in favor of digital quality measurement by 2025, it remains a popular option among small practices that have not adopted EHR software or that are using technology that is not certified for MIPS quality reporting. Furthermore, administrative claims will continue to be used for certain quality and cost metrics, such as those related to hospitalizations and other episodes of care.

Reporting MIPS quality measures through the Medicare Part B claims submission method is similar to reporting HEDIS measures through claims. Each measure has specifications that identify the measure type, description, and instructions along with detailed criteria for establishing the denominator (eligible population) and using claims codes for the numerator (population satisfying the measure), exceptions, or exclusions (for more about measuring clinical quality, see Section 8 of the handbook).

Exhibit 39 shows how Medicare identifies denominator-eligible patients for the MIPS measure Age-Related Macular Degeneration: Dilated Macular Examination using data points included on the claim [date of birth (DOB), date of service, ICD-10, CPT].

Exhibit 39 Example Denominator-Eligible Patient Identification

Screenshot of the sample explained in text above.

Each claim that meets denominator criteria is then analyzed for numerator criteria, which depend on the application of quality data codes (sometimes referred to as “G codes” because many begin with the letter G) to identify whether recommended quality actions were taken and why. Exhibit 40 shows numerator quality data codes options for the AMD measure.

Exhibit 40 Numerator Quality Data Codes Options for the AMD Measure

Sample data codes as explained in text above.

Takeaway: Whether or not a practice is using claims data for QI, it is likely their payers are doing so. Health IT Advisors equipped with an understanding of the mechanisms used in existing programs such as HEDIS and MIPS can offer educational resources and guidance on proactive engagement with payers on value-based care initiatives.[91]

### Facilitating Claims-Based QI Projects

Claims-based performance feedback can provide valuable opportunities for QI, but leveraging claims data effectively in QI can demand significant time and resource investments. [92] Designing an appropriately scoped project depends on assessing questions such as:[92]

- What quality performance metrics are most important to our practice/payers?
- Can the data needed to measure performance be collected on claims?
- Are these data collected reliably and consistently? If not, what changes are required to do so?
- Are these data available internally? If not, are external data accessible (e.g., provided by payers)?
- In what format and by what means can we retrieve claims data?
- Do we have the technical expertise to organize and analyze claims data?
- How will our practice use these data for continuous improvement?
- Is the project focused at the population or individual level?

Health IT Advisors should connect with the claims/coding specialist at the clinic, as possible, before trying to answer the above questions on their own. Health IT Advisors with an understanding of the limitations and potential uses of claims data can more effectively support practices seeking to answer these questions and use the answers to implement successful QI initiatives.

## 7.2 Registries, Population Health Platforms, and Health Information Exchanges

Providers within a single organization will depend on their EHR to support the health services they provide (physical, behavioral, and more recently, social). These organizations range in size from small solo physician’s offices to giant national healthcare systems operating one or more EHRs. The fragmentation caused by EHRs acting as islands of information, or “data silos,” make it difficult to measure quality performance across larger populations, regions, or even nations.

Registries and Population Health Analytics Platforms have emerged as a way of consolidating fragmented information by “consuming” key data elements from the EHRs (and often payer claims) of individual organizations to create a person-centered data pool for research and population health. Related work is being done by Coordinated Registry Networks or “CRNs,” such as that developed by the FDA and National Library of Medicine (NLM) focused on women’s health; information about that effort is available here (https://www.healthit.gov/topic/scientific-initiatives/pcor/coordinated-registry-network-womens-health-technologies-crn). AHRQ’s guide, Registries for Evaluating Patient Outcomes: A User’s Guide: 4^th^ Edition (https://effectivehealthcare.ahrq.gov/products/registries-guide-4th-edition/users-guide), is an important resource on this topic.

By contrast, HIEs exist to aggregate and distribute patient data through interfaces to EHRs, or direct access through dedicated HIE portals.

These are imprecise distinctions. For example, many HIEs offer both registry and population health analytics as a sort of trifecta of data aggregation.

### Two Meanings for “Health Information Exchange”

You will hear the term “HIE” used in two different ways. As a noun, “HIE” refers to a specific IT platform or network that consumes and distributes clinical data from EHRs and other sources. However, as a verb it means to actively exchange clinical data between interoperable IT systems (Appendix A provides a primer on interoperability). Examples of both are shown in Exhibit 41.

Exhibit 41 Two Meanings of Health Information Exchange

Use of HIE | Meaning and Examples of This Use
HIE as a noun | - National data exchange networks; - Vendor consortiums; ○ Care Quality; ○ Common Well Alliance; ○ Sequoia Project; - State or regional health information exchanges; ○ CalRHIO (California); ○ MiHIN (Michigan); ○ Reliance eHealth Cooperative (Oregon); - Acute care admission, discharge notification systems; ○ Collective Medical; - Dedicated platforms for addressing social needs; ○ Unite Us; ○ Aunt Bertha
HIE as a verb | - Use of interoperability standards to exchange clinical data:; ○ Send and receive orders, results, and documents; ○ Send and receive immunizations, use of controlled substances; ○ Send and receive electronic care summaries [continuity of care documents (CCDs)]; ○ Send and receive electronic transition of care notifications; ○ Send and receive referrals for medical, behavioral, and social needs

### Tips for Health IT Advisors

In some respects, the aggregation pools of EHR data provided by registries, population health tools/platforms, and HIEs seem like a giant extension of the organizational EHR with silo walls torn down. There are, however, some important differences.

Some common themes, adapted from Section 7, include:

1. External data sources may provide a wide range of demographic, clinical, administrative, and financial data useful for QI:
  - Registries, population health tools, and HIEs vary widely in the scope, content, and the original sources they consume. For example, a registry hosted by a medical specialty or research organization may only incorporate specific types of data on a subset of patients.
  - Population health tools and HIEs are limited by the cost and complexity of the connections used to pull data from EHRs, claims, and other sources.
  - More sophisticated analytics platforms are often operated by health plans or commercial payers and are limited to data on their beneficiaries.
2. External data sources may provide options for reporting at least some CQMs, generate graphs and dashboards, and generate patient lists filtered by demographic and clinical parameters:
  - Population health platforms, registries, and many HIEs were built to use the data they collect to measure clinical quality and usually offer a wide assortment of CQMs.
  - EHRs are still somewhat limited in the measures they offer and the options for in-depth analysis; external data sources are often designed and built to provide sophisticated analytics beyond simple performance rates.
  - Population health tools (and some HIEs) incorporate advanced computational techniques including natural language processing (NLP), artificial intelligence (AI), and machine learning to provide sophisticated analytics capabilities. Examples include assessing group and individual health risks, generating predictive models, and (when combined with claims data) analyzing healthcare costs.
  - Just like EHRs, these platforms must capture and store data in an appropriate form, usually as structured data. Inconsistent workflows and poor data quality will lead to erroneous conclusions (see Section 2).
  - Errors and distortions can occur as information travels farther from the point of collection. Because aggregate collections of clinical data are completely reliant on feeder systems, the potential for data quality issues is multiplied compared to using a clinic EHR as a single source.
  - Issues can include technical problems with data transfer, challenges linking individual patient records across feeds, and data formatting and mapping problems. For example, HIEs that receive electronic care summaries as continuity of care documents (CCDs) may have trouble parsing out and mapping laboratory results embedded in a CCDs sent by different sources causing missing data that is difficult to detect.
3. Interventions delivered through external platforms depend on good data, consistent workflows, proper training, evidence-based design, and organizational support for success.
  - Health IT Advisors will rarely use external data sources to create and deliver interventions and instead will extract data to inform QI and target other interventions.
    ○ An exception to this is when a clinic has access to separate platforms to help aggregate and analyze their data (e.g., through an EHR vendor or by being part of a larger health system that built their own such platform).
    ○ Another exception to this is when an HIE (noun) uses HIE (verb) to send clinic notifications based on clinical events (an emergency room discharge) or a predefined data trigger (receipt of a positive COVID-19 test from a “feeder” laboratory).
  - Because external data platforms can “see” a more complete picture of an individual’s health history, they may play a larger role in directly impacting quality by delivering CDS interventions in the future.
4. External data sources are not the only health IT tool useful for QI and may not even be the best choice for a given project (see Section 6 for how EHRs may be used).
  - A clinic’s EHR will usually be the most accessible data source for a QI project. Health IT Advisors should be aware, however, of what alternatives may be available and choose the best fit for the project.