# Section 6 EHR Use Cases for Quality Improvement

This section contains a practical guide for the two major applications (or use cases) of an EHR in QI work. The first is to provide a source for the various data elements needed to inform, monitor, and evaluate a QI project (a CQM for example); the second is to act as a platform for delivering a wide range of interventions (CDS).

Choosing from the range of potential uses for an EHR can be overwhelming. For each project it is important to anticipate whether an EHR is capable of meeting the project’s needs and whether the time, resources, knowledge, and skill exist to support its use.

We begin this section with a case study that illustrates how one large health system strategically used their EHR as the cornerstone for improvements to diabetes care, both as a data source and as a platform for interventions. (Alternative data sources are addressed in Section 7.)

## 6.1 Case Study: Leveraging an EHR to Transform Ambulatory Diabetes Care

The following is a published case study from Metro Health System in Cleveland, Ohio (MHS), a large organization that leveraged their EHR in a comprehensive QI initiative to improve ambulatory diabetes care between 2007 and 2014.[64, 65]

MHS is a large organization with a robust EHR (Epic) and strong technology support. When reviewing this case study, Health IT Advisors should keep the following points in mind:

- There were eight specific EHR-related interventions deployed in phases over seven years.
- Each phase built on previous interventions in a sustained and comprehensive QI project.
- The length and scope of this project is not typical of most practice facilitation efforts.
- MHS used their EHR to improve their performance on key process and outcome measures.
- Data showed a significant improvement in measures of quality for diabetes care.

MHS introduced eight EHR interventions one after another with two evaluation points. The first was between 2005 and 2006 and the second between 2007 and 2014.

### Measuring Quality of Care for Diabetes

A difficult step in any QI project is in selecting (or creating) CQMs. MHS used data from their EHR to provide the data for nine custom-developed quality measures (five process and four outcome measures) to inform and evaluate their progress. The nine measures are included in Exhibit 31.

Exhibit 31 MHS’ Custom Developed Quality Measures

MD Centric EHR Measures | Patient centric EHR Measures
Delivery and documentation of diabetic eye and foot exam | Smoking status documented
Pneumococcal vaccination | Body Mass Index (BMI)
Monitoring or treating kidney disease | Glycemic control (A1c)
Cholesterol level for patients taking a statin drug (2005 to 2007) | Blood pressure
A1c test performed (2007 - 2014)

### EHR-based Quality Interventions

The EHR was also used as a platform to deliver eight interventions between 2007 and 2014 specific to diabetes care. These are listed below and summarized in Exhibit 32.

- One (1) intervention was a form of CDS that provided contextual alerts and notifications highlighting gaps in diabetes care (Epic calls these Best Practice Alerts, or BPAs).
- Two (4 and 6) interventions used the EHR to improve documentation of care plans and to capture eye and foot examinations as structured data.
- Four (2, 3, 5, and 8) interventions used the EHR to present tailored data to providers (using a specially developed summary screen) as a resource to engage patients with diabetes in their care planning (EHR-generated letters).
- One (5) intervention used EHR data to create comparative performance reports to spur competition and to provide individual providers with detailed information on the patients in their panel.

Exhibit 32 Introduction of EHR interventions for Diabetes Care at MHS (2007 to 2014)[64]

Chart adapted from: https://www.himss.org/sites/hde/files/media/file/2021/01/20/metrohealth-davies-diabetes-management-case.pdf.

Screenshot of a sample dashboard as described in text above.

### Discussion

There are three key lessons that Health IT Advisors can draw from how MHS leveraged their EHR to improve diabetes care.

First, their choice of process and outcome measures was based on a detailed assessment of what data existed in the EHR, how it was stored, and the feasibility of retrieving it for reports and letters, CDS, and tailored EHR “synopsis” displays (another form of CDS).

Second, we can infer that the data limitations found early in the project informed the selection of later interventions. For example, the intervention to introduce new fields to capture diabetic eye and foot exams as structured data is a logical prerequisite to measuring whether these services were delivered.

Third, MHS approached this as a total transformation of ambulatory diabetes care and not as a technical project to turn on EHR features. Each intervention was tied to the larger objective: leverage the EHR to improve processes and outcomes for patients with diabetes. To assess the impact of each intervention separately, a different design for measurement and evaluation would have been required.

Among other lessons, the authors described specific examples of how their Epic EHR was used to support their quality goals in diabetes care. We suggest that readers dig deeper into the design, implementation, results, use of data visualizations, and lessons learned summarized and discussed in by the MHS team in several publications, including the following:

- Electronic Health Records and Quality of Diabetes Care (https://pubmed.ncbi.nlm.nih.gov/21879900/); Cebul, et al.; NEJM 365:9 (2011)
- MHS Case Study (https://www.himss.org/sites/hde/files/media/file/2021/01/20/metrohealth-davies-diabetes-management-case.pdf) for the HIMSS Davies Award

## 6.2 Use Cases for EHR-supported Quality Improvement

Each of the use cases presented considers how a clinic’s EHR can be used to provide data for QI and serve as a platform for delivering quality interventions.

Hera are some common themes across all of the use cases presented:

- EHRs may provide a wide range of demographic, clinical, administrative, and financial data useful for QI.
- EHRs may provide options for reporting at least some CQMs, generate graphs and dashboards, and generate patient lists filtered by demographic and clinical parameters.
- EHR data must be captured and stored as structured data for most of the uses described here. Inconsistent workflows and poor data quality (see Section 2) will lead to erroneous conclusions (Issues with poor data quality are often referred to as “garbage in, garbage out”).
- EHR-delivered interventions depend on good data, consistent workflows, proper training, evidence-based design, and organizational support for success.
- EHRs are not the only health IT tool useful for QI and may not even be the best choice for a given project (see Section 7 for alternative data sources).
- Incorporating an EHR into practice transformation can be challenging. We discuss how some of these challenges can be addressed at the end of the section.

Important data considerations for finding and using EHR data use the terminology framework introduced in Section 2 (USCDI 3.0), but remember that different EHRs may have unique ways of naming and organizing the same information.

### EHR Use Case 1: Reporting Clinical Quality Metrics from an EHR

Obtaining and using clinical performance data is a core function of practice facilitation and health IT advising. Extracting performance data from an EHR can be done in many ways (see Section 2), but the built-in quality measures provided in an EHR are a good place to start when custom measures are not required.

The need for EHRs to generate standardized CQMs has been part of federal EHR incentive programs beginning with the original Meaningful Use objectives released in 2009. The current Quality Payment Program (QPP) under MIPS attributes 30% of a provider or group’s overall performance score based on a peer comparison of specific quality measures.[66]

While the Medicare programs have had the most influence on what measures a given EHR vendor will provide, Health IT Advisors will quickly find there is a vast selection of CQMs to choose from (also see Section 8) and not all will be found in a clinic’s EHR; Section 7 discusses alternatives to the EHR.

#### Finding CQMs provided by a specific EHR

Most clinics report at least some quality data to incentive programs [MIPS, Comprehensive Primary Care Plus (CPC+)] or payers using EHR-generated CQMs. CMS maintains a searchable library (https://www.cms.gov/Regulations-and-Guidance/Legislation/EHRIncentivePrograms/eCQM_Library) of current eCQMs along with detailed specifications and logic diagrams.

Vendors must complete a certification process for any CQMs their customers will submit to CMS through the MIPS Quality Performance Program. Health IT Advisors can take advantage of this requirement by searching the ONC’s Certified Health IT Product List (CHPL) (https://chpl.healthit.gov/#/search) for any certified EHR by vendor and version.

#### Accessing EHR CQM reports and dashboards

Finding an EHR’s CQM reporting module may require some searching. Most vendors will provide a special dashboard, subsystem, or third-party registry to access CQMs used for MIPS and other quality incentive programs [CPC+, HEDIS (Healthcare Effectiveness Data and Information Set), UDS]. Exhibit 33 shows a typical dashboard for measures used by the Medicare value-based payment program for ACOs.

Exhibit 33 Example of a CQM Dashboard[67]

Graphic included with permission from The American Board of Family Medicine.

Screenshot of a sample dashboard as described in text above.

#### Data and Workflow Considerations

You are not limited to using certified MIPS measures for QI projects. A clinic’s EHR may offer many additional quality measures found in the NQF database for preventive care guidelines, specialty care, federally qualified health centers (FQHCs, called the Uniform Data System, or UDS), and special CQMs for use in value-based payment models (see Section 8 for a primer on CQMs and where to find them).

When standard CQMs are needed for a project, the built-in CQMs provided in an EHR can save time and resources. However, there are some things Health IT Advisors should consider (also see Section 2):

- Standardized CQMs require rigid conformance to specifications and timely updates to measure logic and code values used for inclusion/exclusion criteria. The inner workings of the CQM provided by a vendor may not be clear, making troubleshooting and data validation difficult.
- Vendors may be slow to make changes to the CQM programming when errors or outdated codes are found (not all CQMs require certification with ONC).
- The selection of CQMs provided by a given vendor is limited and may depend on the target specialty for the EHR. For example, a specialty EHR for gastroenterology may not include CQMs useful for primary care, pediatric medicine, or other specialties.
- Most CQM dashboards can provide both aggregate (numerator, denominator, exclusions, and performance rate) and patient-level data. Unfortunately, clinics often must purchase more robust population health software to access advanced features for segmenting a CQM by additional patient demographics, attribution models, or other criteria.
- Some of the limitations of using built-in CQMs can be overcome by exporting the EHR data and combining it with other sources using desktop or analytics software. Example: An all-payer CQM for Depression Screening and Follow-up (CMS 2, NQF 0418) could be combined with a demographic report that includes the patient’s payer(s) and/or that is stratified by age or gender.

And most [underlined: important]:

- The logic and data used by an EHR to calculate a CQM depends entirely on the completeness, accuracy, format, and code mapping of the underlying data elements. An EHR-generated performance metric should only be used if it has been validated and found to be reliable. Tips on assessing data quality are discussed in Section 2.

Exhibit 34 EHR Data Considerations - Using Clinical Quality Measures from an EHR

EHR Element | Description
Assessment and Plan of Treatment | - Diagnosis codes entered as encounter assessments are often used as inclusion/exclusion criteria for EHR-generated CQMs.
Clinical Notes | - Information in unstructured notes, scans, or faxes cannot be used to generate CQM denominators, numerators, exclusions, or exceptions.; - Some EHRs can incorporate structured data into clinical narrative and may be able to capture key elements for CQM calculations.
Clinical Tests | - Tests and procedures performed in the clinic must be properly documented and coded to be used in a CQM calculation.
Diagnostic Imaging | - Orders for diagnostic imaging must be properly documented and coded to be used in a CQM calculation.; - Results for diagnostic imaging must be recorded as structured data to be used in a CQM calculation.
Encounter Information | - Encounter coding is frequently used as inclusion criteria for CQM denominators, numerators, or exclusions (CPT, ICD, SNOMED).; - Some encounter types may be explicitly excluded from a CQM by local configuration or vendor specification.; - Encounter dates for eligible visits are frequently used when calculating the measurement period for a CQM.
Health Concerns | - Self-reported data and assessments must be recorded as structured data to be used in a CQM calculation.; - Specific questions and responses for questionnaires may need to be explicitly coded to correctly calculate denominators, numerators, and exclusions (LOINC, SNOMED).
Immunizations | - Vaccines must be mapped to the correct NDC and/or CVX code to be used in a CQM calculation.
Laboratory | - Laboratory tests and results must be mapped to the correct LOINC code to be used in a CQM calculation.
Medications | - Medications and therapeutic injections must be mapped to the correct NDC and/or RXNORM code to be used in a CQM calculation.
Patient Demographics | - Missing or incorrect data for age, gender, and other demographic fields will affect CQM calculations that use them.
Problems | - Diagnosis codes entered in the problem list are often used as inclusion/exclusion criteria for EHR-generated CQMs.; - Diagnoses must be coded with SNOMED and/or ICD to be used in a CQM calculation.
Procedures | - Procedure codes must be coded with CPT to be used in a CQM calculation.
Vital Signs | - Variation in how and when vital signs are recorded in the EHR may affect CQM calculations (height, weight, blood pressure, BMI, BMI%).; - Workflows for recording repeat readings can affect CQM calculations (the last BP recorded in a visit is often the lowest).; - Height and weight must be consistently recorded to produce accurate BMI and BMI% if used in a CQM calculation.

### EHR Use Case 2: Improving the Delivery of Preventive Care

Improving the delivery of preventive healthcare services in the U.S. is a public health priority.[68] However, as Banksy et al. reported: “As of 2015, only 8 percent of US adults ages thirty-five and older had received all of the high-priority, appropriate clinical preventive services recommended for them. Nearly 5 percent of adults did not receive any such services.”[69]

The gap between evidence-based screening practices and actual care delivery makes preventive care an important target for QI and practice transformation projects. Often, these data come from claims (see Section 7), but EHRs are increasingly used to support preventive care by measuring clinical quality, targeting interventions, and determining how much providers are paid under value-based payment contracts. In the U.S., evidence-based guidelines for preventive healthcare are developed and disseminated by the U.S. Preventive Services Task Force (https://www.uspreventiveservicestaskforce.org/uspstf/topic_search_results?topic_status=P) (USPSTF). EHR-driven QI projects frequently target one or more of these recommendations (https://www.aafp.org/dam/AAFP/documents/journals/afp/USPSTFHealthCareSchedule2020.pdf).

#### EHR Data

- Measuring the delivery of preventive care services:
  Some of the first CQMs developed for EHRs calculate performance rates for delivering specific preventive services. As a result of the federal EHR certification requirements under Meaningful Use and the QPP, Health IT Advisors will find that most clinics can produce common CQMs including performance rates for Screening for colorectal, breast, and cervical cancer; Screening for depression; Recording of smoking status and delivery of cessation counseling; and Age-appropriate immunizations.
  The completeness and accuracy of EHR-generated measures for preventive care is heavily dependent on the quality of the underlying data. For example, depending on how long a clinic has used their EHR, it may not be possible to determine whether the guideline for colorectal cancer screening by colonoscopy was met without access to ten continuous years of structured data (see CMS 130, NQF 0034).
- Targeting populations and individuals for interventions:
  Using EHR data to inform population health is a recurring theme across most QI use cases. EHRs that can calculate CQMs often allow users to “drill down” to a list of individual patients meeting, not meeting, or excluded from a preventive care measure. These lists are often called “gaplists” because they highlight specific gaps in recommended care, and in more robust EHRs can further segment quality data by demographic, administrative, and other parameters useful for targeting interventions.

#### EHR Interventions

- Clinical decision support tools:
  In Section 3 of this handbook, CDS interventions are described as a collection of EHR features and functions designed to draw attention to specific gaps in recommended care. For example, a CDS intervention could be configured as an alert window that pops up in a patient’s chart when age- and gender-appropriate preventive cancer screening tests have not been ordered or performed.
  CDS is a powerful QI tool, but can exacerbate alert fatigue among providers. Therefore, Health IT Advisors should be cautious before recommending new provider-facing CDS alerts. (Also see Section 3.)
- Patient engagement as an intervention:
  Successful preventive care depends on individuals’ following through with provider’s recommendations for screening tests and procedures -- especially unpleasant procedures like a colonoscopy or a mammogram. EHRs can be used to deliver patient-facing reminders, education material, encourage virtual visits, and other targeted interventions. (Also see Section 3.)
  EHRs can also collect data (e.g., blood pressure) and online assessments directly from patients via a portal or smartphone application. For example, a standardized questionnaire to screen for depression such as the Patient Health Questionnaire (PHQ-2 or PHQ-9) can be completed by a patient the day before a visit – freeing up time in the exam room.

Exhibit 35 EHR Data Considerations - Improving the Delivery of Preventive Care

EHR Element | Description
Assessment and Plan of Treatment | - Assessment and billing codes applied to an encounter may indicate services and tests provided for screening and preventive care.; - A treatment plan may include referrals or orders for future screening tests (labs) and procedures (colonoscopy).
Clinical Notes | - Patient-reported history or screening results from external providers may be recorded as narrative in clinical notes or medical history.
Clinical Tests | - In office tests and procedures might be used for preventive care or as part of diagnosis, treatment, and management.
Diagnostic Imaging | - Results for mammograms and other preventive imaging studies may be available as structured data or “hidden” in scanned documents and faxes.; - Imaging results from different providers may have unique names in the EHR (Mammogram versus Mammogram, Screening) or incorrect test code mapping (LOINC, CPT).; - Diagnostic imaging results may be received as unstructured text (scans, faxes).
Encounter Information | - Screening tests are often requested for annual wellness visits as part of standing order protocol.; - Assessment and billing codes applied to an encounter may indicate services and tests provided for screening and preventive care
Health Concerns | - It may be difficult to distinguish tests and services ordered for diagnostic, treatment, and management purposes from “true” preventive care (mammograms, Pap tests, colonoscopy).; - Self-reported assessments on substance use and depression may not be recorded as unstructured data (scans, faxes).; - A validated screening tool must be used for gathering patient substance use data.
Immunizations | - Immunization data in an EHR may not include vaccinations delivered outside of the clinic (see Alternative Data Sources).; - Immunizations can be confirmed with state immunization registries and some practices have a link to their state immunization registry on their website.
Laboratory | - Results for screening tests may be recorded as unstructured data (scan, fax).; - Results from outside labs or providers may not be recorded in the EHR (see Alternative Data Sources).; - Results from different labs may have unique names in the EHR (HbA1c versus Hemoglobin A1c) or incorrect test code mapping (LOINC).; - Pathology and cytology results (Pap tests) may be received as unstructured text (scans, faxes).
Medications | - Rarely used for preventive care QI.
Patient Demographics | - Used to identify individuals eligible for recommended preventive care services.; - Patient demographics information can drive further assessment of health-related social needs regarding preventive care.
Problems | - Used to exclude individuals with an established diagnosis who are in treatment or management and no are longer eligible for screening.
Procedures | - Procedure notes and summaries from outside providers may be recorded as unstructured data (scan, fax).; - Procedure notes and summaries from outside providers may not be recorded in the EHR (see Alternative Data Sources).; - Colorectal cancer screening using invasive procedures may still be considered “diagnostic imaging” by some EHRs (colonoscopy).
Vital Signs | - There may be variation in how and when vital signs are recorded in the EHR (height, weight, blood pressure, BMI, BMI%).; - Workflows for recording repeat readings for blood pressure can impact data quality.; - Height and weight must be consistently recorded to produce accurate BMI and BMI%.

### EHR Use Case 3: Behavioral Health and Social Needs

One of the overarching goals of the U.S. Department of Health and Human Services’ (DHHS) Healthy People 2030 Plan is to “Create social, physical, and economic environments that promote attaining the full potential for health and well-being for all.” [70] The priority DHHS has given to identifying and addressing SDOH highlights the increasing need to collect information on patients’ health-related behavioral, social, and community needs.

Until recently, EHRs used in primary care settings did a poor job of handling data outside of the traditional medical encounter. However, the move to integrate or “embed” behavioral, mental health, and social services into clinics is rapidly expanding the types of data an EHR can provide for QI.

#### What are Social Determinants of Health (SDOH)?

Research suggests that traditional medical care contributes only 20% to overall health outcomes in the United States.[71] As the healthcare system seeks to address the 50% of health-related social factors, practice transformation and QI will increasingly require data on economic, educational, environmental, and social/community contexts for their patients. Health IT Advisors can play an important role in helping clinics establish the needed workflows and EHR settings to consistently and accurately capture SDOH data, including demographic factors that can affect health such as self-reported race, ethnicity, and language preference, as well as other factors important in SDOH mentioned above including education level attained and other socioeconomic information. For example, if programmed for this, EHRs can capture data about a person experiencing homelessness, depending on public transportation to access health services, and/or living in a building with known high lead levels, etc. The County Health Rankings Model in Exhibit 36 shows how social factors can impact health and health outcomes.

Exhibit 36 Determinants of Health from the County Health Rankings Model (2016) [72]

Graphic included with permission. ©2016 University of Wisconsin Population Health Institute (UWPHI).

A graphic displaying how Policies and Programs lead to Health Factors and then to Health Outcomes (which are 50% length of life and 50% quality of life). The Health Factors include Physical Environment (10%), which includes Air & Water Quality and Housing & Transit; Social & Economic Factors (40%), which include Education, Employment, Income, Family & Social Support, and Community Safety; Clincial Care (20%), which includes Access to Care and Quality of Care; and Health Behaviors (30%), which includes Tobacco Use, Diet & Exercise, Alcohol & Drug Use, and Sexual Activity.

#### EHR Data

- Identifying Social and Behavioral Needs:
  More EHRs are capable of incorporating SDOH and behavioral health data in the form of validated assessments, such as Protocol for Responding to and Assessing Patients’ Assets, Risks, and Experiences from the National Association of Community Health Centers (PRAPARE - NACHC (https://www.nachc.org/research-and-data/prapare/)), and as structured data that can be mapped to standard code values. For example, you will increasingly find that EHRs provide (or can be configured with) structured demographic fields for sexual orientation and gender identity (SOGI), race, ethnicity, language, and disabilities. Standard codes are also being developed and implemented for social needs pertaining to health, including housing, food, and/or transportation.[73] AHRQ’s social determinants of health microsite (https://www.ahrq.gov/sdoh/index.html) provides additional information, including tools to assess patients social risks and needs (https://www.ahrq.gov/sdoh/practice-improvement.html).
  A QI project focused on SDOH could further segment traditional CQMs. For example, structured data capturing food insecurity might be combined with a CQM for controlling hypertension to provide new insights and target interventions.
  Because many clinics are early in their efforts to integrate behavioral health and screening for social needs, Health IT Advisors can provide valuable assistance in developing the workflows and EHR capabilities needed to assess, capture, and use data on non-medical domains of health.

#### EHR Interventions

- Clinical decision support tools:
  There are exciting opportunities for QI once supporting data on social and behavioral health are available in the EHR and accessible by CDS. For example, structured data collected by screening for depression or unhealthy alcohol use could be used to trigger a reminder when appropriate follow-up, referral to care, or medication is not provided to high-risk individuals. A care-coordinator dashboard can be implemented, and automated referrals to social workers can be included, as well as pre-populated home visit templates for community health workers or visiting nurses.
- Patient engagement as an intervention:
  Patient portals can be used to collect SDOH demographics and screen for behavioral and social needs and to deliver tailored education and instructions for self-care. Health IT Advisors must consider whether an EHR-based intervention is appropriate or equitable based on the population of interest. For example, individuals dealing with homelessness may have difficulty accessing patient portals or smartphone apps.

Many EHR data considerations that are related to social and behavioral needs are outlined in Exhibit 37.

Exhibit 37 EHR Data Considerations - Identifying/Managing Behavioral and Social Needs

EHR Element | Description
Assessment and Plan of Treatment | - Assessment and billing codes applied to an encounter may indicate services and tests to assess and document behavioral and social needs.; - A treatment plan may include referrals to behavioral or community services to address needs identified during an encounter.
Clinical Notes | - Patient-reported concerns about food, housing, transportation, mental health, and other health-related risks may be recorded as narrative in clinical notes.; - Records of treatment for substance use are protected by CFR 42 Part 1 and may not be accessible in the EHR.
Encounter Information | - Assessments for behavioral (depression, anxiety, substance use) and social/community needs may be recorded during an annual wellness visit.; - Assessment and billing codes applied to an encounter may indicate what assessments were done and needs identified.; - Records of outside assessment, counseling, specialty care, and community services may not be incorporated into the clinics EHR.
Health Concerns | - Routine collection of self-reported assessments for behavioral (depression, anxiety, substance use), social/community needs, and disability status are becoming more common in primary care settings.
Medications | - Certain medications may indicate a positive finding for behavioral health concerns (anti-depressants) and substance use (naltrexone).
Patient Demographics | - Screening tools are often validated for specific age groups (CRAFFT for adolescents versus AUDIT for adults) or scored by gender (alcohol consumption).
Problems | - Used to identify individuals with or without specific behavioral conditions or diagnosed substance dependency.; - Diagnosis coding standards for SDOH are still in development and may not be represented on a problem list.; - Expect variation in how individual providers document “diagnoses” for behavioral conditions, substance use, and social needs using EHR problem lists.
Social Determinants of Health | - Version 2.0 of the USCDI explicitly creates new data elements to capture and exchange SDOH information as structured data.; - To be useful for QI, SDOH data must be recorded as structured data either directly from the questionnaire (an electronic form) or re-entered by staff or clinicians.; - Terminology and coding standards for SDOH domains are being developed and may not be fully implemented by the vendor.; - Race, ethnicity, language, and disability is often recorded as a demographic data element.

## 6.3 Tips for Health IT Advisors on Using EHR for Quality Improvement

Earlier in the handbook we made five statements about how EHRs might be used by Health IT Advisors to support QI projects. Here, we return to these broad generalizations and provide some practical tips for effectively using the EHR as a tool for practice transformation.

1. EHRs may provide a wide range of demographic, clinical, administrative, and financial data useful for QI:
  - Once you have a grasp on the goals, objectives, and data requirements for a project, create a written data plan explicitly listing the data elements that will be needed. Use this list to determine whether the EHR can supply these data, and in a form you can use.
  - Consider mapping terms that people in the clinic use to refer to important types of data to make sure you are requesting or retrieving the correct information from the EHR. Remember that the USCDI nomenclature used here is meant to be generic.
  - In addition to knowing if you will find needed data elements stored in the EHR, you must also determine whether the workflows for capturing data are used consistently and data are incorporated without errors in the form you expect. For more on assessing workflow and data quality, see Section 2.
2. EHRs may provide options for reporting at least some CQMs, generating graphs and dashboards, and producing patient lists filtered by demographic and clinical parameters:
  - Choosing and using appropriate and meaningful CQMs is one of the most important considerations when designing a QI project. Different EHRs vary widely in what CQMs are supported and how they are accessed. Health IT Advisors will quickly learn how common vendors generate and report CQMs, for example, how to get to a MIPS dashboard to retrieve CMS measures or run a registry report to pull a filtered patient list.
  - Clinics rarely use all the features in their EHR. Unless they are currently pulling CQMs for incentive programs (MIPS, Patient-centered medical home, UDS) or their own internal use for QI, they may not know what data capabilities they really have. Health IT Advisors serve an important role in helping clinics learn their own technology.
  - EHR vendors will do their best to accurately calculate quality measures. Unfortunately, you may find that built-in reports and CQMs are thrown off by missing data, unexpected workflows (entering blood pressure values as free text), or improper configuration (lab results not being mapped to LOINC in the EHR). The answer to this is to systematically assess the quality of ANY EHR data being used (see Section 2 for how to do this).
  - You may find that a built-in CQM is close, but not quite what is needed for your project. One solution is to combine data extracted from the EHR, for example a list of patients in the denominator of the Poor A1c Control CQM (CMS 122, NQF 0059), with a separate file containing additional variables using spreadsheet, database, or analytics software. Use caution, however. Combining data sets can introduce errors if record matching is done incorrectly.
3. EHR data must be captured and stored in an appropriate form, usually as structured data. Inconsistent workflows and/or poor data quality (see Section 2) will lead to erroneous conclusions:
  - This is a recurring theme in this handbook. From the start of a project, it should be clear that all needed data is consistently captured, stored, and extracted in a form that is appropriate to the analysis. With very rare exceptions, this means that structured data will be required.
  - QI projects can always be designed to include training, workflow changes, or new data fields that will support consistent and accurate data capture. In fact, a project might explicitly include improved clinical documentation as one of its objectives.
  - There are alternatives when needed data elements are not available as structured data. The most common is to perform a manual chart abstraction (see Section 2), but in the future sophisticated software for natural language processing (NLP) may open up how data stored as free text can be used for QI.
4. EHR-delivered interventions depend on consistently entered data that is located in the correct documentation location, consistent workflows, proper training, evidence-based design, and organizational support for success:
  - Quality interventions using an EHR may involve the delivery of context-sensitive information to a user when a trigger condition is met. We have broadly referred to this in this handbook as a form of CDS. It is imperative that Health IT Advisors carefully consider the quality and completeness of the underlying data used to generate an alert or display clinical information. It does not take long for clinicians to lose confidence when alerts or information pop-ups are firing inappropriately or are incorrect.
  - CDS alerts and other types of EHR interventions directed toward clinicians require special attention, even when a CDS alert is well designed and incorporates high-quality data. Introducing another “click” to a provider’s workflow can contribute to alert fatigue even when the notification is timely and accurate. Health IT Advisors must include user input and engage in a formal acceptance process before implementing any interruptive CDS interventions.
5. EHRs are not the only health IT tool useful for QI and may not even be the best choice for a given project (see Section 7 for alternative data sources).
  - As Health IT Advisors get more familiar with specific EHRs, it is tempting to see them as a one-stop source for quality data and for delivering interventions. Remember, though, that the EHR may not always be the best choice: be sure to consider external data sources and even non-technical solutions. The next section of this handbook addresses possible alternatives.