# Section 5 Incorporating Patient-Generated Data for Quality Improvement

## 5.1 Advantages of Patient-Reported Outcomes and Patient-Generated Data

Patient-reported data and patient-generated data together offer an opportunity to capture information for use at the point of care, with potential cost savings and improvements in quality, care coordination, and patient safety.[53] Patient-generated health data (PGHD) includes patient-reported outcomes (PROs). According to the Food and Drug Administration (FDA), a PRO is a report coming directly from the patient regarding the status of a patient’s health condition without amendment or interpretation of the patient’s response by a clinician or anyone else.[54]. Data can be captured by a patient, family caregiver, provider, or device. Data can be retrospective (i.e., capturing data on things that have occurred in the past) or entered in real time. AHRQ has published an important resource on this topic, Integrating Patient-Generated Health Data into Electronic Health Records in Ambulatory Care Settings: A Practical Guide (https://digital.ahrq.gov/sites/default/files/docs/citation/pghd-practical-guide.pdf).[53]

PROs can be collected from patients at various times and in various ways, including:

- during clinic visits
- when they are at home (including all locations in someone’s daily life)
- online through various web tools
- through mobile devices used either for treatment or for research.[54]

PGHD includes any health-related patient data that originates from the patient or patient designee. This includes data captured by:

- wearable technology
- sensors
- patient-reported treatment, symptom, or lifestyle data

It is now understood that it is critical to value the patient as a source of vital health information. The timely receipt of additional data from the patient, the patient’s family, or other caregivers outside of the clinical visit can eliminate critical information gaps, such as recent changes in the patient’s condition or symptoms that might prompt a change or reconsideration of the care plan.[55]

Acquiring knowledge that a patient had a procedure or test from another provider can help reduce duplicative services. Additionally, an up-to-date list of medications from all providers, including what is being taken as compared to what has been prescribed, is vital for care coordination. Data regarding medications, allergies, intolerances, and outcomes can help mitigate safety risks and adverse outcomes.

Policies and practices for the safe and effective collection and use of data generated by patients outside the clinical setting will help support delivery and payment reform goals. Developments in healthcare delivery, such as patient-centered care, the patient-centered medical home, and payment reform programs such as Accountable Care Organizations (ACOs) seek to strengthen patient engagement and care team coordination as contributors to better outcomes and efficiencies.[55]

Additionally, the use of PGHD can spur patient engagement, self-monitoring, and self-management. This encourages some activities to shift from being provider-driven to patient-led.[55]

Health IT Advisors can teach practices to incorporate PROs and PGHD with point-of-care information to improve coordination of care and include the patient as an active care participant. Workflows to include this external information in the medical record and in shared decision making will also be essential for practices.

Exhibit 29 Overview of Patient-Generated Health Data[56]

Graphic included with permission. © 2020 American Cancer Society.

An Overview of Patient-Generated Health Data (PGHD). First box includes self-reported medical or treatment history, second box includes patient-reported outcomes; and third box includes biometric or wearable sensor data.

## 5.2 Patient-Reported Data Examples and Sources

A patient’s health history can be collected in an outpatient or inpatient setting. The purpose of obtaining the health history is to gather subjective data from the patient or the patient’s family. The health history is essential so the healthcare team and the patient can collaboratively create a care plan that will promote health, address acute health problems, and minimize the effects of chronic health conditions.

Health history data is traditionally gathered from patient encounters at the point of care. Health history data collection requires additional resources and typically must be completed during the patient visit. Patients may also be provided the option to enter these data through a patient portal. Enabling patients to enter this historical information through a portal has many benefits as noted above.

Health IT Advisors can help practices develop workflows that reinforce patient data entry of health history changes into the patient portal and incorporating new patient-generated data into point of care visits. Workflow changes include asking patients during triage if they have had any ancillary treatments, appointments, or admissions since their last encounter. This self-reported information is then entered into the EHR.

Exhibit 30 below demonstrates how health-provider-generated data can be transmitted to a patient and how patients can self-report information that can be transmitted back to their health provider through a patient portal.

Exhibit 30 Integrating Patient-Generated Data Directly into Primary Care Providers’ EHR Workflow[57]

Graphic adapted with permission.

Exhibit 30 demonstrates how health-provider-generated data can be transmitted to a patient and how patients can self-report information that can be transmitted back to their health provider through a patient portal. Pathway A shows the path from the Health Provider to patient through imputting medical information into the EHR, then selected information goes into the patient portal where it can be accessed by the patient. Pathway B shows bi-directional communication between the Health Provider and Patient using telephone, fax, email or SMS, or the Health Provider using a messaging service to answer questions in the patient portal, which reprots specialist visit information to the patient.

Providers with registry capabilities or affiliations with hospital networks may have access to emergency room and inpatient admission data. Unfortunately, though, many independent and rural primary care practices do not have this kind of direct access to inpatient utilization data. (A clinical registry is an ancillary computer database that collects secondary information about patients. Information can include prescriptions, immunizations, diagnosis, conditions, and procedures.)

Health IT Advisors can work with providers to assess available sources of external data for their particular practice, and help determine the costs and benefits of integrating with existing data sources or setting up new internal processes for collecting data from patients.

## 5.3 Technical Issues/Privacy & Security/Barriers

### Technical Issues

Technical and data standards are vital to the effective use of PGHD. Patients may need to be taught how to measure data accurately, track changes in health, and transmit data in a standardized manner. The information must be collected and submitted in standardized ways that ensure that the information can be received, understood, and integrated into the EHR if desired.[53]

User-friendly data dictionaries will be required to enable standardized data entry and integrate patient activity into patient portals, electronic health tools, and platforms to create useful health information. (A good resource regarding data dictionaries can be found at: What is a Data Dictionary? | Journal Of AHIMA (https://journal.ahima.org/what-is-a-data-dictionary/#:~:text=A%20data%20dictionary%2C%20as%20defined%20by%20the%20AHIMA,reports%20use%20that%20data%20element%2C%20and%20so%20on.).) In a dynamic consumer electronic health environment, it will be critical to incorporate PGHD into the EHR.

### Privacy and Security Issues

Patients and providers need to be assured that data transmitted and received are private and secure. Authentication of the patient (or caregiver if that person is submitting information) is critical to ensure that information authorship can be correctly attributed. A method of connecting specific information to its source is essential to track data moving from system to system, particularly from patient-controlled sources to provider EHRs, so that the integrity of the data can be ensured. [55] Encryption is another option to secure transmitted patient-generated data. However, this requires the additional steps of creating and storing passwords which may hinder patient usability.[53]

Health IT Advisors may support practices and providers by identifying security needs including encryption and workflows that include obtaining additional patient consent for sharing private health information. There could be a need to address patient authorization for secondary sharing of PGHD, if the patient prefers that the data not be shared with other providers or for other purposes.[53] In general, adhering to best practices regarding data governance is particularly important in the context of PGHD. The AHRQ PGHD Guide mentioned above has a section on data governance (Folio 4).

## 5.4 Patient-reported Symptoms and Health-Related Quality of Life

Patient-reported symptoms regarding health, pain, and well-being can be helpful to determine current treatment plan effectiveness as well as future treatments.[58] These may include symptoms after cancer treatments, surgical procedures, or changes in medications. Patients can relay symptoms through connection to a web-based platform.

PROs can take a variety of forms, including measures of differences in symptom severity and impact and measures of health-related quality of life (HRQoL). A consensus among health researchers is that HRQoL is a multidimensional construct composed of at least four dimensions:

- Physical function (i.e., daily activities, self-care)
- Psychologic function (i.e., mental state, mood)
- Social role function (i.e., social interactions, family dynamics), and
- Disease or treatment symptoms (i.e., pain, nausea)[59]

Symptom reports represent a subset of HRQoL. Symptoms are viewed as the patient report most closely related to the disease process and may be as impactful as HRQoL components such as well-being, perception of daily functioning, global impressions of the impact of treatment on daily life, satisfaction with treatment, and perception of overall health status.[59]

## 5.5 Home-Reported Outcomes/Patient-Generated Health Data

Physicians regularly collect data on patients’ physical vital signs at the point of care, but they most likely do not know much about their patients’ home and community environment. This lack of information is problematic because factors such as where you live, what you eat, whether you have the chance to exercise, and other social factors have a significant impact on patient health outcomes.

Appropriately collecting and acting on PGHD, such as self-measured blood pressure data, has the potential to better engage patients in self-care, improve patient outcomes, and reduce healthcare costs related to readmission and emergency room visits.[60] This can be done through telemonitoring devices such as automated blood pressure machines, pulse oximeters, scales, and other measurement mediums. There are options for these devices to be connected to a web-based platform or transmitted directly into EHRs.

In addition to tele-monitoring, other technologies have been developed to enable patients to collect their health information beyond the clinical setting and share that information with providers. Examples of these new technologies and applications include Personal Health Records (PHRs), wearables, and telephonic applications such as those that utilize Bluetooth to send data to a patient’s phone and generate reports and data that can be shared with healthcare providers. Connected devices have also been developed to test a variety of other health indicators such as blood glucose, cholesterol, and oxygen levels.

## 5.6 Electronic Health/Well-being (Preventive Screenings)

With chronic disease prevalence signaling the need for a refocus on primary prevention, electronic PGHD might be essential in strengthening proactive and person-centered healthcare.[61] Screenings such as depression, weight, nutrition, smoking cessation, and substance use can be incorporated into patient portals or administered utilizing remote video-conferencing platforms. Screenings can also be paired with external devices such as smart watches, pedometers, glucometers, and scales.

Patient-generated health screening data can potentially improve health literacy and patient engagement through promotion of improved patient engagement in care.[61] Preventive health management alone requires patient participation and goal setting. Generating and transmitting prevention/screening data can be taxing for the patient and provider; however, this type of data is vital to help providers determine if health and well-being factors may impact disease and the patient’s ability to adhere to a treatment plan. In order to prevent implementation of PGHD from causing disparities, practices need to ensure that patients with limited ability or access to computers and the Internet, or limited numeracy, have the opportunity to provide PGHD.

[image] | TIP:; Health IT Advisors can work with practices to review current preventive screening workflows and assist in the development of workflows that include PGHD and well-being data in patient encounters and treatment plans.; Practices will also require assistance to identify standardized tools and incorporate them into EHRs to collect PROs. Incorporating PROs from web-based platforms into EHRs and alerting providers of outcomes may require vendor support and/or IT architecture development.

## 5.7 Data Collection and Use Challenges

There are many challenges to collecting patient-reported data and patient-generated data. There is an overall lack of motivation and cost benefit to collecting and using PROs.[62] Inclusion of patient-reported data into the EHR may require changes in workflow, increased staff allocation for transcription or review, and clinical decision support modifications. If PROs are not incorporated in treatment, then providers may not see the value in their use.

Recently, stakeholders have become interested in expanding the use of PROs for direct patient care. Other stakeholder efforts include input in quality measurement and patient-reported outcome measures in value-based payment programs. To optimize the value of care we provide from our patients’ perspective, we must ensure that the right patient-reported outcome measure (PROM) is used for the appropriate indication. Without proper alignment between PROMs and measurement goals, data may be unfounded and may result in poor decision making.[63]

Additional barriers might also impact the standardized collection of patient-reported outcomes in clinical practice. Lack of motivation to collect and use PRO data driven by inertia is a significant concern, just as inertia is a barrier to widespread adherence to clinical guidelines.[62] There are many HRQoL instruments; however, clinicians are generally unfamiliar with them. Additionally, providers may not know what action is appropriate to take on PRO data and/or may not know how best to incorporate this data into shared decision making. Even exposure to educational programs to improve knowledge of PROs may not be sufficient to change clinicians’ behavior enough to improve health outcomes.