# Section 4 Patient Portals and Engagement Technologies

Before smartphones and personal health applications, a “patient portal” usually meant a secure website typically integrated with an EHR that allowed patients to view (some of) their medical record and securely exchange messages with clinic staff. Patient portals and related engagement tools (smartphone apps, text messaging, personal health records) have rapidly evolved to provide patients and caregivers with a more “connected experience." Recent federal requirements meant to streamline access to an individual’s own health records has created new opportunities to view and interact with data.

For the Health IT Advisor, patient portals and related platforms can provide data for QI and deliver targeted interventions directly to patients.

Patient-generated data (see also Section 5) captured through a portal could include health screening results, health logs, and (increasingly) biometric data from devices.

Patient-facing interventions delivered by portal could include patient reminders for preventive care, individualized education and self-care instructions, and motivational messaging.

Common features found in many patient portals include:

- Providing patients, parents, and caregivers with secure electronic access to parts of their EHR including the following:
  ○ Demographics and insurance information
  ○ Visit and referral history
  ○ Laboratory and imaging orders and results
  ○ Care summaries and procedure reports
  ○ Problem and medication lists
  ○ Vital signs
  ○ Provider progress notes
  ○ Individualized care plan
- Serving as a platform for telehealth and virtual care by providing real-time communication with clinic staff and providers
- Delivery and management of secure messages, test results, alerts, reminders, and personalized education material
- Allowing users to download and share their medical record by securely transmitting a summary to another provider or a personal health record or smartphone application (e.g., Apple Health)
- Remotely capturing and incorporating patient-provided data into the EHR, including electronic forms, questionnaires, and assessments
- Remotely and securely capturing and incorporating data from personal health devices including glucometers, step counters, and blood pressure cuffs; this includes real-time remote patient monitoring solutions (RPM).

## Using the Portal for Quality Improvement

EHR portals and patient engagement platforms have the potential to reshape how, where, and when an individual’s health data are collected. Information that once used pen and clipboard can be acquired in the clinic on a tablet computer or kiosk, or outside of the office.

Health IT Advisors should consider the following use cases when a patient portal is available:

1. Use EHR logs and audits to measure how and when users interact with portals and apps.
2. Incorporate structured data from forms, questionnaires, and assessments collected via a portal or app into a QI project.

The principles of data governance (see Section 2) also apply to data collected through portals or other patient engagement technologies. When it is used for QI, Health IT Advisors should observe how patients or caregivers interact with the portal to look for gaps or red flags in data quality. For example, there may be issues with how data are collected (unformatted text, for example) and when and how data are transferred and incorporated into the EHR.

And most important, not all patients can (or will) use patient engagement platforms, including traditional EHR patient portals. You should carefully consider whether adoption and use may be limited to a subpopulation with higher literacy and numeracy and/or greater access to or affinity for technology. Equity and inclusion are important issues that need to be addressed when use of patient-facing technology is being considered.