# Section 3 Clinical Decision Support

Clinical Decision Support (CDS) is a broad term for a powerful set of health IT features that provide users with context-sensitive guidance, information, warnings, and prompts for actions through the application of pre-defined rules, algorithms, or clinical guidelines.

For QI projects, CDS in an EHR can be a source of data (e.g., a project to measure the frequency of user overrides on medication alerts) or serve as a quality intervention (e.g., implementing a preventive care guidance tool to improve colorectal cancer screening).

The term CDS can be used differently by clinics, vendors, and even informaticists. To help conceptualize the types of CDS when preparing QI projects, we suggest the taxonomy developed by Wright, Sittig, Ash, and colleagues shown in Exhibit 28. [50, 51]

Exhibit 28 Types of Clinical Decision Support Commonly Found in EHRs

Clinical Decision Support | CDS Type | Examples/Descriptions
Condition-specific order sets | Guidance | - Evidence-based menu or picklist to guide appropriate orders for tests, procedures, medication, education, and treatment based on specific conditions or risk factors.
Contextually relevant reference information | Informational | - Provides access to context-specific medical reference and patient education resources tailored to the patient or situation. This can be helpful in effectively engaging in shared decision making and providing patient-centered care.
Diagnostic support such as differential diagnosis tools | Guidance | - Uses data in the EHR and reference sources to aid in diagnosis using evidence-based probabilistic algorithms (and more recently artificial intelligence).
Documentation templates | Guidance | - Provides pre-defined clinical content that can be structured to guide documentation quality and support decision making.
Drug-drug and drug-allergy interaction checks | Alert or Warning | - There is a potential drug-drug interaction or the patient is allergic to a medication being prescribed.
Electronic presentation of clinical guidelines | Informational | - Display of evidence-based care plans for patients with specific conditions or risk factors. (Also helpful in shared decision making/efforts to center care on the patient.)
Focused patient-data reports and summaries | Informational | - Reports or screen displays optimized for specific tasks, clinical contexts, or conditions. Used to focus attention by tailoring how information is presented.
Health maintenance reminders | Prompt | - Patient is overdue for colonoscopy, mammogram, Pap, or other preventive care.

## Using CDS for Quality Improvement

CDS can be a powerful tool for QI, but overuse of alarms and other reminders has been shown to create “alert fatigue” and even lead to important warnings being ignored or bypassed when users are busy or under stress.[52]

Below are some things Health IT Advisors should consider when incorporating a provider-facing CDS intervention in an EHR:

- Remember that CDS includes several possible interventions, including on-demand contextual access to reference data, “smart” documentation templates and phrases, and the design and layout of flowsheets and rounding sheets (a “synoptic report” for diabetes care was used in the Case Study presented in Section 6). Even printed reports can be organized and presented to enhance clinical decision making, thus making them a form of CDS using our broad definition.
- Overuse of CDS alerts and other reminders, poorly designed prompts, and “bad” data leading to inappropriate triggers can all lead to alert fatigue. Clinics should carefully prioritize and manage the number and intensity of CDS interventions and be cautious about adding new interruptive prompts or warnings that can distract (and annoy) clinicians and staff.
- CDS interventions should align with related quality efforts. For example, if a clinic is reporting quality measures to focus attention on diabetes care, including a CDS alert to flag high or missing A1c values would be a logical choice.
- EHR vendors often provide pre-defined CDS content in the form of a menu of prompts, alerts, templates, order sets, and third-party content. Where possible, these should be carefully evaluated and tailored to fit the clinic’s workflows and priorities.

[image] | EXAMPLE:; After proposing a new CDS alert as part of a QI project, you find that the clinicians are actively hostile to the idea of adding “another click” to their workflow. You dig deeper and find that the vendor had turned on many alerts by default, leading to alert fatigue. After addressing default alert settings, you suggest that—additionally—are view seeking “low-value” CDS be performed, which may also reduce unhelpful alerts and alert fatigue.

When Health IT Advisors plan to implement new CDS interventions, they can assist clinics by first reviewing and optimizing existing alerts and prompts to weed out those with low value and/or those driven by poor data, as well as to ensure—before implementation—that any planned CDS efforts will have sizable, meaningful impact.

- Patient data needed to drive CDS triggers and logic must be as complete as possible. For example, setting a ten-year time window for a preventive alert for colonoscopy only works if ten years of data are accessible by the EHR and not “hidden” in scanned documents or clinical narrative.
- CDS interventions should be evidence-based. Before designing or implementing a new CDS intervention, search the literature for triggers and logic paths that have been validated in a similar setting and with a comparable patient population.
- As artificial-intelligence (AI) tools are added to EHRs and other health IT platforms, it is critical to ensure that logic paths and algorithms--and the data on which algorithms are based--are transparent and predictable, and that they produce accurate, consistent, and equitable guidance for clinicians or patients.

Additional information about how health advisors may use CDS for quality improvement may be found through the Electronic Clinical Quality Improvement (eCQI) Resource Center (https://ecqi.healthit.gov/cds). Health advisors may also find re-usable, interoperable CDS resources and artifacts as building blocks for their CDS projects at AHRQ’s CDS Connect (https://cds.ahrq.gov/cdsconnect) platform.