# Section 2 Working with Electronic Health Records

This section of the handbook focuses on the EHR as a tool for QI. Section 7 addresses useful alternative electronic data sources including external electronic registries, population health platforms, and HIEs, and Appendix A covers standards for data exchange, or interoperability, between systems.

The EHR is the most common type of health IT used by healthcare providers in the U.S. To qualify for the CMS Quality Payment Program (QPP) and other government and value-based incentive programs (see Section 7), EHRs must have a current certification with the federal Office of the National Coordinator for Health IT (ONC). The certification criteria specify the minimum technical and functional requirements that an EHR vendor must meet to qualify for the Medicare MIPS, [3] Promoting Interoperability requirements, formerly called “Meaningful Use”). As of 2022, this is the 2015 edition.[30]

In 2022, there were more than 400 unique EHR developers with products listed with the ONC and more than 600 individual EHR products and versions. Exhibit 10 shows the most common IT vendors adopted by ambulatory providers in the U.S. from a survey in 2017, with the majority of providers using products from Epic, Allscripts, eClinicalWorks, GE, athenahealth, and Cerner Corp.[31]

Health IT Advisors may have to work with a number of different EHR systems, and, thus, may have to learn different methodologies to generate data needed for QI or to deliver an intervention based on the EHR a practice has adopted.

Exhibit 10 Certified EHR Technology Used by Ambulatory Providers as of 2017 [32]

A bar graph showing certified EHR technology (CEHRT) use reported by ambulatory care providers as of 2017. The most common EHR is Epic Systems (92,241), followed by Allscripts (33, 044), eClinicalWorks (26, 498), NextGen Healthcare (19,414), GE Healthcare (18,310), athenahealth (18, 018), Cerner (17,132), Greenway Health (10,605), Practice Fusion (8,440), eMDs (6,333), Integrated Practice Solutions (4,919), Eyefinity (4,287), MEDENT-Community Computer Service (3,835), McKesson (3,504), MedSeek (3,477), Sunquest Information Systems (3,208), Modernizing Medicine (3,202), Compulink Business Systems (2,957), SRSsoft (2,672), FairWarning Technologies (2,304), All other commercial vendors (93,737), and self-developers (13,960).

[image] | TIP:; It is helpful to know what a clinic’s EHR capabilities are before beginning a QI project. A quick way to find out is to use the ONC’s online Certified Health IT Product List (CHPL) search tool to review the certification status, product conformance, and what quality measures the vendor provides for a given product and version. Besure to ask for the details regarding the clinic’s EHR system (and version, etc.) before conducting this search. A screenshot of the search tool is shown in Exhibit 11.

Exhibit 11 ONC’s Certified Health IT Product List Search Tool (https://chpl.healthit.gov/#/search) [33]

Screenshot of the search tool.

[image] | EXAMPLE:; You will be working with a small independent practice using an EHR from vendor ABC. They are currently on version 123, which has a current ONC certification. For the project, you will need clinical performance data on the number of patients with controlled diabetes before and after a quality intervention. After looking up the vendor and version on the CHPL, you find that the vendor offers several certified quality measures that could be used for the project. For the project, you decided on “Diabetes: Hemoglobin A1c (HbA1c) Poor Control (> 9%), (CMS 122, NQF 0059)” as a potential metric to use. [34]

The following topics provide an overview of the fundamental concepts and best practices to consider when using an EHR for QI and practice transformation. We begin with a conceptual map of the data an EHR is likely to contain.

## 2.1 An Overview of Generic EHR Data Groupings and Elements

With so many different EHRs, it is difficult to make general statements about how a given product stores and represents the data it collects. There are, however, common design elements and terminology that can guide Health IT Advisors, and many of these terms reflect the common “ancestor” of the EHR: the traditional paper medical record. It is very important to keep in mind the fact that the original function of EHRs was to support billing and payment, and this still affects both EHR development as well as clinician use of these systems.

An EHR has multiple functions. The most obvious is to serve as the primary patient medical record to inform, deliver, and coordinate patient care. However, today’s EHRs have evolved to provide some (or all) of the following capabilities:

- Perform scheduling and billing (the original function of most major EHRs!)
- Serve as a primary, organizational medical record
- Deliver clinical decision support
- Provide registries and tools for managing population health
- Provide dashboards for cost and quality analytics
- Qualify for EHR incentive programs
- Support patient engagement and communication
- Support telehealth and virtual visits
- Connect to remote patient management devices
- Provide data for clinical and health services studies, and
- Coordinate care within internal care teams and external care partners.

Trying to meet all of these demands in one technology solution, the EHR, creates challenges for developers, implementers, and users alike. A Health IT Advisor should be prepared for the remarkable diversity of EHR implementations in the field.

### Why are EHRs So different From Each Other?

We have come to expect a degree of standardization when using websites, desktop applications, and phone apps. It can be surprising to see how much variability there is in EHR user interfaces, features, technical capabilities, configurations, and workflows. This variability is the results of many factors, including the following:

- A thriving commercial market for EHRs, driven by federal government incentives, which spawned a proliferation in vendors and products
- Federal certification requirements for functionality and design are relatively new (2009)
- Major EHR vendors usually create flexible solutions for broad adoption
- Vendors generally allow extensive site-specific customization during implementation, and
- Users may choose different workflows or user settings within the same product and version.

### A Conceptual Map of EHR Data

Despite wide variability among EHRs, a Health IT Advisor will find similar groupings of patient information from one system to another. For example, any EHR should provide a place to capture, store, and view current medications, diagnoses or conditions, test results, and many of the other groupings described below. The key differences between EHRs are likely to be: 1) the workflows used to enter and view data (discussed in the next section of the handbook); 2) navigation of screens and layout of displays; 3) vendor terminology; and 4) the potential range of user preferences and custom settings.

EHR screen designs for grouping and presenting data are unique to each system but follow the same general design themes. Below is an example of the VistA EHR developed by the Veterans Administration that illustrates several of the groupings described by the United States Core Data for Interoperability (USCDI) standard.[35] The USCDI is a vendor-neutral model and terminology standard for organizing patient-specific clinical information for exchange with other systems, and will be required going forward for certification of APIs and EHRs. (The topic of interoperability is covered in Appendix A of the handbook.)

Exhibit 12 Example of a Patient Summary Screen from the U.S. Department of Veterans Affairs’ Vista EHR [36]

Screenshot of the sample summary as described in text above.

[image] | EXAMPLE:; In comparing EHRs across clinics, you find that the clinical documentation of a patient encounter is called progress note at one clinic, visit note at another, and SOAP note (Subjective, Objective, Assessment, and Plan) at a third. The fourth simply calls it “the chart.” Health IT Advisors should use the particular terminology a clinic uses when discussing its data or EHR features. This can sometimes be difficult when working with multiple clinics.

The “conceptual map” we have chosen to provide is a generic grouping of information in an EHR based on a recent specification, mentioned above: United States Core Data for Interoperability (USCDI) (https://www.healthit.gov/isa/united-states-core-data-interoperability-uscdi).[35]

Exhibit 13 shows the major information groupings for draft version 3.0 of the USCDI released in January 2022 (the final version 3.0 of USCDI will be released in the summer of 2022).[35] The important groups to consider for QI are summarized in Exhibit 14 and can be a useful guide to “where to look for…” when encountering a new EHR.

Exhibit 13 Draft USCDI v3 Summary of Data Classes and Data Elements [37]

A table with information about the Draft USCDI v3 Summary of Data Classes, which includes Allergies and Intolerances; Assessment and Plan of Treatment; Care Team Member(s); Clinical Notes, Clinical Tests; Diagnostic Imaging; Encounter Information; Goals; Health Insurance Information; Health Status; Immunizations; Laboratory; Medications; Patient Demographics; Problems; Procedures; Provenance; Unique Device Identifier(s) for a Patient's Implantable Device(s); Vital Signs.

### Expansion of the USCDI to New Quality Domains

In 2021, the USCDI was expanded to incorporate new data elements for behavioral and social needs and assessments. For example, a new class was added to address social determinants of health (SDOH) and substance use treatment, an important target for QI. A use case for how these data might be used for QI is found in Section 6. In January 2022, a draft version 3 of USCDI was published. The most current specification for the USCDI’s data structures and data elements, can be accessed through HealthIT.gov here (https://www.healthit.gov/isa/united-states-core-data-interoperability-uscdi).

Exhibit 14 EHR Data Groupings Useful for Quality Improvement (USCDI Data Classes)[35]

EHR Data Grouping | Description
Assessment and Plan of Treatment | - Represents a health professional’s conclusions and working assumptions that will guide treatment of the patient.
Clinical Notes | - Represents narrative patient data relevant to the respective note types.
Clinical Tests | - Includes non-imaging and non-laboratory tests performed on a patient that results in structured or unstructured (narrative) findings specific to the patient, such as electrocardiogram (ECG), visual acuity exam, macular exam, or graded exercise testing (GXT), to facilitate the diagnosis and management of conditions.
Diagnostic Imaging | - Tests that result in visual images requiring interpretation by a credentialed professional.
Encounter Information | - An episode defined by an interaction between a healthcare provider and the subject of care in which healthcare-related activities take place.
Health Concerns | - Health-related matter that is of interest, importance, or worry to someone who may be the patient, patient’s family, or patient’s healthcare provider.
Immunizations | - Record of an administration of a vaccination or a record of a vaccination as reported by a patient, a clinician, or another party.
Laboratory | - The name of the analysis of specimens derived from humans which provide information for the diagnosis, prevention, treatment of disease, or assessment of health.; - Documented findings of the analysis of a tested specimen. Includes both structured and unstructured (narrative) components.
Medications | - [Prescribed medications]
Patient Demographics | - Current Address; - Date of Birth; - Email Address; - Ethnicity; - First Name; - Gender Identity; - Last Name; - Middle Name (including middle initial); - Phone Number; - Phone Number Type; - Preferred Language; - Previous Address; - Previous Name; - Race; - Sex (Assigned at Birth); - Sexual Orientation; - Suffix
Problems | - Information about a condition, diagnosis, or other event, situation, issue, or clinical concept that is documented.
Procedures | - An activity that is performed with or on a patient as part of the provision of care.
Vital Signs | - BMI Value (calculated from height and weight); - BMI Percentile (2 - 20 years); - Body height; - Body temperature; - Body weight; - Diastolic blood pressure; - Head Occipital-frontal Circumference Percentile; - Heart Rate; - Inhaled oxygen concentration; - Pulse oximetry; - Respiratory rate; - Systolic blood pressure; - Weight-for-length Percentile (Birth - 36 Months)

### Identifying EHR Data Elements for Quality Improvement

The USCDI graphic in Exhibit 13 shows the high-level data elements included in each group. For example, the group (or data structure) for vital signs includes finding blood pressure, which is frequently used in measures of clinical quality.

For projects where one or more EHR will be used as a data source, a Health IT Advisor must answer each of the following questions -- even when clinics using the same vendor (see the discussion on variation).

#### Are the data elements needed to inform the project captured in the EHR?

In an ideal world, the EHR would contain all of the relevant information that a clinic creates, stores, receives, or retrieves on its patients. Sadly, this is rarely the case. Before planning to use EHR data for a QI project, Health IT Advisors must confirm that the needed data elements are there and in a format that can be used.

Because needed data can be entered by typing, dictation, scanning, electronic interfaces, medical devices, or entered by patients on a smartphone or portal, ensuring data consistency and quality is an important function of the Health IT Advisor. Even today, clinical information also continues to be stored in scans or faxes, offline paper files, desktop spreadsheets, or specialized databases.

#### How are the data elements entered and where are they viewed in the EHR?

The best way to determine where needed data elements “live” in the EHR is to observe users entering the information into the EHR. A process for “following the data” is described later in the handbook. It helps to know: What screens are accessed for input? How are these data viewed by clinicians and staff? Can data be viewed for more than one patient at a time?

#### How are the data elements represented in the EHR?

For QI work, how data elements are captured and stored in an EHR is as important as where. Electronic data can be represented in an EHR as unstructured, structured, or multimedia, with important implications for extraction and analysis.

Unstructured data includes short or long free text in the form of a result (“See report,” “No malignancy noted”), a brief phrase (“Counseled patient on smoking cessation”), or a lengthy narrative (“The patient presents with a…”). Information entered into an EHR as free text can be very difficult to extract and analyze.

Structured data constrains a data element to a predefined format or standardized code list and is the best choice for extracting and analyzing data from an EHR. Structured data is usually entered using picklists, checkboxes, validated numeric fields or dates, yes/no responses (Boolean), or “macros” that generate structured responses from user input, a “dot phrase,” or a “smart form.”

Multi-media data includes fax and document images, photographs, diagnostic scans, voice or dictation files, and medical device telemetry. Information entered in this form is nearly impossible to extract or analyze without specialized software and equipment. Data needed for a project is often “hidden” in faxes and scanned documents creating challenges for QI (and many other secondary uses).

#### Can the data elements be extracted through reports, dashboards, or custom queries?

Extracting data from an EHR is challenging. It is important to consider all of the options available for retrieving the data you need, and how the format of the stored information might impact these efforts. As a rule, structured data is much easier to extract and use than unstructured data.

Health IT Advisors can also save time and effort by adapting an EHRs’ built-in reports and dashboards instead of requesting (or developing) a EHR custom report or database query. [34]

[image] | EXAMPLE 1:; You need to use clinical data from an EHR to measure diabetes control in a sub-population of a clinic’s patients. Your project preparation shows that Hemoglobin A1c values are being captured in the EHR as structured data and that a built-in quality measure (Poor A1c Control CMS 122, National Quality Forum (NQF) 0059) will suit your needs. Unfortunately, on closer examination, you find that the built-in quality measure reports all active patients with diabetes and cannot distinguish the subpopulations you are targeting for an intervention.; You might get what you need by merging data from the EHR report with a patient list reflecting your inclusion criteria.

## 2.2 The Impact of EHR Workflows on Data for Quality Improvement

[image] | EXAMPLE 2:; In addition to looking at A1c values, you also want to collect the measure for Diabetic Eye Exam (CMS 131, NQF 0055). After being told initially that “these reports are in the EHR,” you learn that the practice has been scanning faxed reports into the EHR and not using structured data.; You will find this is a recurring issue. The best option for retrieving data “hidden” in documents or scans is usually to perform a chart audit as discussed below.; For the long term, you will want to encourage and support changes in data-entry workflows to address the problem more directly. In doing this, you will be using an opportunity to improve data practices overall as part of building more robust QI capabilities.

Exhibit 13 is a list of EHR data groupings commonly used in QI projects. Health IT Advisors must understand how local clinic workflows, design of EHRs, and availability of high-quality data will affect a QI project.

[image] | EXAMPLE:; You plan to use the CQM for Poor Hemoglobin A1c Control (CMS 122, NQF 0059) built into a clinic’s EHR for a project looking at the quality of diabetes care. After pulling data from the EHR’s dashboard, you find that the A1c values received as scanned laboratory reports are missing, making the performance rate look worse than it is.

The historical A1c values from the scans may not be available without resorting to a chart audit. However, it is not unusual for a QI project to explicitly include the development of new EHR workflows to improve structured data capture. For example, you might find out if external A1c values can be entered into the EHR to correctly update the quality measure and how much additional work that would be for staff.

### Reasons for EHR Workflow Variation

We have seen that EHR workflows can vary widely among clinics and users. Even practices using the same EHR vendor and software version might have significant differences in how they capture, enter, and store patient information. Health IT Advisors will encounter several reasons for this, summarized in Exhibit 15.

Exhibit 15 Common Reasons for EHR Workflow Variation

Reason for EHR Workflow Variation | Example
Individual workflow preferences of clinicians and staff | “The checkbox is too many clicks; I prefer to type my notes.”
Deeply embedded habits carried over to the EHR | “We’ve always done it this way.”
Poorly configured EHR settings or hidden features | “I didn’t know it did that!”
Inadequate training during and after implementation | “This is how I was taught to do it.”
Unique circumstances | “The laboratory only sends us results by fax.”
Regulatory or payer requirements for documentation | “XYZ insurance will only pay for X if we do this.”
Alternate workflows to “workaround” a bug or missing feature | “The screen crashes if I try to enter numbers.”
Using data systems outside the EHR | “We view our patients’ discharge summaries in the hospital’s EHR using their portal.”

There may be good reasons for a clinic to choose workflows that adversely impact data quality to use for QI. While addressing them may be out of scope for your project, you can mitigate the impact of “alternative” workflows by identifying any data limitations early and incorporating them into the design of the project.

[image] | EXAMPLE:; Dr. Smith is one of ten clinicians who are part of a QI project that requires them to enter structured data by clicking a new template in their notes. He refuses to change his workflow. Asking providers to change their workflows, especially if it means more time navigating the EHR (“more clicks”) can be difficult. An option is to find a way to deal with the missing data, or negotiate a workflow where staff handles data entry on behalf of the provider.

We will discuss the importance of data governance and quality assessment later in this section of the handbook.

### Data Implications for Key EHR workflows

Thomas Bodenheimer identified 23 EHR workflows that Health IT Advisors frequently target for improvement, as shown in Figure 26.7 in Module 26: An Introduction to Electronic Health Records and Meaningful Use (https://www.ahrq.gov/sites/default/files/wysiwyg/ncepcr/tools/PCMH/pcpf-module-26-ehr-and-mu.pdf) of the Primary Care Practice Facilitation Curriculum.[38] Exhibit 16, below, lists how EHR workflows may impact data important to QI work.

Exhibit 16 Data Considerations for 23 Key EHR Workflows

EHR Workflow | Data Considerations
Recording patient demographics | - Are key patient demographics (age, gender, language, race, ethnicity, etc.) recorded consistently and using a standard vocabulary?
Recording vital signs | - Do providers and staff consistently record blood pressure and other vital signs; especially when repeat values or alternate postures are used (sitting, standing, supine BP readings)?
Maintaining an up-to-date problem list | - Are clinicians diligent about maintaining a current problem list by adding, updating, or removing codes when indicated?; - Is the problem list a reliable source for assessing current and historical acute or chronic conditions?; - Does the problem list use a standard vocabulary for documented diagnoses [international classification of diseases (ICD), systematized nomenclature of medicine (SNOMED)]?
Maintaining an active medication list | - Who in the clinic is responsible for their routine medication reconciliation process to ensure medications are current in the EHR?; - Are medications mapped to standard drug codes [national drug code (NDC), RxNorm] or can free text or custom medications/supplements be prescribed?; - Is there a consistent process for electronically prescribing medications including: phone orders, refill requests, and controlled substances?; - Are paper prescriptions ever used?
Maintaining an active allergy list | - Are patient allergies for food or drugs consistently recorded using a standard vocabulary?
Recording smoking status [and other health screening assessments] | - When and how are screening questions for health risk (smoking), preventive care (depression screening), behavior (alcohol use) and social needs recorded in the EHR?; - Are individual questions from health screening assessments captured in the EHR as structured data versus scanning a questionnaire?; - Are billing codes used to determine when screening services are delivered or may be overdue?
Providing patients with clinical summaries for each office visit | - Can patient summaries produced by the EHR provide context or detailed data to patients for a QI intervention?; - Can paper or electronic care summaries deliver education or self-care interventions?; - Do patients have full access to office notes online?
E-prescribing | - Are medications mapped to standard drug codes (NDC, RxNorm)?; - Can free text or custom medications/supplements be prescribed?; - Is there a consistent process for electronically prescribing medications including: phone orders, refill requests, and controlled substances?; - Are paper prescriptions ever used?
Checking for drug-drug and drug-allergy interactions [Clinical Decision Support] | - How receptive are prescribers to drug-drug and drug-allergy alerts? This may be a warning sign of alert fatigue making new CDS interventions difficult to implement.
Exchanging electronic information with other sites of care | - How are care summaries and consultation reports received by the clinic?; - Are external electronic care summaries incorporated into the patient’s chart?; - Are paper or faxed summaries scanned or uploaded into the EHR?; - How can external data be accessed and extracted from the EHR?
Implementing a decision support rule and tracking compliance with the rule [Clinical Decision Support] | - Has the clinic implemented CDS rules for preventive care reminders or other alerts that could inform or support a QI intervention?; - What other forms of CDS could be used to deliver quality interventions (templates, online resources, etc.).
Maintaining systems to protect privacy and security of patient data | - How do workflows for protecting patient data impact the availability and accessibility of key data elements? For example, are paper forms shredded after recording findings in the EHR.
Reporting CQMs to CMS or States | - Has the clinic implemented the EHR workflows needed to accurately and consistently populate quality measure dashboards and reports in the EHR (MIPS, UDS)?; - Does the clinic have alternatives to EHR reporting including external registries, population health tools, or access to a health information exchange?
Generating lists of patients for QI or outreach | - What tools and workflows are available for pulling ad hoc lists of patients with specific conditions, visit types, demographics, or other registry criteria?
Providing electronic health education resources | - Does the EHR provide online education resources for patients and caregivers at visits or through the portal that could be used to deliver a QI intervention?
Performing medication reconciliation between care settings | - Does the clinic use a routine medication reconciliation process to ensure medications are current in the EHR?
Generating summary of care record for referrals and transitions | - What are the workflows for sending and receiving patient information when referring or transitioning patients to acute, specialty, or long-term care?; - How do processes differ for referrals to internal groups using the same EHR and those external groups using other EHR systems?; - Are EHR workflows for referrals and transitions consistently used, or are there other ways the clinic requests and tracks them outside of the EHR (fax, an HIE)?
Providing immunization data to regional registries | - Does the clinic routinely update immunizations from outside sources (state registry, pharmacies, other providers)?; - Are immunizations mapped to standard codes (CVX, MVX), or can free text vaccines be entered?
Providing surveillance data to public health agencies [Registries] | - Can the clinic identify and report a list of patients with specific conditions based on diagnosis, lab results, symptoms, or other criteria?; - Does the EHR provide demographic, disease, or condition-specific patient lists, or registries, that can be used for targeted QI interventions?
Using patient reminders for prevention/chronic care [Clinical Decision Support] | - Has the clinic implemented CDS rules for preventive care reminders or other alerts that could inform or support a QI intervention?; - Are there prompts and reminders for routine and follow-up appointment scheduling?; - What other forms of CDS could be used to deliver quality interventions (templates, online resources, etc.).
Providing patient access to lab results, problem and medication lists, and allergy information | - What options do patients or caregivers have for accessing their own clinical information in the EHR?; - What information can patients or caregivers access using the clinic’s portal?; - Do portals or other patient engagement tools (voice and text messages, email, mailings) provide options for targeted QI interventions?
Performing drug formulary check | - Do prescribers have access to payer-specific drug lists (or formularies) when they select medications in the EHR?
Entering lab results into EHR | - Do workflows for entering or receiving lab and imaging results populate structured (discrete) or unstructured (text) data elements?; - Are lab values mapped to standard LOINC (logical observation identifiers, names, and codes) or SNOMED codes by sending labs or in the EHR?

Source: The 23 EHR workflows described in this table are from a Bodenheimer communication cited in Module 26 of the AHRQ Primary Care Practice Facilitation Curriculum.[39]

### Workflow Analysis as a Tool for EHR Data Exploration

Health IT Advisors must know how to observe, document, analyze, and improve clinical workflows to fully understand how data from an EHR can be used in their projects.

A “workflow” is a collection of activities (or tasks) performed to achieve a specific outcome. This outcome might be a physical artifact (filling out a form), an electronic record (documenting findings from a medical examination or laboratory test), or a trigger for additional workflows (a portal reminder prompting a patient to take a home blood pressure reading).

EHR workflows are often observed and mapped as part of a QI project for four main reasons:

- To collect the data needed to design improved work practices
- To better support population health
- To illustrate how clinical processes were done before and after a workflow change or quality intervention, and/or
- To discover how specific data elements are collected, captured, and viewed in a clinic’s EHR.

While a how-to guide for conducting workflow analysis using all of the available tools and techniques is beyond the scope of this handbook, we present three practical steps that can use workflow analysis as a tool to identify potential data sources, workflow variations, and identify limitations of data from the EHR.

#### Step 1: Identify workflows that impact EHR data

The twenty-three workflows in Exhibit 16 are central to collecting, recording, storing, and retrieving data elements that may be useful for QI. Before drawing any conclusions from the data, Health IT Advisors must carefully identify how and where data are acquired (by humans or computers) and the process used to transform real-world information (a blood pressure reading, a lab result, a faxed consult report) into electronic data structures stored in an EHR.

#### Step 2: Conduct a targeted workflow analysis

The opportunities to study a clinic’s use of an EHR will largely depend on how much access the health IT Advisor has to the clinic. Many times, it is not possible to directly observe clinicians and staff as they interact with the EHR, and remote or virtual methods may be necessary. Below are three options.

- Option 1: Directly observing important workflows is the best way to understand how clinicians and staff use their EHR. Health IT Advisors can document their findings in brief field notes or jottings, sketches and diagrams, or even audio or video recordings that do not expose PHI.
- Option 2: When visiting the clinic is not an option, ask for a virtual demonstration of the workflows you are interested in. Screen-sharing or online collaboration software can be used to virtually interview users.
- Option 3: As last resort, a lot can be learned about EHR workflows by collecting forms, screenshots (being careful of PHI), job aids or “cheat sheets,” written procedures, or user manuals. Be careful of using proprietary materials provided by vendors without explicit permission.

Remember that variations in workflow are not uncommon even within the same clinic. It is important to ask if an observed workflow is the same for all users and is consistently followed to see if there are workflows that might impact your data or interventions.

#### Step 3: Analyzing workflows to assess EHR data

The results of a targeted workflow analysis are usually represented by a diagram. This can be a simple flow chart or a swim-lane chart (splitting workflows into lanes for each actor). An experienced process analyst might even use a data flow diagram used by software engineers to illustrate how data travels through a clinic.

An example of a practice workflow for an office visit for blood pressure control (with care-team roles highlighted) is shown in Exhibit 17. This could be modified for a targeted workflow analysis to focus only on the tasks that directly) or indirectly) impact the data (the box for the medical assistant, in this example).

[image] | EXAMPLE:; Given the importance of blood pressure findings from the EHR to your project, you do a targeted workflow analysis to study how blood pressure readings are captured in a telehealth visit. You find that patients or caregivers have the option to enter home readings when they check in to the online appointment and are surprised to see that a free text entry box is used with no validation for a standard reading (e.g., “140/80”).; This discovery is a red flag that you will need to take extra care to ensure improperly formatted home blood pressure readings are not distorting the clinic’s performance on hypertension control when you extract and analyze the EHR data.

Exhibit 17 Example of a Workflow Diagram for Blood Pressure (BP) Control

Flowchart of a sample workflow as described in text above.

Module 10 (https://www.ahrq.gov/sites/default/files/wysiwyg/ncepcr/tools/PCMH/pcpf-module-10-workflow-mapping.pdf) of Primary Care Practice Facilitation Curriculum provides guidance on how to conduct a workflow analysis and reviews how flowcharts and swim-lane diagrams are constructed, as does the Practice Facilitation Training Module Process Mapping (https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation/modules/index.html#mapping). AHRQ has also developed a comprehensive toolkit (https://digital.ahrq.gov/health-it-tools-and-resources/evaluation-resources/workflow-assessment-health-it-toolkit) for Health IT workflow analysis with a detailed discussion of workflow tools and techniques.

## 2.3 Assessing EHR Data Quality

A clinic’s EHR will often be the best (and sometimes only) option to facilitate QI. Care must be taken, however, to ensure that the quality of underlying data elements is sufficient to accurately measure quality, inform practice transformation, and/or trigger health-IT based interventions.

This section reviews data problems often encountered in QI projects and provides tips to prevent, identify, and address troublesome data you will find in EHRs and other electronic data sources.

### Common Problems with EHR Data

Before discussing what can go wrong with EHR data, it may help to consider what “good” data looks like. There are numerous practical and scholarly approaches that define (and even quantify) various aspects of data quality. The ONC model below defines five dimensions of data quality that can serve as a framework to discuss the characteristics of “good” EHR data.[40]

Each of the five dimensions shown in Exhibit 18 should be a prompt for Health IT Advisors to think critically about any EHR data they use in quality work.

Exhibit 18 ONC’s Five Quality Dimensions for EHR Data

Data Quality Dimension | Definition
Completeness | Is the truth about a patient present in the EHR?
Correctness | Is an element that is present in the EHR true?
Concordance | Is there agreement between elements in the EHR or between the EHR and another data source?
Currency | Is an element in the EHR a relevant representation of the patient state at a given time?
Plausibility | Does an element in the EHR make sense in light of other knowledge about what the element is measuring?

Consider asking each of these questions as you assess project data:

#### 1 Completeness: Are any needed data missing or incomplete?

Despite our best efforts, healthcare is delivered in multiple places by multiple providers and caregivers. This leads to a fragmented medical record scattered across many instances of electronic (and paper) records used by hospitals, laboratories, specialists, behavioral and community service providers, and other “silos” where health data can be found. Examples of incomplete data include the following:

- Inconsistent user workflows can lead to missing data. Example: Not all A1c values are recorded as structured data.
- The clinic does not receive key data elements needed for QI. Example: Outside care summaries or specialty reports are not received.
- Needed historical data might pre-date new workflows or system configurations. Example: New fields were created for a recent health screening assessment.

#### 2 Correctness: Are the data accurate?

Correct data are not only accurate (truly reflecting a real-world patient attribute or finding) but are also captured in the expected data structure and format (see home blood pressure example above). Incorrect data might result from the following:

- Users forget to clear or change default selections from documentation templates or questionnaires.
- Users record data in notes or clinical narratives instead of available structured data. Example: A medical assistant types the result of a depression screening in the notes instead of the screening form.
- Expected numeric data, units of measure, or free text are entered with an incorrect format. Example: A medical assistant types “Left arm140over 80” instead of the expected “140/80” for a blood pressure reading.

#### 3 Concordance: Are the data consistent and in the proper context?

Discordant data can be difficult to detect when looking at raw data in a spreadsheet. Correlating suspicious data might require a manual chart check for corresponding records or to comparing project data with related clinical information. Examples of discordant data include the following.

- Missing or conflicting documentation of key data elements: Example: No colonoscopy report exists despite a structured data field indicating that one was done.
- Laboratory values from different sources with different units or analytical methods: Example: Lab A reports an A1c .075 versus Lab B that provides the percentage 7.5%.

#### 4 Currency: Are the data in the EHR the most current?

Data currency is usually determined by the dates and times (or “timestamps”) attached to a data element. For example, a laboratory result might include when a sample was collected, when a result was reported, and even when a clinician reviewed the result. Here are some examples where data currency may not be obvious.

- Key data elements are pulled forward from previous visits or history. Example: The EHR pulls data in the social history section forward to the current record, but the previous data were not confirmed during the visit.
- The EHR data reflects when the element was entered and not when it was first identified. Example: When a new diagnosis is added to the problem list, the timestamp reflects today’s visit and not when the problem first began (“added date” versus “onset date”).
- There may be more recent data available outside of the clinic EHR. Example: Tests, referrals, hospital visits, procedures, and referrals may all be missing from the clinic’s EHR unless workflows exist to retrieve and incorporate them.

#### 5 Plausibility: Do the data make sense?

A subjective “gut check” can often identify troublesome data. For example, laboratory values outside of the range of human life are an obvious clue that there is an issue with the EHR process for receiving, recording, or reviewing test results. Additional examples of implausible data include the following:

- Numeric values or structured data impossible or incompatible with life. Example: A percentage value over 100%.
- Findings that are unusual or inappropriate for a patient’s attributes. Example: A recorded smoking status on an infant.
- Blatant data inconsistencies in the data. Example: A patient both received and declined screening for social needs.
- Data errors introduced during extraction or analysis. Example: Data elements are automatically reformatted by a spreadsheet application when the EHR data file is imported.

### Techniques for Assessing the Quality of EHR Data

Many techniques have been developed to assess the completeness, correctness, concordance, currency, and plausibility of EHR data. [40] While a review of formal data quality assessment methods is beyond the scope of this handbook, below are some practical tips to ensure that data elements extracted or abstracted from an EHR accurately represent the clinic’s quality and performance.

[image] | TIP 1: FOLLOW THE DATA; Earlier, we discussed how technical design, configuration, and workflows all affect the presence and reliability of data in an EHR. A simple approach to compensate for all this variation is to directly observe how and where users document the key data elements needed for the project. Although this technique can be done at the same time as a formal workflow analysis, following the data is more focused on how and where specific data elements are captured in the EHR. We refer to this as a targeted workflow analysis (addressed earlier in this section).

[image] | TIP 2: INSPECT THE DATA FOR “RED FLAGS”; The quality of EHR data should never be taken for granted. Formal research studies require rigorous protocols and statistical analysis to assess data quality, but QI projects may lack the time, expertise, and resources for this. Below are red flags that can help detect data quality problems:; Missing data often indicates that the clinic’s EHR records may not be complete, consistent, or accurate.; Compare the available data elements within the data set for concordance. Example: Do all values for laboratory results and vital signs have realistic dates?; For numeric values, calculate the median, mean, and standard deviation to detect outliers or unusual variation. A box-plot can be especially helpful to detect outliers. Example: Is a mistyped A1c value of “76%” skewing the sample?; Graph the data on a scatter plot to quickly identify potential gaps or anomalies in the data.

[image] | TIP 3: COMPARE EHR DATA WITH A GOLD STANDARD, BENCHMARK, OR ADDITIONAL DATA SOURCES”; When direct access to a clinic’s EHR is available, it may be possible to compare supporting documentation within the patient record with the extracted data used for a project. Project data can also be correlated with external data sources. (Also see discussion of this in Section 1.8).; Seek corresponding data from other electronic or paper sources. Example: External data sources including health information exchanges and specialty registries may provide data not found in the clinic’s EHR.; Use an external performance benchmark from national or quality organizations for similar clinics to find values for comparison.; Compare denominators and numerators from similar measures. Example: The denominator for one quality measure could be used as a sample for a manual chart audit for a similar measure.; Search the medical literature for disease prevalence to “gut check” a clinic’s population. Example: Does the clinic’s diabetes or hypertension rate seem reasonable compared to national or regional prevalence data?

[image] | TIP 4: ASK THE CLINIC FOR A “GUT CHECK”; Clinics usually have a good subjective idea when their data seems off. Periodic “data checks” can be part of an overall project communication plan to create an opportunity to get another set of eyes on the data. Here are some additional tips:; Be careful not to overwhelm clinics with raw data. The idea is to assess the “reasonableness” of the data you have collected; summary data is generally best for this. Example: Share the number of qualifying visits for depression screening with the clinic and not a list of 3,000 non-compliant patients.; Focus on intuitive metrics to share with clinicians and staff. For example, a clinic administrator will know when values for certain visit types or billing codes seem plausible while a quality manager can quickly determine if performance on quality measures seems off.; Follow up on any concerns the clinic may have. It is not unusual for an EHR quality measure to seem “just wrong” before implementing the necessary workflows to populate specific codes according to the vendor’s best practices.

[image] | EXAMPLE:; Using an EHR’s quality dashboard, you retrieve the performance rate for Depression Screening and Follow-up (CMS 2, NQF 418). When the clinic reviews the data, they are shocked and tell you this cannot possibly be right. On investigation, you learn that the EHR is relying on a structured data field to determine whether follow-up was provided on positive screens. The clinic does not use this field, throwing the measure off substantially.

#### Assessing EHR Data for a Quality Measure

In this extended example, you are helping a primary care clinic improve their annual screening for risky alcohol use. In this example, we have simplified the quality measure for illustration purposes.

The clinic’s performance on Screening and Brief Intervention and Referral to Treatment (SBIRT)[41] will use the quality measure for “Unhealthy Alcohol Use: Screening and Brief Counseling” (CMS 431, NQF 2152)[34] that counts eligible patients, screening rates, and whether a qualifying intervention was delivered on a positive screen.

You begin by identifying the data elements needed to generate the quality measure for the project and create a table like that in Exhibit 19 or the Data Collection Plan introduced earlier to explicitly list the data elements needed to satisfy the measure and make note of any potential questions or concerns. You have confirmed that resources are available to generate an EHR extraction file with the data you need.

Exhibit 19 Data Components of the SBIRT Quality Measure (CMS 431, NQF 2152)

Data Component | Elements | Further Considerations
How many patients were eligible for SBIRT screening? | - Patient age (Integer); - Encounter code for visit [current procedural terminology (CPT)]; - Excluding diagnoses (ICD-10); - Patient refused screening (Yes/No) | How is “eligibility” is defined and what inclusion and exclusion criteria will be used to select patients?
How many eligible patients received SBIRT screening? | - SBIRT given? (Yes/No); - SBIRT date and time; - SBIRT tool used (List of assessments) | Of those eligible, who received screening, when, and what assessments were used [Alcohol Use Disorders Identification Test (AUDIT), Alcohol Use Disorders Identification Test-Consumption (AUDIT-C), CRAFFT].
How many SBIRT screens were “positive”? | - Result of SBIRT screen (Positive/Negative); - Additional assessments (Type, Score) | What constitutes a “Positive” for the assessment tools being used? How are the screening results represented in the EHR?
How many “positive” screens resulted in a brief intervention? | - Was an intervention given? (Yes/No); - Intervention date/time; - Type of intervention (List of interventions); - Was this a qualifying intervention (Yes/No) | How many patients received a qualifying intervention, when, and what type (counseling, a referral, or medication).

The following are more specific steps to take in putting the tips above into practice:

Step 1: Follow the data

- Do a targeted workflow analysis to determine if, when, and how the required data elements are collected and entered in the EHR. Tips for observing workflows are discussed in Section 2.2.
- Map the required data elements for the quality measure to the information in the EHR by observing users or reviewing screen shots (being careful to protect PHI!)

Step 2: Inspect the data for “red flags”: Inspect the extracted data file for potential issues, asking the following questions:

- Are the data adequate to determine each patient’s eligibility for a SBIRT screen?
- Does the total number of eligible patients pass a “gut check”?
- Are there gaps or coding issues with the encounter codes exported to the file?
- Are there any outliers or obvious format errors in dates, numeric data, or coded values?
- Are coded values for screening assessment and interventions what is expected?
- Are dates and times associated with SBIRT screening and follow-up realistic?

Step 3: Compare EHR data with a gold standard, benchmark, or additional data sources

- Finding appropriate comparison data in this example could be difficult. Some options to consider include the following:
  ○ Confirm the patient age distribution against known values for the clinic
  ○ Find a reasonable benchmark for a “typical” number of patients eligible for screening
  ○ Make sure screening tools, scoring criteria, and risk interpretation are consistent with a validated assessment tool.
  Example: You find that data for the AUDIT, an assessment used to score risky alcohol use, are included in the data set, but the questions and scoring found in the EHR do not match the validated assessment. How can this be best addressed?

Step 4: Ask the clinic for a “gut check”

- To avoid overloading clinic staff, a “gut check” for this example might include the following:
  ○ A preview of the performance rate for a short measurement period
  ○ The total number of eligible visits; does this track with the total visits during that period?
  ○ A chart showing frequency of specific intervention types; is it realistic that all of these services were delivered?

### Conclusion

The wide adoption of EHRs by medical practices has created a wealth of data that can be used to support QI projects. Knowing where to start begins early in the project and the implications of poor-quality data must be clearly understood and addressed. While not all projects will require all of these steps, Health IT Advisors must always ensure data quality before using any EHR data for a project.

## 2.4 Core Principles for Handling EHR Data

Health IT Advisors have a legal and ethical obligation to follow best practices when handling data both within, and extracted from, an EHR. Data governance refers to a set of best practices for handling all types of data and provides a useful framework for handling the EHR data used for QI.

This section is presented in two parts: the first addresses general concepts for data governance; the second focuses on a brief review of HIPAA and other privacy and security requirements.

### The Information Lifecycle

The information (or data) lifecycle contains all of the processes needed to collect and manage data. The lifecycle model shown in Exhibit 20 was developed by the American Health Information Managers Association (AHIMA; now under copyright to Iron Mountain)[42] and can be used by Health IT Advisors as a comprehensive framework to ensure accountability, transparency, integrity, protection, compliance, availability, retention, and disposition of any clinical data used for QI.

We will use the Iron Mountain lifecycle model to provide tips for the collection, use, storage, and disposal of EHR data used in the course of a QI project.

Exhibit 20 Information Governance Framework and Lifecycle

Graphic adapted with permission. © 2022 Iron Mountain Incorporated. All Rights Reserved.

The Information Governance Framework and Lifecycle from Iron Mountain includes blue boxes across the top that include Metrics, Controls, Policies, Procedures, Rules, and Roles. Then, in green, the lifecycle is shown as a process starting with Capture, then Process, then Use, then Store, then Dispose. Under that is a red bar with the words Share/Exchange. Finally, a purple bar presents Information Governance Principles: Accountability, Transparency, Integrity, Protection, Compliance, Availability, Retention, and Disposition.

### Capture: Acquiring Quality Data from the EHR

Data stored in an EHR can come from multiple sources. For example, a single EHR may include data from internal sources (data entered by typing, scanning, dictating, touchscreen, etc.) and external sources (outside results, summaries, immunization, medication, acute or long-term care records, etc.).

Moreover, data in an EHR may be created or reported by a wide range of actors, including providers, staff, electronic interfaces, and patients or their caregivers through the use of portals and phone apps (patient-generated data is discussed in Section 5).

When using EHR data, it is vital that the original source be considered including the following questions:

- Where did the data originate from and who created or reported it?
- Who is accountable for ensuring accuracy and completeness of data at the point of collection?
- How is it incorporated into the EHR and by whom (user or automated processes)?
- If data originates on paper forms, are they kept?
- Are special protections needed when accessing stored paper records?
- Is there a risk of data being hidden, lost, or altered when it is incorporated into an EHR?

Importantly, too, custom methods developed for acquiring quality data from the EHR should be added to the clinic or system’s Data Quality Improvement Plan (see Section 1.7).

### Processing: Extracting Data from an EHR

The methods used to pull data from an EHR will vary depending on several factors discussed below; however, the following considerations apply to all methods. Health IT Advisors must ensure that data are not lost or altered during retrieval from reports and dashboards, electronic extraction from the EHR, or abstraction from manual chart audits.

- Are required data agreements in place before accessing the EHR data?
- Who is responsible and accountable for extracting /abstracting data from the EHR?
- Who will control and monitor the quality and integrity of the data retrieved from the EHR?
- How will you ensure privacy, security, and integrity when processing and transporting the data?
- If required, how will the retrieved data be de-identified, encrypted, or securely transmitted?
- Is the extraction file format appropriate for the data to be extracted [comma separated value (CSV), proprietary file]?

### Use: Managing EHR Data after Extraction/Abstraction

The goal of extracting EHR data is to draw meaningful and accurate conclusions about patient populations, clinical quality and performance, or outcomes of quality interventions. Here are some considerations for managing extracted data:

- Who will manage, update, maintain and protect data sets after extraction (paper or electronic)?
- Are there constraints on how EHR data can be used or shared within and outside the team?
- Are there any data elements that require special care under HIPAA and other regulations?
- Has the quality of the extracted data been assessed prior to using it for the project?

### Storage and Disposal: Protecting and Disposing of Extracted EHR Data

Most data acquired from a clinic’s EHR will contain PHI falling under HIPAA privacy and security rules (see Section 2.5 below). Storage and final disposition of the data used for a quality project are sometimes an afterthought, but these considerations are important to meeting requirements for privacy and security.

- Will PHI and other sensitive data be removed from the clinic (electronic, paper)?
- Does the quality team have appropriate training in handling sensitive data?
- Are all required agreements in place authorizing the storage and use of EHR data?
- Are procedures in place to use transfer, store, and dispose of EHR data used by the team?
- Is the technology used to store electronic EHR data approved and configured for PHI?
- Are the data extracted from the EHR the “minimum necessary” for the project?
- How long can data be stored and who manages and disposes of “old” data?

## 2.5 Privacy and Security Considerations for EHR Data

No discussion of data governance would be complete without addressing the unique regulatory requirements involved in retrieving, handling, and storing clinical data defined as PHI under the Health Insurance Portability and Accountability Act’s (HIPAA’s) privacy rule.

PHI is defined by the HIPAA Privacy Rule (https://www.hhs.gov/hipaa/for-professionals/privacy/index.html) as demographic data, which relates to: the individual’s past, present or future physical or mental health or condition; the provision of healthcare to the individual; or the past, present, or future payment for the provision of healthcare to the individual. It is also data that identifies the individual or for which there is a reasonable basis to believe it can be used to identify the individual. Individually identifiable health information includes many common identifiers (e.g., name, address, birthdate, Social Security Number).[43]

As discussed in Section 1, Health IT Advisors working with EHRs will have access not only to PHI, but other types of data protected by national and/or state regulations. Any quality team members who work with these data should have, at a minimum, documented HIPAA training and a thorough understanding of their obligations to the clinic as a participant in a Business Associate Agreement or through a Data Use Agreement mentioned earlier in the handbook.

In addition to HIPAA, other laws or regulations may constrain how EHR data can be used in a project, and how it must be managed and disposed of if taken out of the clinic on paper or electronically. Examples include the following:

- Rules set by the Institutional Review Board that approved the project
- Organizational rules for protecting and storing sensitive data
- Additional protections for data relating to mental health and substance use (code of federal regulations (CFR) 42 Part 2) [44]
- Special protections for educational records [Family Educational Rights and Privacy Act (FERPA)][45]
- Financial and administrative data that should not be shared outside the team.

## 2.6 Extracting Data from an EHR

This section addresses how EHR data can be retrieved from built-in EHR reports and dashboards, extracted to an electronic data file, or abstracted by visual inspection of the electronic chart for use in a QI project.

### Using Built-In EHR Reports and Audits

EHRs offer many standard reports and audits that can be useful for QI work. Unfortunately, few users take the time to explore all of the reporting options available to them and may overlook a relatively easy way to retrieve data for a project.

Built-in, or “canned,” reports and audits cover the spectrum from financial reports (daily charge summaries, missing billing codes), security audits and logs (login attempts, clinical decision support system (CDSS) overrides), administrative reports (patient no-shows), and enrollment and management for special programs (Medicare Chronic Care Management services).

Clicking through the “Report” or “Quality” menus in an EHR can uncover a variety of useful reports including patient lists, quality measures, clinical decision support logs, and specialty reports. Often, the clinic may not be aware that these reports are there, but make sure you have permission before you browse.

Exhibit 21 Advantages and Challenges of Using Built-In EHR Reports and Audits

Advantages | Challenges
- Leverages existing EHR capabilities; - Available with little or no configuration; - Output can often be exported to Excel or CSV; - Standard reports can be compared across clinics | - The vendor defines the format and contents; - Access may be restricted; - Vendors may charge extra for specialty reports; - Not all reports work “out of the box”; - May include more data than is needed; - Need to validate data in reports

### Using EHR Registry Searches and Patient Lists

Many EHRs provide powerful search tools to pull lists of patients who meet specific criteria for diagnoses, encounter history, results of screening or laboratory tests, medications, provider panels, patients attributed to payers, and many other parameters. Examples of the names vendors use for this feature includes “Registry” (eClinicalWorks), “Report Builder” (Athena Health), and “Report Workbench” (Epic). Note that registries external to EHRs are addressed in Section 7 and can also be a valuable source of data.

Pulling filtered patient lists from a registry can be a powerful tool for QI. Not only can subpopulations of patients be found meeting very specific parameters, but EHRs often integrate patient lists with features to view the chart, launch patient messaging, create alerts, or identify patients with special needs or chronic illness for targeted care management.

[image] | EXAMPLE:; You want to pull a list of all of the clinic’s adult patients with diabetes seen within the last six months for a targeted intervention. After reviewing the EHR’s registry feature, you find that a search can be created for the needed age range, specific diabetes diagnoses, a visit date within your project’s time range, and whether they have already received the intervention (assuming this is recorded in the EHR).

Exhibit 22 Advantages and Challenges of Using EHR Registry Searches and Patient Lists

Advantages | Challenges
- Leverages existing EHR capabilities; - Available with little or no configuration; - Offers flexible search and filter options; - Output can often be exported to Excel or CSV; - Registries are used by clinics for population health | - Access may be restricted; - Creating a search may take some training; - Not all vendors provide these tools; - Vendors may charge for advanced reporting; - Need to validate data in reports

### Using EHR Dashboards

Dashboards are a form of built-in report designed to calculate and display a variety of clinical, process, and financial metrics. Because many EHR incentive programs (MIPS, UDS) require reporting of EHR-generated measures (CQMs), most EHRs provide a dashboard that can present a selection of quality measures chosen by the vendor.

Most certified EHRs can present both aggregate data (numerator, denominator, exceptions, exclusions, and performance rates) and patient-level details using graphical and tabular formats that can be saved to Excel or a CSV file. Lists of patients who meet or fail to meet a specific quality measure are often called “gap lists,” and these are discussed further in Section 6.

A robust dashboard will allow users to filter and segment quality measures so that patient sub-populations and measurement periods can be adjusted to fit the project (these may be available as an add-on purchase to the EHR or as a third-party product).

Note that smaller vendors may choose to partner with a third-party or registry to provide an external dashboard. For example, the Prime Registry (https://primeregistry.org/) is available to members of the American Board of Family Medicine diplomates at little or no cost. External registries and dashboards are discussed in Section 7 along with tips for finding out which measures are supported by a given EHR.

[image] | EXAMPLE:; In preparing for the diabetes project, you find that the clinic’s EHR quality dashboard has a certified quality measure for Poor Diabetes Control (CMS 122, NQF 0059) [34] that will work for the project; however, it does not support the measure for Diabetic Eye Exam (CMS 131, NQF 0055).[34]

EHR vendors can pick and choose which quality measures they wish to develop or package as an additional module for population health management. When a needed CQM is not provided by an EHR, your only recourse is to seek alternatives to extract the raw data (see below) or to seek it elsewhere (see Section 7).

Exhibit 23 Advantages and Challenges of Using EHR Dashboards

Advantages | Challenges
- Leverages existing EHR capabilities; - Vendor eCQMs must pass certification; - Dashboards may provide useful filters; - Dashboards can link to patient-level data | - Vendor’s measure logic can be hard to validate; - Measure logic usually cannot be changed; - Measures rely on specific workflows for data; - Needed measures may not be available or free; - Need to validate data in reports

### Extracting EHR Data to Electronic Media

Creating custom programs or reports to extract EHR data is an appealing option for QI work. The data extracted by a custom extraction will exactly match the needs of the project and the output can be tailored to streamline review, assessment, and easy integration with spreadsheets, external databases, or analytics software. Unfortunately, developing the queries needed to extract EHR data comes with several challenges.

Exhibit 24 Advantages and Challenges of Using Custom Extraction

Advantages | Challenges
- A custom report or query extracts only the needed data elements for the project; - The output can be tailored to streamline review, transfer, and analysis; - Raw data files can be imported into external databases or combined with other data sets; - Some quality teams have extensive experience in extracting data from EHRs; - A custom query can be programmed and run without clinic participation (provided access is granted) | - EHR reporting tools can be costly and difficult and can be difficult to learn; - “Back-end” database access may be limited (or prevented) by the vendor or IT department; - Custom reports and queries are often a low priority for local IT resources, or costly for a vendor to develop; - EHR databases are not standardized, requiring detailed knowledge of each product; - The access required to create custom extracts can expose sensitive information; - It takes time experienced developers to design, write, test, and deploy a custom query; - Queries may have to be adapted for use in other clinics using the same product; - Need to validate data in reports; - Custom reports often stop working with new EHR versions

Unless the project team has the access, resources, time, and knowledge to develop custom EHR reports or queries, Health IT Advisors are advised to prioritize other methods to obtain needed data.[46]

FHIR, the future of EHR data extraction for quality?

Health IT Advisors have a limited choice of options to retrieve, extract, or abstract data from an EHR to support QI projects. The government and healthcare industry both recognize that there is an urgent need to make secure retrieval of EHR data much easier for patients, providers, and payers.

Encouraged by federal requirements to alleviate “information blocking” under the 21st Century Cures Act, vendors have started opening their EHRs to application programming interfaces (APIs) using an interoperability standard called FHIR ®, which has been developed by Health Level Seven International (HL7®).

Updates to the MIPS certification requirements in 2022 will require vendors to supply APIs to extract with patient and population level data needed to measure quality and calculate CQMs.

The FHIR framework is discussed in Section 10 of the handbook. See fact sheets (https://www.healthit.gov/topic/standards-technology/standards/fhir-fact-sheets) for more information about FHIR.

### Using Chart Audits to Abstract EHR Data

Compared to the convenience of using existing EHR reports or the complications of developing custom extracts, using a chart audit to retrieve EHR data for QI is often a last resort. Manually abstracting data is labor-intensive and requires broad access to patients’ records to find and record needed data elements.

Exhibit 25 Advantages and Challenges of Using Chart Audits to Abstract EHR Data

Advantages | Challenges
- A “low tech” option that can be used anywhere; - Provides data for QI while data challenges (e.g., mapping errors) are resolved; - Provides access to non-structured data; - Can provide data for rapid testing of process improvements that have not yet been spread throughout the practice; - Sampling strategies can reduce the work effort; - Procedures for abstraction are more flexible; - Can usually be done remotely | - Requires significant time and resources; - Quality of data can vary depending on auditor; - Auditors require broad access to patient records; - A sampling strategy may exclude important data; - Clinics may be reluctant to allow access to charts

#### When should chartaudits be used?

Sometimes, when a chart audit is not prohibited by limited resources and physical (or virtual) access, doing a manual chart audit to retrieve EHR data can actually be the best choice. Health IT Advisors might consider doing a chart audit to collect data in the following situations:

- When clinics are already are doing chart audits and are willing to collect extra data
- When a small number of records needs to be audited to provide required data elements
- When required data elements are “hidden” in narrative text, notes, or scanned documents
- When additional interpretation or context is needed to collect the needed data elements
- When measures produced by EHR reports are challenged as inaccurate
- When the use of a sampling strategy will not impact data quality
- When testing improvements with a subset of the practice
- When there is a desire to validate the data coming from automated reports
- When there are no other options to retrieve EHR data.

[image] | EXAMPLE:; In a previous example, your goal of extracting A1c values directly from the EHR was complicated by the significant number of results “hidden” in scanned documents. Once you have ruled out modifying workflows to capture structured data, using an existing EHR report, dashboards, or requesting/developing a custom query, then a protocol to extract the lab results visually from the scanned documents may be the only choice.

#### Procedures for Conducting Chart Audits

Health IT Advisors should be familiar with the best practices for sampling, record access, rules for handling missing or discrepant data, and procedures for handling PHI. For example, in addition to planning the design and logistics, a data abstraction form like the one shown in Exhibit 26 should be developed to ensure consistent data collection.

For those not familiar with procedures for auditing electronic (or paper) charts, we recommend “8 Steps to a Chart Audit for Quality (https://www.aafp.org/fpm/2008/0700/pa3.html)” by Gregory, et al.[47] For a more detailed introduction to conducting chart audits, see Module 14 (https://www.ahrq.gov/sites/default/files/wysiwyg/ncepcr/tools/PCMH/pcpf-module-14-collecting-performance-data.pdf): Collecting Performance Data Using Chart Audits and Electronic Data Extraction, of the Primary Care Practice Facilitation Curriculum, as well as a related Practice Facilitation Training Module on chart audits (https://www.ahrq.gov/downloads/ncepcr/pf-modules/chart-audit/story.html).

Exhibit 26 Sample Data Abstraction Form for Use in a Chart Audit[48]

Image of a sample diabetes chart audit form as described in text above.

## 2.7 Obtaining EHR support for Quality Improvement Projects

Health IT Advisors will encounter a wide range of EHR vendors, products, and versions when working with clinics. While this handbook emphasizes common themes, no individual can be an expert on every EHR. In this section, we provide tips on where to turn for support.

In most cases, the type of support required will determine whether an experienced colleague on the quality team, local experts within the clinic, or direct contact with the EHR vendor (with a representative of the clinic present) is needed to address a question or issue. Below are some common areas where EHR support may be needed:

- Education and training
- Population health reporting
- Clinical decision support
- Design and configuration options
- Clinical content
- Troubleshooting and bug fixes
- Enhancement requests
- Custom reports and programming
- Peer group support
- Best practices
- IT and communications infrastructure
- Security and compliance
- Health information exchange and interoperability

The EHR support most accessible to a Health IT Advisor will be the quality team assigned to the project. Often, another Health IT Advisor will have run into a given situation or have previous experience with a specific EHR product.

The second-best resource is the clinic’s internal EHR support. In many small practices this might be a medical assistant trained as a “super-user” or a tech-savvy clinician. In larger organizations there may be dedicated IT support that can help with EHR or data questions. Be sure to get approval before approaching clinic staff outside of the project team. Going outside of the official contacts for the clinic, even with the best intentions, may damage relationships.

The last line of support will be the EHR vendor. Health IT Advisors will rarely have direct access to a vendor’s help desk or online support tools unless working for the clinic or having access through their own organizations.

[image] | EXAMPLE:; Your team has a great idea for a quality intervention that uses the EHR’s CDS capabilities to generate an alert that blocks providers from ending a visit without asking about smoking. It is tempting to ask IT directly whether this alert is feasible and how long it would take to implement but doing this runs the risk of damaging your relationships.

[image] | TIPS FOR ACCESSING SUPPORT RESOURCES:; 1. At the beginning of the relationship with a clinic, Health IT Advisors should assess their internal and external EHR support capabilities by asking the following questions during the planning stage of a project (also see Section 1.1):; - Who is responsible for the day-to-day operation and maintenance of the EHR?; - Who do you call when there are software, hardware, or network issues?; - Who approves and manages upgrades, enhancements, or changes to the EHR?; - Who provides user training to clinicians and staff?; - What is the process for making content or workflow changes?; - Who decides what CDS is appropriate?; - Who handles requests for new reports or queries?; - Who should I call with EHR questions related to the project?; 2. Become familiar with major menu options and identify screens that capture or display data elements needed for the project. Remember that individual users may have different configurations based on their role and security level. If you plan to retrieve, extract, or abstract data it helps to know the following for each EHR:; - How to search for a patient; - How to access problems, medications, vital signs, test results, and chart notes, etc.; - How progress notes are organized; - How external reports, summaries, and external records are accessed; - EHR-specific terms that are used as shorthand (“dot-phrase,” “macro,” “flowsheet”).; 3. A Health IT Advisor who has a long-term and valued relationship with a clinic may be given access to internal and external EHR resources like a vendor’s support portal. Remember that vendor documentation (including screen shots) is usually proprietary and use by third parties may be explicitly prohibited. Resources may include the following:; - Access to training and support documents and videos; - Help files or on-line reference material access through the EHR application; - “Cheat sheets” developed by or for the clinic with tips and shortcuts; - Access to a training system, or “sandbox” EHR that does not contain patient data.

[image] | TIPS FOR WORKING WITH EHR SUPPORT DESKS:; 1. Only contact the clinic’s help desk with permission from the project lead for the clinic. In addition to having permission, a best practice as a Health IT Advisor is to contact the EHR Support Desk with a clinic staff member or project lead present in order to ensure awareness and clear understanding. This also may avoid future confusion if a charge is incurred to the practice related to support-desk outreach.; 2. When creating service requests (sometimes called “logging a ticket”) online or by phone, be sure clearly identify the question or issue and include the following information:; - Any troubleshooting steps you have tried; - The correct support team or resource to handle the request; - Examples or screen shots (be careful when including PHI); - An appropriate priority (do not abuse high priority tickets), and; - Direct-contact information and available times.; 3. Track and follow up on open service requests.; 4. Be sure to “close” the ticket when a problem or question is resolved.

[image] | TIPS FOR REQUESTING REPORTS, DATA EXTRACTS, AND CUSTOM QUERIES:; When requesting special access or asking for a custom report or data extract it is important to be prepared. Collect the following before you work with an analyst:; - Confirm that the requested data exists in the EHR; - Specify the data elements needed for the project; - Specify the parameters for selecting patient records; - Specify the reporting parameters including date range and any special filters; - Provide an estimate of the number of records you expect to extract; - Be clear about how the report should be formatted and delivered; Exhibit 27 shows an example of an IT request asking for A1c data on a sub-population of patients with diabetes.; For good reason, clinics carefully control who has access to their EHR. Gaining direct access to advanced report tools or “backend” connections to the EHR database will need to be explicitly approved by the clinic’s management and all privacy and security regulations must be followed; this includes, but is not limited, to HIPAA.

[image] | EXAMPLE:; For a project collecting blood pressure values, the clinic’s IT analyst agrees to pull an extract file containing the information you need. In the data request, however, you did not consider that some visits will have multiple blood pressure readings in different positions (standing, sitting), or as a repeat measurement for “white coat syndrome” (nervous patients have higher blood pressures). As we have discussed before in the handbook, the time to evaluate what data will be needed and how they will be collected for a project should happen early during the planning stage (see Section 1). This situation might require a targeted workflow analysis to clarify specific data needs and potential issues with the data.

Exhibit 27 Example of an IT Request for Data Extract[49]

#### Diabetic Patient Identification IT Instructions

##### Patient list generator

Step 1: Identify all patients that meet all of the following criteria:

- Diabetic: Select patients with any ICD9 = 250.xxx [underlined: in the billing data].
- Among those, select patients with birth dates after 1/1/1927 and prior to 1/1/1962 [Age > 50 years and <85 on 1/1/12]

⮞ Record number of patients seen at least twice in the 2-year period (3/30/2010-3/31/2012)____

- Generate list seen at least once in both 12-month periods (3/30/2010-3/30/2011 AND 3/31/2011-3/31/2012).

⮞ Record number of diabetics identified____

- Of diabetic patients selected, select those with three hemoglobin A1c values dated from 3/31/2011 to 3/31/2012:
  ○ Record number of patients identified____

Step 2: Identify all patients that meet all of the following criteria:

- Hypertensive: Select patients with any ICD9 = 401 or 402 or 403 or 404.
- Among those, select patients with birth dates after 1/1/1927 and prior to 1/1/1962 [Age > 50 years and <85 on 1/1/12]

⮞ Record number of patients seen at least twice in the 2-year period (3/30/2010-3/31/2012)____

- Generate list seen at least once in both 12-month periods (3/30/2010-3/30/2011 AND 3/31/2011-3/31/2012).

⮞ Record number of hypertensives identified____

Of diabetic patients identified in Step 1 (excluding criteria for hemoglobin A1c values, including those seen twice in both 12-month periods and only those within the range of birth dates listed), how many have any ICD9 = 401 or 402 or 403 or 404?

## 2.8 Tips for Documenting and Sharing EHR Best Practices

Health IT Advisors have a unique opportunity to discover and share how individual clinics design identify, prioritize, and implement QI using their EHR or other health IT. Here are some tips for documenting and sharing EHR best practices:

1. Recognize that specific vendor capabilities, local EHR configuration, workflow, and user preferences can make it difficult to generalize about EHR workflows and best practices.
2. When documenting innovative workflows, try to use vendor-neutral terminology. For example, “dot phrase” and “smart form” are both fairly specific to a particular EHR (Epic and eClinicalWorks, respectively); consider “templated structured data” as a more general term.
3. Get the clinic’s permission to share examples and stories that may identify them or an individual. For example, sharing forms with a clinic logo or screen shots that contain identifying information about a clinic or provider.
4. Only share vendor materials, including screen shots, with permission. Screen design is protected by intellectual property rights; and vendors may be strict about how product images are used even for academic, research, and QI purposes.
5. Make sure that examples, screen shots, forms, and images are clear of any PHI. When obscuring PHI in a slide presentation, be sure to completely replace the image so that it cannot be re-edited. For paper, a black marker is often used to obscure PHI.
6. Flowcharts, swim-lane, and workflow diagrams are an excellent way of representing before-and-after process changes or comparing work practices in different clinics.
7. Consider presenting the results of your project to local, regional, or national EHR user groups and industry associations (The Healthcare Information and Management Systems Society (https://www.himss.org/) [HIMSS], The American Medical Informatics Association (https://amia.org/) [AMIA], The American Health Information Management Association (https://ahima.org/) [AHIMA]). For user groups, vendor-specific material and terminology are often appropriate (and appreciated by fellow users).