# Introduction

Over the past two decades primary care practices have been encouraged to implement new, evidence-based approaches and advanced models of care to close the quality “chasm” in healthcare.[1] Increasingly, value-based payment programs also tie practice reimbursement to the implementation of processes that are designed to improve quality. [2–4]

External support, particularly practice facilitation, has emerged as a successful method to help practices implement new approaches to improving quality of care [5–10] and advanced primary care models.[11–22] Practice facilitators – also called practice coaches – draw on their skills in engaging and motivating change and improving work processes to help practices improve the quality of care they provide. [23] Agency for Healthcare Research and Quality (AHRQ)-funded EvidenceNOW initiatives (https://www.ahrq.gov/evidencenow/index.html) have provided evidence of the effectiveness of practice facilitation as well as an increased understanding of the importance of high-quality data for the practice improvement process.

However, practice facilitation is implemented by a variety of different types of organizations, and practice facilitators vary in their background and skills in clinical health information technology (IT). This has led some practice transformation and quality improvement (QI) organizations to develop the role of a health IT-focused coach (or a “Health IT Advisor”) as a complementary resource to support practices in their QI and practice transformation efforts.[8, 24] Health IT Advisors are essentially practice coaches who focus on healthcare information technology. For example, they may help a practice look at their EHR reports and data to determine their baseline results around the quality of care they are providing. Or, Health IT Advisors may help practices with data validation around specific quality measures. [25] While some health systems and practices have internal staff that can serve in this role, there is value to having an external health IT coach share the best practices they have learned from working across many practices, with different electronic health records (EHRs) and other health IT platforms, and from addressing a wide variety of issues.

AHRQ has developed extensive resources to support primary care practice facilitation (https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation.html), including a Primary Care Practice Facilitation Curriculum (https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation/curriculum/index.html) and related Practice Facilitation Training Modules (https://www.ahrq.gov/ncepcr/tools/transform-qi/deliver-facilitation/modules/index.html) (and the precursor to these materials, the Practice Facilitation Handbook (https://archive.ahrq.gov/ncepcr/tools/pf-handbook/practicefacilitationhandbook.pdf)). These resources include information regarding the use of data for QI; however, they contain only limited information about the use of EHRs and other health IT as sources of data for practice improvement and transformation. The current handbook was developed to provide the more in-depth information Health IT Advisors need to effectively support the IT needs of primary care practices as they increasingly engage in QI and practice transformation efforts.

## About This Handbook

The authors designed Obtaining and Using Data in Practice Improvement: A Handbook for Health IT Advisors and Practice Facilitators to be a resource for the coaches who provide health IT-related assistance for primary care practices to support their QI and practice transformation efforts. The audience for this handbook includes both the health IT-focused coaches who support QI work (who we refer to as “Health IT Advisors”) as well as the practice facilitators/coaches who have the necessary background, interest, and skills to provide clinical health IT support. Although the handbook is primarily intended for external coaches working with primary care practices, we believe the content could also be useful for practice-based staff responsible for addressing health IT needs related to QI.

The handbook assumes readers already have a basic level of comfort with EHR use and with extracting and using electronic data for QI. While the handbook does not cover advanced health IT topics, it does include links to supplementary information in these areas where appropriate. Finally, the handbook does not include practice facilitation information already covered in other resources (described above).

The handbook is organized into nine sections and four appendices:

- Section 1: Strategies for Health IT Advisors. This section is a review of general strategies for Health IT Advisors working with practices to promote QI using EHRs and other health IT and includes information about assessing QI practice capacity; different health IT systems that coaches will see in the field; obtaining practice buy-in and engaging leadership; collaborating with practice QI staff; establishing shared QI goals; monitoring adoption and providing feedback; incentivizing QI; establishing data protocols; and understanding policy and legal issues as well as patient attribution and empanelment.
- Section 2: Working with Electronic Health Records. This section is a review of foundational concepts for Health IT Advisors working with practice electronic EHRs, including data structures; how workflows impact data; how to assess data quality; best practices for handling EHR data; privacy and security considerations; tips for extracting data and obtaining EHR support; and suggestions for documenting and sharing best practices.
- Section 3: Clinical Decision Support. This section provides a review of clinical decision support (CDS) and includes a discussion of CDS applications for QI. Types of CDS commonly found in EHRs and best practices for using CDS in QI work are also discussed.
- Section 4: Patient Portals and Engagement Technologies. This section provides a review of patient portals and related patient-engagement tools and their applications for QI, including a discussion of common features of patient portals and how they may be used in practice improvement efforts.
- Section 5: Incorporating Patient-Generated Data for Quality Improvement. This section provides an introduction to patient-generated data and applications for QI, including a discussion of the advantages of patient-reported outcomes and patient-generated data; data examples and sources; technical, privacy, and security concerns; patient-reported symptoms and health-related quality of life; electronic health screenings for preventive care; and da ta collection and use challenges.
- Section 6: EHR Use Cases for Quality Improvement. This section serves as a practical guide to using EHR data as a platform for delivering QI interventions, including a diabetes case study and use cases for using EHR data for quality measurement and improving preventive care.
- Section 7: Beyond the EHR: Alternative Data Sources for Quality Improvement Data. This section provides a look at how to use claims data and how health IT platforms beyond the EHR (including registries, population health platforms, and health information exchanges [HIEs]) can be used for QI.
- Section 8: Review of Clinical Quality Measures. This section provides a comprehensive review of how clinical quality measures (CQMs) are constructed and used to support QI. This includes reviews types of CQMs; finding CQMs for use in QI; the anatomy of a CQM; CQM specifications; a worked-through example of a CQM; and tips for presenting CQM data.
- Section 9: Review of Risk-Stratification in Primary Care. This section provides an introduction to risk stratification, including the identification of high-risk patients; a discussion of health and social factors that impact health; diseases and risk-stratification; and other risk-stratification data sources, goals, and barriers.
- Appendix A: Review of Interoperability and Data Standards. This supplemental section provides a review of key interoperability concepts and data standards, including components of interoperability, interoperability standards, and information models.
- Appendix B: Health IT Crosswalk for the Ten Building Blocks for Primary Care. This supplemental section applies the Ten Building Blocks Model for Practice Transformation to health IT concepts.
- Appendix C: Example of Data Planning for Quality Improvement. This supplemental section provides additional tips on data planning for a QI project.
- Appendix D: Tips on Designing Reports and Data Visualizations. This supplemental section provides a guide for selecting and designing data presentations and visualizations to communicate findings.