# Section 1 Strategies for Health IT Advisors

This section reviews general strategies for working with practices to improve EHR and other data capabilities and to promote ongoing QI. Some of the topics introduced in this section are covered in greater detail in subsequent sections. As a general approach, we recommend that the strategies described here should be employed with the goal of building a true partnership with each practice, rather than providing expert instruction.

## 1.1 Assessing Practice Capacity, Motivation, and Interest in Quality Improvement

A careful assessment of practice data capacity, both broadly and specific to the needs of a QI project, is a crucial initial step. This includes determining the specific EHR version and other data systems in use, the ability of the practice to generate key measures and data, the ability of the practice to produce usable, clean, and accurate data, and the use of data in QI and other practice management activities. Potential delays or barriers in producing data should be identified and addressed as early as possible in the process. Practices can vary widely in their data culture, and the promotion of a practice culture of data-driven process and improvement—in close collaboration with practice staff—should be a primary mission of the Health IT Advisor.

For practices to use data to guide their quality efforts, the data must be accessible, timely, accurate, and trusted. Health IT Advisors can assess these important aspects of a practice’s health IT capacity through informal conversations or structured assessments. Section 1.2, Health IT Systems and Platforms, discusses core aspects of clinical health IT that advisors can assess across the practices they serve.

## 1.2 Health IT Systems and Platforms

Health IT Advisors may need to work across dozens of practices and health systems where EHRs and other health IT can vary substantially. By keeping an inventory of key health IT by practice, Health IT Advisors can more quickly spot common barriers and spread useful solutions. Listed below are some examples of important systems and functions that Health IT Advisors can consider documenting for their own information or through a standard questionnaire like the example showed in Exhibit 1.

- EHR system name and version
- Population health software and patient registry tools
- Certified Health IT Products List (CHPL) identification number(s) of health IT systems
- Name and functions of Health Information Exchanges used by the practice
- Adequacy of broadband connectivity, and
- Contact information for IT support and troubleshooting.

Exhibit 1 Sample Health IT Inventory

Graphic derived from the Shared Practice Learning and Improvement Tool developed by the Practice Innovation Program at the University of Colorado and included with permission.

Screenshot of a sample inventory as described in text above.

### Access to Key Reports

Health IT Advisors help practices create and optimize their feedback reports, ensure results satisfy the reporting requirements for external programs, and demonstrate the impact of a practice’s internal QI efforts. Key questions to ask include:

- How and when will reports be generated?
- Who has access to the reports?
- Do the numerator and denominator definitions make sense clinically and satisfy the external project specifications?
- How often should reports be updated? Will this time period line up with how fast changes are expected in the project and meet project specifications?
- Does the local QI team trust the results? Do the results line up with the practice’s expectations? Are patients included that should not be? Are there patients missing?
- What would make the report more useful for the practice?

### Workflows for Reliable Data Capture

Every CQM is made up of smaller key data points. Health IT Advisors need to quickly assess the accuracy and reliability of these core data elements because inaccurate or inconsistent data entry can cause patient care issues and lead to validation concerns in quality reports. The example provided in Exhibit 2 is a simple assessment a Health IT Advisor can use to understand if data is being accurately and regularly recorded in discrete sections of the her (a table that can be filled in and printed can be found here (https://www.ahrq.gov/sites/default/files/wysiwyg/evidencenow/tools-and-materials/ehr-data-assessment-worksheet.pdf)). The table can be modified to only include the elements relevant to any given project, and it can be completed with the practice’s improvement teams to highlight workflows in need of attention.

Exhibit 2 EHR Data Assessment Table (https://www.ahrq.gov/sites/default/files/wysiwyg/evidencenow/tools-and-materials/ehr-data-assessment-worksheet.pdf)

EHR Data | | Data captured in discrete fields accurately and consistently on all patients | Data captured in discrete fields with accuracy and/or consistency concerns | Data not captured in discrete fields
Patient Linking Number
Date of Birth
Gender
Ethnicity
Race
Medications
Height
Weight
Body Mass Index (BMI)
BMI percentiles (for children)
BMI follow up plan (for children) – Exercise counseling
BMI follow up plan (for children) – Nutrition
Blood pressure – Diastolic
Blood pressure – Systolic
Substance abuse screening
Substance abuse follow up plan
Anxiety Screening results
Depression screening for patients 12+ years old
Maternal depression screening
Depression follow up plan
Standardized way to assess risk for child developmental, behavioral, and social delays
Immunizations
Colon cancer screening results
Mammogram results
Hemoglobin A1C results
Green | Data captured in discrete fields accurately and consistently on all patients
Yellow | Data captured in discrete fields with accuracy and/or consistency concerns
Red | Data elements not captured in discrete fields

Graphic derived from the Shared Practice Learning and Improvement Tool developed by the Practice Innovation Program at the University of Colorado and included with permission.

## 1.3 Obtaining Organizational Leadership Buy-in

Engaging the leadership of a practice and their organizational stakeholders ensures there is a resourced and focused team capable of aligning a practice-wide vision with concrete goals and objectives that the Health IT Advisor can support. This is a key step in any effort to implement evidence-based practice improvements and advanced primary care frameworks.

Leadership introduces the practice to concepts important in improving primary care, enters into value-based payment agreements, creates budgets, determines funding for health IT, allocates time of team members to projects, and sets the stage for the Health IT Advisor in the practice’s quality improvement efforts. Within a health system, practice, or system, leaders are critical in getting attention and engagement from the organization’s health IT vendors, which can be a major barrier. Leaders exist at all levels in healthcare organizations and primary care practices. Local teams may lack the positional power of system directors and executives but often have the most to gain (or lose) from changes in practice workflows. Understanding how to identify and engage effective formal and informal leaders at all levels of a practice and/or system will help the Health IT Advisor meet improvement objectives. Effective leadership can expedite decision making, provide strategic credibility, and authorize resource allocations.

Dynamic engagement outlasts the one-time pitch. When focusing on implementation, QI data needs, and health IT capabilities, obtaining leadership buy-in should not be a one-time ask. In addition to the recurring funding required for technology licensing, leadership also must regularly invest in team trainings, data extraction, validation, optimization, and reporting to support ongoing data monitoring and quality improvement.

## 1.4 Opportunities for Health IT Advisors to Engage Leaders

A data-driven business case: QI efforts that also improve the financial standing of a practice have a higher likelihood of leadership support and long-term sustainability. Health IT Advisors can help teams compile locally relevant data points to define target populations and capture potential savings or new revenue for a team’s proposed interventions.

[image] | EXAMPLE:; Practice A was hesitant to shift staff time from other duties to address a growing backlog for patients waiting to be scheduled for internal behavioral health and procedure visits. The Health IT Advisor pulled data on the size of the backlog, the average collections for these visits, and their internal versus industry standards for conversion rate of internal referral to a completed visit. With this data, the team found they could generate over $200,000 of additional revenue per year if a dedicated staff member was assigned to schedule an extra100 behavioral health and procedure visits each month from this backlog. Sharing this information with leadership lead to hiring a dedicated staff person for this function.

Displaying key data at leadership meetings: Run charts (line charts of data graphed over time; also called run-sequence plots;) and other data visualizations showing data progression over time can be effective tools for orienting leaders to project goals and developing a sense of urgency for making improvements.

[image] | EXAMPLE:; Practice B participated in a project to increase the prescribing of statins for patients with diabetes. To increase attention to the project and inform conversations about potential interventions, the Health IT Advisor helped update a monthly run chart showing the proportion of diabetic patients prescribed a statin aggregated at the clinic level and at the provider level. The Health IT Advisor reserved agenda time at the practice’s leadership meeting each month to review the data. The team was able to show leadership success in increasing statin prescriptions for this patient population.

Highlighting success: Busy leaders rarely carve out time to celebrate successes in QI projects. Teams do better when they see they are making progress. Rather than waiting until a practice meets their larger goals, Health IT Advisors can support leaders by pointing out positive trends and important data milestones to bolster the sense of accomplishment for the team

[image] | EXAMPLE:; As a part of a broader project to integrate behavioral health into primary care, Practice C’s leadership team set a goal to screen over 90% of their new mothers for postpartum depression. They spent the first3 months of the project creating a new documentation module within their EHR to capture this data within the newborn’s chart. The Health IT Advisor made a point to congratulate the full clinic team after the first time a screening was properly documented using their new EHR workflow and included leadership in celebrating this achievement.

## 1.5 Collaborating with Practice Quality Improvement Staff

To be successful in QI and practice transformation efforts, you need buy-in from other staff beyond leaders and health-IT-focused employees. This requires a team effort. Health IT Advisors can collaborate with practice staff members and assist in developing a practice support plan that connects the practice’s vision for advanced patient care with how they will benefit from multiple projects over time. If a practice has a well-developed QI process already in place, engagement of that team and its leaders will make any efforts easier and more streamlined. If the practice does not have an existing quality improvement team or effort, identification and engagement of potential clinician and staff leaders interested in change and QI will be an important initial part of the effort for the Health IT Advisor.

Once the appropriate practice members have been identified and engaged, work proceeds according to basic QI and change management processes. Throughout, ongoing collaboration with a variety of practice clinicians and staff members will be needed, either through regular team meetings, interactions with individuals, or, generally, both. As an example, to track patents screened positive for unhealthy alcohol use, the Health IT Advisor will need to:

- Learn the clinic’s current workflow/process for incorporating a screening tool (this may be in place of other validated tools, or may not yet exist)
- Work with clinicians and staff to select a screening tool
- Coordinate with clinical and operational staff to ensure they are using the screening tool and documenting data in the proper location within the EHR so that it can be counted
- Assist staff members in developing a process to build and run reports regarding the number of patients screened, and
- Share the reports with clinicians and staff at QI meetings for refinement of ongoing efforts to improve screening.

## 1.6 Collaboration to Determine Health IT Needs and Establish Quality Improvement Goals

Practices may be working with multiple Health IT Advisors, and practice facilitators representing practice transformation efforts, research projects, health system initiatives, health plan payment programs, and other programs or projects. Communication and understanding across various Health IT Advisors and others working with the practice are crucial in coordinating and aligning practice efforts and decreasing the potential for confusion. A shared practice support plan can serve as one way to frame multiple projects in the service of a practice’s long-term QI goals. Practices have motivations for working on quality that will outlast any individual project and may involve support from multiple Health IT Advisors and other aligned resources. Understanding and managing the complex and dynamic interplay among individuals, projects, and organizations can often be a source of frustration for Health IT Advisors as well as practice members. Health IT Advisors can use a shared practice support plan to help everyone make sense of QI efforts.

A shared practice support plan starts with a practice’s overall mission and vision statement and an outline of their QI resources (Exhibit 3). The shared practice support plan allows QI leaders and Health IT Advisors to explicitly document why a practice decides to participate in QI initiatives, how they see the projects advancing the practice’s overall vision, and how the requirements will fit within their current QI infrastructure. For more involved projects, support plans can document project requirements, data expectations, and a coordinated intervention plan that describes ways in which the Health IT Advisor and other support team members will approach working in the practice. Over time, a practice can use this plan to strategically decide on new projects in which to engage and reflect on past experiences to take better advantage of potential project resources.

Exhibit 3 Shared Practice Support Plan

Graphic derived from the Shared Practice Learning and Improvement Tool developed by the Practice Innovation Program at the University of Colorado and included with permission.

Screenshot of the sample plan described in text above.

## 1.7 Developing Shared Goals and Action Plans

Relating closely to the development of a practice support or implementation plan regarding the core content of a particular project, the Health IT Advisor should assist in developing a data quality improvement plan to guide the recording, extraction, cleaning, and reporting of key data related to the project. A simple template for documenting these plans is shown in Exhibit 4, and a template that can be filled in and printed can be found online here (https://www.ahrq.gov/sites/default/files/wysiwyg/evidencenow/tools-and-materials/dqip-goal-setting.pdf). A data quality improvement plan can be developed and monitored:

- With the practice’s QI team during regular meetings that include key data personnel from the practice and the Health IT Advisor
- In special meetings with data personnel and other key people from the practice, led by the Health IT Advisor
  ○ This especially tends to be the case in system practices, where key data personnel may be centralized and not available for regular meetings in the practice. In this case, communications with the Health IT Advisor and the practice QI team are critical to maintaining alignment of plans and expectations.

Key elements of a data quality improvement plan consist of goals that are SMART (SMART Goal Setting (https://www.cms.gov/Medicare/Provider-Enrollment-and-Certification/QAPI/Downloads/QAPIGoalSetting.pdf)): Specific, Measurable, Achievable, Realistic, and Timely. Useful areas of focus for an initial data quality improvement plan include:

- Accurate and consistent capture of core data elements in discrete fields
- Validation of reports and registries, and
- Communicating metrics of success to leadership and care team members.

Data quality improvement plans often contain longer-term ambitions. It is important to help break these plans into smaller, more actionable SMART goals that can be achieved in 1-3 months. SMART goals are good touch points to bring up and adjust periodically to keep teams on track with both short-term progress and long-term aims.

Exhibit 4 Data Quality Improvement Plan Goal Setting Form (https://www.ahrq.gov/sites/default/files/wysiwyg/evidencenow/tools-and-materials/dqip-goal-setting.pdf)

Graphic adapted with permission from the Practice Innovation Program at the University of Colorado.

A simple template for documenting a data quality improvement plan including guidance about developing the plan. Guidance includes to instituting an improvement team with regular check-ins; including those who are involved in creating and using the data on the team; indentifying goals for data quality improvement related to identified uses and issues, and establishing measures of success. The template asks users to insert three goals for improving data quality in their practice, and suggests 1) making the goals SMART (specific, measureable, attainable, realistic, and timely); 2) considering how to consistently pull reports and validate informaiton relevant to each clinical quality measure (CQM); and 3) including a measure of success with each goal.

Once initial data sources are identified and initial reports developed, a practice can be guided—collaboratively—through steps to assure data accuracy. It is likely that initial reports will contain errors due to erroneous patient attribution, inconsistent data entry into key E HR fields, and a variety of other issues. Careful data cleaning is generally required. Chart audits to verify the accuracy of the data and to determine why it might not be accurate are often very helpful. This entire process takes a great deal of time and varies according to multiple factors, including the type of data being tracked, the EHR or other data source being used, health IT resources within a practice and/or system, and many other variables. [8, 24, 26] In addition, practices often must go through stages of a kind of grief – often including denial and anger – before accepting that the data is a true reflection of the care being provided.

## 1.8 Monitoring Practice Adoption and Providing Ongoing Feedback

Once clean and trustworthy data are obtained, regular data reports can be used to monitor implementation and improvement over time. These reports provide a picture of where the practice is starting and can be reviewed regularly at QI team meetings. Developing a culture of ongoing use of data to inform decision making is a key objective for this type of QI and practice transformation work.

When sharing feedback, keep the following tips in mind:

- Practices like comparing themselves to others. People are competitive, and these comparisons can provide a great deal of motivation for change and improvement. Run charts, like the one in Exhibit 5, show performance on CQMs over time. They are a classic example of tools that Health IT Advisors can deliver to practices for ongoing feedback. Adding reference ranges from other practices in a project and national benchmarks if they exist can add context for the practice team as it reflects on its progress.
  Not all measures will have outside reference ranges or benchmarks. In these situations, consider using a control limit chart. Control charts can show how processes change over time and can quickly identify when results change more than expected with random variation in data points. Alternatively, breaking down and comparing data between individual providers can be as motivating as external comparison data.

Exhibit 5 Sample Quarterly Clinical Quality Measure Run Chart with Project and National Benchmarks

Graphic derived from the Shared Practice Learning and Improvement Tool developed by the Practice Innovation Program at the University of Colorado and is included with permission.

Sample chart as described in text above.

- The 3% rule of thumb. The 3% rule of thumb assumes that a successful QI project will produce a sustained 3% absolute improvement in a clinical outcome metric over the course of a 12-month intervention. This principle, developed by quality improvement programs based on experience – and used by the Practice Innovation Program at the University of Colorado – is a quick and easy way to put a practice’s QI achievements into perspective. Of course, a Health IT Advisor will need to consider where a practice started (high starting performance may limit how much improvement is possible) and how much control a practice has over the metric (it is easier to change process measures than patient outcomes). Also, process-related measures can sometimes improve more rapidly through improved capture of key data elements. Regardless, the 3% rule is a convenient reference for many QI projects.
- Stories resonate with staff and providers. Tables and graphs filled with numbers can motivate analytical team members, but many others find feedback less sterile and more memorable when it is tied to real patient and care team experiences. Health IT Advisors can work with QI teams to share success stories that build momentum or bring up examples of a poor outcome that can develop a sense of urgency for change.
  For example, a Health IT Advisor could use this run chart (Exhibit 6) showing the number of patients screened for unhealthy alcohol use to ask the QI team, “Your data shows a great increase in screening for unhealthy alcohol use; can you think of any of these patients who screened positive that you then went on to connect with resources to help stop drinking?”

Exhibit 6 Sample of a Simple Run Chart

Sample chart as described in text above.

- Feedback can be used to rein force good data practices. Health IT Advisors can draw attention to how the practice advanced their QI agenda by using foundational data skills like validating a report, creating a new patient registry, or training staff on new documentation workflows. This feedback can be brought up at regular QI meetings, by annotating run charts, or when debriefing at the end of a project. Sharing feedback with a larger clinical team as well, beyond QI groups, will promote greater buy-in for future projects.

## 1.9 Incentivizing Quality Improvement

The Health IT Advisor is positioned to translate programmatic benefits and incentives related to quality data systems to practice teams and individuals. Both intrinsic (personal development, belonging, recognition, altruism) and extrinsic (rewards, penalties, compliance) motivators matter when promoting data-driven continuous QI.

What can a Health IT Advisor do to incentivize QI in a practice?

- Contribute your understanding of programmatic incentives. Practices look to their Health IT Advisor to answer questions about program requirements. Good Health IT Advisors demonstrate how the practice’s health IT strategies and tactics are directly related to achieving success in payment, QI, and other programs. Alignment of practice motivations and incentives across programs can help the practice make sense of the multiple requirements that are bombarding them and greatly assist in developing coherent action plans moving forward.
- Build on intrinsic motivators of team members. This includes autonomy, mastery, belonging, and competition. Foster curiosity in the data. For instance, try asking “Which patients of yours could we help if we focused on this measure?”.
- Engage the patient voice. Most people in healthcare choose to work in this field to help people and their community live happier, healthier lives. If a practice has a patient and family advisory council, engage them in understanding and supporting the use of data in improving care in the practice.
- Provide feedback. Share data in a manner that allows the practice to advance multiple aspects of their existing QI work.
- Celebrate wins. Rarely do leaders take time to reflect on and celebrate success. It is easy to gloss over seemingly small health IT wins such as a valid CQM report. Assist the practice in developing a culture where wins are regularly celebrated and rewarded.

## 1.10 Establishing Clinical Protocols for EHR Data

Beyond CQM extraction, cleaning, use, and reporting, practices need clean data and efficient workflows for other uses of their data. This is especially true for practices participating in advanced payment models that incentivize population management, care management, longitudinal tracking of preventive care, and avoidance of unnecessary expenditures. Health IT Advisors can help care teams increase reliability of processes and decrease duplicated effort by ensuring data is thoughtfully embedded within a practice’s operating protocols. There still are major deficiencies in clinical health IT systems, but Health IT Advisor scan help practices continue to chip away to achieve useful and desirable data resources.

Health IT Advisors have a role in:

- Promoting reliable and discrete data entry. While EHRs are rapidly trying to improve their interfaces, many documentation procedures remain so clunky that busy clinical teams often find it easier to simply type their findings in free text fields. But for a data point to flow seamlessly among multiple reports and over time, it needs to be in a discrete, searchable field. With practices new to discrete data entry, consider data that have cross-cutting implications but remain in a practice’s control like accurate documentation of repeat blood pressure readings, entry of behavioral health screening results, and recording patient demographics like gender, race, ethnicity, and language preference in a sensitive and affirming manner.
- Codifying best practices. Once a team decides on a reliable workflow that involves data entry, Health IT Advisors can help them embed that workflow into policies and training documents. While these documents take an upfront lift to produce, they can make it easier to on board new members and refresh memories when people fall back into old habits when new priorities inevitably arise. Policies and procedures are important tools to sustain improvements in quality and efficiency.

[image] | TIP:; Health IT Advisors can drastically cut down the time it takes to produce policy and training documents by sharing examples from other practices with which they work. Just remember to ask for permission from the example practice first. Ensure that policies and training documents are reviewed and updated on a regular basis, in accordance with an established schedule.

- Advancing interoperability. The ecosystem of interoperable health data systems continues to expand. Health information exchanges (HIEs) vary by region, state, EHR platform, and even data type. Health IT Advisors can link practices with organizations and services that provide clean and useful data affordably. While data and reports for some of these purposes are slowly being included in new versions of EHRs, Health IT Advisors can often help practices in navigating this important space through recommending and assisting in the implementation of third-party solutions, such as various types of registries, HIEs, behavioral symptom screening assessments, self-management support platforms, and many others.

[image] | TIP:; HIEs are often able to generate reports with lists of a practice’s patients admitted, discharged, or transferred (ADT) reports from local hospitals. Managing transitions of care using these ADT reports can be a sustainably reimbursable activity through Medicare and other payers and a key lever for controlling costs in value-based payment programs. The Centers for Medicare & Medicaid Services (CMS) now has a Conditions of Participation (CoP) requirement regarding receiving ADT alerts from hospitals.

## 1.11 Understanding Policy Issues

Federal and state laws have had a dramatic impact on health IT adoption through policies, regulations, and incentive programs. The health IT Timeline in Exhibit 7 shows how key legislative efforts reach back decades and have progressively increased pressure on practices to use data systems to improve health outcomes.

Exhibit 7 Health IT Timeline

Graphic adapted and included with permission from Abel Kho MD, MS, Northwestern University.

The health IT Timeline in Exhibit 7 shows how key legislative efforts move over time from a focus on privacy to more and better data, and then to more portable (and private) data. The timeline starts with HIPAA in 1996, which defines protected health information (PHI), The Office of the National Coordinator for Health Information Technology's (ONC's) establishment in 2004 to address low electronic health record (EHR) adoption rates; The American Recovery and Reinvestment Act (ARRA)in 2009, which included the Health Information Technology for Economic and Clinical Health Act (HITECH) and meaningful use and Regional Extension Centers; Widespread adoption of EHRs in 2014; The Medicare Access and Children's Health Insurance Program Reauthorization Act (MACRA) in 2015, which included a switch to value based payment; The 21st Century Cures Act in 2016, which included information blocking, Application Programming Interfaces (APIs), and the cancer moonshot; The Trusted Exchange Framework and Common Agreement in 2019, which promotes interoperability and reducing documentation burden and General Data Protection Regulation in the EU and the California Consumer Privacy Act in the US; and present day with new Centers for Medicare and Medicaid Services (CMS) and ONC interoperability rules.

Practices often struggle to stay up to date on the shifting (and sometimes conflicting) rules that impact their teams and patients. With a firm understanding of key laws and regulations, Health IT Advisors can help identify when new laws will bring added resources aligned with the practice’s QI goals and point out areas needing attention to stay in compliance with new rules. Important information about health IT laws and regulations can be found on the Office of the National Coordinator for Health Information Technology’s website ONC | Office of the National Coordinator for Health Information Technology (healthit.gov) (https://www.healthit.gov/). Exhibit 8 outlines a few key laws and regulations that impact health IT and the work of Health IT Advisors in practices.

Exhibit 8 Key Health IT Laws and Regulations

Important Health IT Laws and Regulations | Summary | Impact On Health IT Advisors Work
HITECH Act (2009) | Passed in January 2009, as a part of the larger American Recovery and Reinvestment Act, this specified general guidelines for the development and implementation of a “nationwide health information technology infrastructure.”[27] Spurred federal government investment to promote the widespread adoption of EHRs that were intended to improve the quality, safety, efficiency, coordination, and equity of healthcare in the US.; Created Meaningful Use, which drove EHR adoption by hospitals and office-based care providers. Also advanced standards in CQMs. | Help practices choose or develop EHRs that will meet federal requirements. Focus on reporting on CQMs.
Medicare Access and CHIP Reauthorization Act (MACRA; 2015) | Adjusted how physicians were paid for their services. Sped the adoption of value-based payment programs that achieve the Triple Aim. Consolidated several QI reporting programs. Authorized the Quality Payment Program, creating the Merit-based Incentive Program and Advanced Alternative Payment Models Tracks 1 and 2. | Continues down path of CQM reporting. Focuses more on electronic CQM (eCQM) reporting through EHR or third-party registry. Moves away from self-reporting metrics from EHR.
Health Insurance Portability and Accountability Act (HIPAA; 1996) | Defined protected information with focus on privacy and security of patient health information. Determines rules around permissible electronic health data exchange. | Focus on Security Risk Analysis. This was started under HIPAA and re-emphasized under the HITECH Act.
Certified Electronic Health Record Technology (CEHRT; 2010) | Rules established within Meaningful Use by the Office of the National Coordinator for Health IT (ONC) defining certified electronic health record technology (CEHRT). This helped standardize many of the requirements that EHR vendors had to follow in designing new EHR systems. | With certified technology, practices have a base-level capability for CQM reporting.
21^st^ Century Cures Act (2016; 2020) | Among other goals, aims to reduce regulatory burdens of using EHR systems and other health IT. Provisions are focused on making progress toward interoperability and ensuring that IT developers do not engage in “information blocking,” which is the prevention of or creation of barriers to accessing, sharing, and/or using electronic health data. As part of the “next phase” of the Cures Act, CMS and ONC finalized rules about this in March 2020. | Vendors are increasingly opening their EHR systems to application programming interfaces (APIs) using a platform-agnostic interoperability standard called FHIR®, which has been developed by Health Level Seven International (HL7®).

## 1.12 Understanding Legal Issues

Health IT Advisors will encounter a variety of scenarios that are covered by legal protections of various types. The development of several types of agreements between the Health IT Advisor’s organization and a practice and/or its health system will define the relationship between the various organizations, outline the use of data as part of this relationship, and protect the practice, its patients, and the Health IT Advisor. While Health IT Advisors will not generally be responsible for developing agreements between organizations, they need to be aware of key regulations and whether appropriate agreements are in place early in the process of working with a practice.

These agreements and regulations include:

- Business Associate Agreements. A business associate agreement, or BAA, is a written document that details how to protect health information when it is shared between two organizations or individuals. It is often required when a Health IT Advisor works for a separate organization from the practice and will need to view protected health information (PHI). For a Health IT Advisor this can include looking at patient information in a practice’s EHR for a QI or research project. As outlined by the U.S. Department of Health and Human Services (DHHS), “if a covered entity engages a business associate to help it carry out its healthcare activities and functions, the covered entity must have a written business associate contract or other arrangement with the business associate that establishes specifically what the business associate has been engaged to do and requires the business associate to comply with the Rules’ requirements to protect the privacy and security of protected health information.”[28] Health IT Advisors should verify if a BAA is needed or in place prior to the beginning of a project. An example of a business associate agreement can be found here: Model Business Associate Agreement (hhs.gov) (https://www.hhs.gov/sites/default/files/model-business-associate-agreement.pdf).
- Data Use Agreements. When Health IT Advisors work on projects with practices from different organizations around specific clinical data or quality measures, a data use agreement (DUA) might be needed. “A data use agreement establishes who is permitted to use and receive the Limited Data Set, and the permitted uses and disclosures of such information by the recipient.”[29] The DUA specifies what data will be shared and how that data will be used by partnering organizations. It will also specifically list how the data will be destroyed or returned at the end of a given time period. The Health IT Advisor should be aware of any DUAs prior to starting a project.
- Institutional Review Board. Institutional review boards (IRBs) help ensure that human subjects research is conducted in an ethical manner and in compliance with federal and organizational guidelines. Health IT Advisors often work on research projects and therefore need to be aware of how IRB rules impact data covered under research protocols. This data may include clinical data from an EHR, survey data, and interviews that Health IT Advisors participate in for a project. When working on an IRB-approved research study, Health IT Advisors should be aware of the specific descriptions of data gathering and use included in the research protocol and the IRB approval documents. IRBs’ role in the protection of human subjects in research is guided by DHHS’ “Common Rule (https://www.hhs.gov/ohrp/regulations-and-policy/regulations/common-rule/index.html).” QI research projects that involve human subjects will require IRB review, but not all QI projects require IRB review and approval.

## 1.13 Understanding Patient Attribution and Empanelment

Empanelment and attribution are related concepts differentiated by the source of the allocation of patients, among other factors; some of these are shown in Exhibit 9.

Exhibit 9 Empanelment Versus Attribution

Features of Empanelment | Features of Attribution
- Process a practice uses to identify their “active patients” and to assign those patients to a single provider or care team panel; - Foundation for establishing continuity between patient and provider/care teams; - Managing panel size is an important step in balancing access to and demand for services; - Requires ongoing monitoring as patients change primary care providers, move, or die, and as providers leave practices; - Helps define the inclusion criteria of many QI metrics; - Used to credit quality outcomes to individual providers and care teams and for programs like CMS Medicare Merit-based Improvement Payment System (MIPS) | - Process insurance companies and other purchasers of group healthcare use to assign patients to a particular provider, practice, or health system; determines payment; - Contractual agreement where assigned providers can receive incentives to provide a certain set of services or achieve certain aggregate outcomes; - Understanding attribution is a core element of value-based payment programs in which many practices are participating; - Changes as people gain and lose insurance, methodologies adjust, and health plan options evolve

Traditionally, the definition of “active patients” includes patients who have sought care at the practice within the last 24 to 36 months, allowing inclusion of some patients who have minimal preventive or chronic healthcare needs. In practices who also have attributed patients, empanelment should also include those patients assigned to the practice by a health plan, even if those patients have never sought care with them.

Health IT Advisors can take certain steps to help practices with traditional empanelment as well as attribution, including:

- Help the team determine an empanelment methodology and workflow and document agreed-upon procedures with key clinicians and staff
- Ensure all active patients are assigned to a provider panel
- Monitor concordance between internal empaneled patients and payer attribution reports
- Help practices follow payer methodologies to reconcile any discrepancies, and
- Explain when CQMs include attributed patients in specifications to avoid confusion among care teams.