# Appendix D Tips on Designing Reports and Data Visualizations

The first step in designing a report is to identify the task of the report. Who will be using the report? Will it be for internal clinicians, organization leadership, ACO, payer, regulatory, or something else?

A report should tell a story and it is important to think about the components that make up that story and maybe more importantly, the components that do not. Be careful mixing stories because this can lead to a busy and confusing report (see more below). What does the report need to convey? Think about the data that are needed to support this story. What systems do the data currently live in and what access is required, or is this new data collection? What frequency will the report need to be updated? Below we will cover some thoughts around automated and a method for semi-automation that does not require programming or systems administration.

Before embarking on creating a new report, first check to see if the report already exists (see Section 3). Is this report covered by a standard report (e.g., MIPS) that may be already built into your EHR? Check with the EHR vendor or handbook or website to see if a related report already exists. In some cases, the reporting role may require a separate license. With practice staff, ask your vendor if there is any training available for the reporting module. In most cases, the use of a standardized report is preferable to maintain consistency, ease of use, and reduce the practice resources needed. If you are in a health system, it may be a good idea to reach out to your data analytics team. They may know of something outside of the EHR.

If the report will be used in the clinic, think about the intended purpose. Will this be used to support day-to-day operations? For example, one idea is to create “buckets” that show how many patients are waiting in each room and for how long. Another is to track occurrences of incomplete, partial, or complete processes for review and improvement. Another idea is to use quality measures at the individual provider level and create a dashboard for teams of providers to see how they compare to their peers in terms of controlling for disease in their patient population.

Finally, a dashboard showing a running average of costs for procedures or processes can be helpful for a clinic to meet financial goals. Costs side-by-side with related quality measures could be a very powerful visualization.

Many EHRs provide an integrated reporting module that allows the user to build a report (there may be additional costs). The simplest of these reports is to run a list of patients that have a certain characteristic, for example, a hypertension diagnosis. The user interface and commands used to create a custom list will vary by EHR, but most support Boolean logic like that shown in the example below:

- Select (All patients)
- AND (Between 18 and 85 years old)
- AND (Seen within 365 days)
- AND (for an office visit) OR (for a tele visit))
- AND (having a diagnosis of ICD-10 I.10, Essential Hypertension)
- NOT (pregnant).

When getting started developing a data visualization, many people want to start by designing a data structure before they know what they want to present. While digging into and knowing the data is good from the standpoint of identifying what is possible, it is difficult to know exactly what structure is needed until there is a plan for the presentation and an intended purpose for the presentation. In this section we will discuss choosing a data visualization software solution, identifying the right data visualization for an intended purpose, as well as how to prep and structure data to feed the visualization.

## Choosing a Software Tool

For simplification, all the examples in this section use Tableau Desktop, which is a popular software solution. However, it is important to note that there are many other software solutions available such as SAS Visual Analytics, Microsoft Power BI, Qlik, Microsoft Excel, and many more. There are also free tools such as Google Charts and Tableau Public. There are also several open-source programming frameworks that are powerful such as D3.js and Chart.js. The intention of this section is not to promote any one solution, however, there are some important considerations to take into account as a Health IT Advisor.

### Ease of Use

If you do not currently have experience working with a particular tool, it is important to assess how much effort you are willing to put into learning a one. Are you a programmer or plan to become one? Using programming frameworks such as D3.js provide the [underlined: most] flexibility and capability but come at the steepest learning curve. Prior knowledge of JavaScript, at a minimum, is required. Non-programming tools such as Tableau and Microsoft Power BI, try to assist the user throughout the entire workflow starting with data ingest, such as connectors to some of the most popular data sources (excel, CSV files, database servers, SAS datasets, etc.), to identifying data types such as text/strings, numeric, dates, true/false, IDs, geographic variables, etc., to suggesting visualizations based on selected data (bar charts, line graphs, etc.), to publishing (export to a portable document format (PDF), embed in a website, upload to a tool-specific cloud hosting provider). Simplification usually comes at the cost of capability and flexibility. For example, a tool may enable you to easily build a beautiful, stacked bar chart by just pointing it to your data and dragging and dropping specific variables. However, if you want to customize the labels in the legend, change the display of hover values, or add click-through events when clicking on the chart, it simply may not be possible. Choosing a tool that meets your needs without exceeding the amount of time you are willing to dedicate is critical to your success. There are many online training resources available such as LinkedIn Learning, Coursera, and Udemy as well as many books on developing data visualizations and using specific tools.

### Security / HIPAA

As health IT professionals we must take patient privacy and security seriously, which eliminates many data visualization tools from consideration. Cloud-hosted tools are numerous and growing in popularity. However, we cannot publish sensitive data to a cloud provider such as Google Charts or Tableau Public, without consulting with legal counsel. Doing so is usually only possible with a Business Associate Agreement (BAA) in which the cloud provider agrees to accept responsibility for keeping the data secure and private specifically for your organization. This limits us to locally hosted (on our Desktop) or organization hosted (company server) solutions. Luckily, there are many great options to choose from. Tableau Desktop, Microsoft Power BI, SAS Visual Analytics, and Excel, just to name a few, can all be installed on your desktop with a paid license and/or subscription. Your organization may choose to provide one of these solutions on their servers, which is also a great, secure, option. No matter what, when working with sensitive data on our personal computers, it is important to keep in mind that we are taking on a much higher level of security responsibility and vulnerability to cyber-attacks. Our computers need extra protection, and we need additional training. User behavior is the number one reason why sensitive data are compromised. Consult with your IT department and let them know that you plan to store sensitive data on your computer prior to doing so. If you plan to develop on a laptop or portable device, we suggest that you implement “full disk encryption.” With full disk encryption enabled, if your laptop is lost or stolen, the contents of your hard drive remain secure. We will not go into detail on how to set this up, so contact your IT department to learn more. When you are finished developing a data visualization, the next step is to share it. Be aware that some solutions make the underlying data accessible to the viewer. For example, if you share a Tableau Workbook, even if data being presented are aggregate and de-identified, the data source containing row level (patient level?) data is accessible. We will go into more detail on this and other considerations such as small cell sizes later.

### Costs

The costs of software licensing can vary wildly depending on the specific situation. For example, if the organization currently supports an Office 365 environment, Power BI is currently available as part of the Office 365 Enterprise E5 version (https://docs.microsoft.com/en-us/office365/servicedescriptions/power-bi-service-description). If the organization does not have E5, it is available as a stand-alone cloud-based software as a service (SaaS). If the organization currently contracts with SAS, SAS VA may already be available (SAS VA is included with SAS Viya). The same goes for Tableau Enterprise. Your organization may already be using one of these solutions for internal reporting, which may provide the most cost-effective path for your project. Tableau Desktop is free if the intent is to publish to Tableau Public, however, given the sensitivity of the Health IT Advisor’s work, this is typically not an option. Tableau does not allow the user to save any data locally in the free version, only to the Tableau public server. Most likely clinic-based reporting will need to be hosted on a solution paid for by the organization.

Please note, if hosted with a 3^rd^ party vendor such as a cloud-based hosting solution, most organizations require a BAA to set expectations for liability associated with HIPAA.

Once you have identified which solutions, if any, most closely align with your organization’s existing infrastructure, you will need to determine if you can handle the work or if you need to identify a developer. Most larger organizations have in-house business/data analytics teams that can help. This would likely be the most cost-effective route. If your organization does not provide this service, there are plenty of 3^rd^ party contractors available. Just do a search on the most popular job community websites such as (e.g., Linked-In, Indeed, or Upwork) for your intended solution. For example, “Tableau Developer” or “Power-BI developer.” At the time of this writing, you can expect to pay between $100-$175 per hour for an experienced developer that has prior experience designing visualizations with health data.

### Keep it Simple

In general, many of these solutions provide default color schemes and default visualization options such as traditional/stacked/grouped bar charts, (multiple) line graphs, and pre-defined axis title and tooltip locations. If possible, stick with the defaults as this will simplify development and allow the developer to focus on what matters most. Do not underestimate the amount of effort it takes to customize these options. Ask yourself, is this customization adding significant value to the visualization? Do not be afraid to frequently ask the developer for their opinion on the most cost-effective solution. Tell them upfront that you are interested in simplicity and to please let you know if they feel that anything you ask is disproportionately time-consuming with the return on investment (ROI).

Under the following examples, we will provide the estimated amount of effort that was required to create each visualization in terms of hours. Please refer to Section 2 of this handbook for the various methods and considerations related to extracting data, which plays a big part in the amount of required and cost.

## Identifying the Message, Intended Purpose, and Minimum Viable Product (MVP)

Before identifying data, thinking about data structure, or even contracting with a developer, you should determine the intended purpose of the project. Here are a few examples:

- Quality of care improvement
- Process/Workflow efficiency
- Billing and or administration
- Data quality checks

One suggestion is to form a committee of stakeholders and conduct brainstorming sessions. What are the needs? Where are the gaps in the existing reports? develop a matrix of intended audiences and feature ideas. The intersection of the columns and rows should be a planned use case for how the intended audience will use that feature. See example in Exhibit 61.

Exhibit 61 Matrix of Intended Audiences

| Physician | Health IT Advisor / Practice Manager | Administrator
Feature #1 | Physician use case for feature #1
Feature #2 | | Practice Manager use case for feature #2
Feature #3 | | | Administrator use case for feature #3

This tool will help you home in on which features are highest priority and part of the Minimum Viable Product (MVP) vs. those that are nice-to-haves. Having this knowledge before approaching development will save time, money, and produce a higher quality solution.

## Wireframes and Mockups

Once you know the features that you plan to include in the MVP, it is time to start working on your design. Because data visualization ideas are hard to communicate using verbal language, it is sometimes more effective to use visual language such as with a wireframe. A wireframe is a representation of an idea in its simplest form. It is much easier to iterate on a design in its simplest form, and therefore time and money will not be wasted on implementation before the design has been communicated and thoroughly discussed. A wireframe could be a simple drawing on a whiteboard, which can then be shared by taking a photo with your phone. The most important thing to remember when wireframing is to keep it simple and only draw what you need to get your idea across. For example, consider which option shown in Exhibit 62 is more effective for conveying the information:

Exhibit 62 Wireframe Data Presentation Examples

Wireframe examples as explained in text above. Case vs Control Vaccination data in verticle and horizontal bar charts and in a line graph.

It would be hard to describe these with just words in a meeting or a phone call. The wireframes are able to communicate so much more in less time. The answer to “which is more effective?” is often subjective and will require discussion and possibly some us ability testing on actual stakeholders. The good news is that with a wireframe, you can quickly make changes, possibly in real time. In addition to discussing pros and cons for each visualization, be sure to discuss titles, axis labels, choice of colors, in-chart data labels, legends, interactivity (hover tooltips), custom filters or user controls, and supporting content/documentation.

Once you have consensus on the most effective visualization(s) and design options, you have 2 options. You could dive straight into implementation, or you could build a mockup. A mockup mimics what the final product will look like. This includes color choices, layout of multiple components, supporting content, etc. This could be beneficial if you are building a dashboard or something more comprehensive than a single visualization. Unfortunately creating a mockup of a data visualization is difficult to do without actually building one. One method is to use a tool such as Tableau Desktop to quickly build your chosen visualization using dummy data. This serves two purposes. For one, it allows you to mockup what your final product will look like. And two, it allows you to start thinking about your data structure requirements for the chosen visualization and if your raw data will work for what you want to do. If you are building a dashboard, you can take screenshots of your dummy visualization and place them in a word document or design tool such as Visio (windows) or Omnigraffle (mac) and lay out the viz with supporting content such as an overview, FAQs, how-to instructions, and frequently used terms (see example dashboard below in Exhibit 63).

## Preparing your Data for Visualization

Depending on your chosen visualization and tool, preparing your data and developing the viz may be a circular process. First you will want to use dummy data to create a visualization in your chosen tool. For example, do not spend time feeding in raw data and calculating aggregate results, only to change your mind on the entire visualization later. With your raw dataset in mind, build a sample dataset in excel by hand with minimal expected aggregate results. This will give you data to play with different visualization options and it will be easy to quickly change data structures.

Exhibit 63 Example Dashboard

Graphic included with permission from the Gillings Global School of Public Health COVID-19 Dashboard at the University of North Carolina at Chapel Hill: https://gillingscovid19.unc.edu/visualization/long-term-care-facilities [121]

Screenshot of a sample dashboard showing county data for the state of North Carolina.

Tableau expects the data structure to look like the table included in Exhibit 64.

Exhibit 64 Example Data Structure for Tableau

date | county | state | Population | cases10k | deaths10k | cases_rolling7 | deaths_rolling7 day
12/15/20 | county a | NC | 174055 | 21.14 | 1.21 | 0.71 | 0
12/15/20 | county b | NC | 38755 | 9.81 | 0 | 0.41 | 0
12/15/20 | county c | NC | 11510 | 15.64 | 0 | 0.62 | 0
12/16/20 | county a | NC | 25289 | 26.1 | 0.4 | 0.28 | 0.06
12/16/20 | county b | NC | 28150 | 12.79 | 0 | 0.1 | 0
12/16/20 | county c | NC | 18035 | 1.11 | 0 | 0 | 0
12/17/20 | county a | NC | 47490 | 7.58 | 0 | 0.12 | 0
12/17/20 | county b | NC | 19601 | 63.77 | 2.04 | 0.73 | 0
12/17/20 | county c | NC | 34444 | 30.19 | 0.58 | 0.41 | 0

Because the visualization allows the user to select multiple measures in the first drop-down, we need a column for each measure. The viz also allows the user to drag a slider to select the date they would like to view COVID-19 data for. Without the date selector, you would only need one row per county. With the date selector, you must have one row per county per date. As you can see, adding features to your data viz can drastically change the data structure required.

After you have your data structure with dummy data and your visualization looking the way you want it, now you should have some idea of what processing will be needed in order to manipulate your raw data into the expected data structure required for the viz. For this handbook, we will not go into all the different methods of processing and transforming data. However, if you plan to publish your visualization to Tableau Public, it can be to your advantage to handle data processing outside of Tableau. Data processing within Tableau can drastically slow your visualization, especially if you have a lot of data. If you plan to export a PDF, JPG, or some other static form of your visualization, it will not matter if you do all your data processing in Tableau or not.

If this report will be published to a website, you will most certainly want to think about automating the data refresh. This plays a large role in your design. Generally, you will want to avoid any manual/human process because humans cannot be automated. For this handbook, we will not go into all the methods of automation which may require shell scripting, Python or programming languages, and possibly support from systems administration. One semi-automated method worth mentioning though is with Tableau Public. If you have decided to use Tableau Public, and your data can be made completely public, Tableau public can read from a Google Sheet. This is handy because there are many ways to update a google sheet. You can sync the sheet to your desktop and have a semi-automated process on your desktop that updates the sheet. You can share the sheet with staff and ask them to update the sheet, which will in-turn update the Tableau. This is a nifty trick to have in your back pocket, which may just meet your requirements without involving a programmer or system admin.

## Data Quality and Missingness

Once you have your raw data loaded into your data visualization, now is the time to look for anomalies. Spikes in line graph that would otherwise be a smooth and continuous line, may indicate missing or erroneous data. The same goes for expected bars missing from a bar chart, or other anomalies. Data visualizations are a great way to check for data quality. Also, missingness in data may not be an error. Missingness can be an important story in your data that you will want to highlight in your supporting content. For example, data suppression due to HIPAA concerns with respect to protecting the privacy of patients, can create missingness. Most organizations will implement a minimum small cell count. This is something you will want to explain in a sidebar and/or FAQ.

## Developing and Sharing Visualizations

It is a good idea to start designing your visualization on paper or using tools such Visio (for windows) or Omnigraffle (for Mac) first, before jumping straight into development. This can save you time and money overall because it is much easier to iterate on a design than it is to develop the solution. There are some exceptions to this though. If your intended solution is a very simple data viz such as a bar chart or a line graph, then many of these tools will allow you to explore and “play” with various visualizations. For example, some tools will allow you to load your data into an X and Y axis and then browse visualizations that it suggests based on your data. Be very careful with this feature though as it is easy to make assumptions in what it is presenting you that are simply not factual. It can be a quick turn-around solution if your data are simple, verifiable, and it fits your needs.

The purpose of this handbook is not to be an all-encompassing tutorial on every possible data visualization. For a large gallery of visualizations and a great place to find inspiration, visit the D3 gallery (https://observablehq.com/@d3/gallery). D3 is a JavaScript library that is not for the novice, but if you are working with a developer or simply want to find ideas you can implement, it is a nice place to browse.

## Considerations Around Diversity, Equity, and Inclusion

One important step that many organizations miss is pilot your solution before publishing. Having stakeholders from your intended audience review and provide feedback can uncover gaps in your planned design. It can also prevent embarrassing mistakes or oversights from being released to a wider audience and minimize risk or possible damage. For example, the decision to list white males first in every data visualization may have just been an oversight but could send a completely different message than you intend. The stakeholder committee could simply be the original committee you initially engaged with, but do not overlook the opportunity at this step to identify members of the broader community.

This would be a good time to identify actual users and get their feedback. One exercise that we found particularly useful was to organize is light-weight usability study. Here are the steps we followed:

- Identify actual users/stakeholders from your intended audiences who will agree to participate in a study where they will be recorded as they attempt to complete various tasks using your new solution
- Schedule meetings with each stakeholder to meet with an interviewer on a video conferencing solution (Zoom, MS Teams, etc.) to discuss the format, content, presentation, and aesthetics of the visualization.

## Conclusion

As discussed in this Appendix (also see Section 8), designing visualizations to present quality data to diverse stakeholders is an art and a science. Below are some examples of different visualization types that may be of use.

## Example 1: Line Graphs / Run Charts

Generally, in order to track performance over time, it is useful to display quality and performance measures graphed as a function of time, a display called a run chart. [122]

The run chart below is a generic example. In a run chart, it is often helpful to show all patients seen during a given unit of time (such as a month), to create visual evidence of the effect of various improvement interventions. In this example, the time points of the process change activities are indicated by the call-outs boxes.

Exhibit 65 Example Run Chart

Sample Run Chart - line graph shows three process changes over Time.

## Example 2: Bar and Pie Charts

Exhibit 66 CQM Performance Data Presented as a Bar Chart

Bar chart example

Exhibit 67 CQM Performance Data Presented as a Pie Chart

CQM Performance Data shown in three sample pie charts: CMS115A, CMS155B, and CMS155C.

## Example 3: EHR or Population Health Dashboards

A dashboard pulls together multiple data visualizations into a single view for the user to see at a glance related metrics. For example, the following dashboard shows multiple measures that are related. It is important to know that dashboards can get very busy and detract from their intended purpose or worse, confuse the user into thinking something is true that is not. In the below example, you can see that the developer chose to use color and text formatting very sparingly because there is a lot of information on the screen. The user’s eye is drawn to the changing colors and triangles, which is the intent of the design. All of the information in view is related. Additional detail and other views are separated into tabs across the top.

Exhibit 68 Example Dashboard [67]

Graphic included with permission from The American Board of Family Medicine.

Screenshot of a sample dashboard as described in text above.

## Example 4: Complex Time Series

The next example is a very complex data visualization that requires a lot of explanation. This is actually part of a larger COVID-19 dashboard, but we chose to separate each visualization on its own page in order to provide enough space and supporting content around each visualization to address questions a user may have. Users of this dashboard ranged from the general public to county administrators, to state legislatures, to research scientists. In addition to the visualization, each of the following components were considered when creating this dashboard page: Title, Overview, frequently asked questions (FAQ), How to Use, and Terms Used. Each visualization on the dashboard had a similar page with all of the same components.

Exhibit 69 Complex Time Series Visualization Graphic

Graphic included with permission from the Cecil G. Sheps Center for Health Services Research for the Gillings Global School of Public Health at the University of North Carolina at Chapel Hill.

Sample line graph shows percentage of cumulative case in North Carolina by race.