# Appendix C Example of Data Planning for Quality Improvement

A careful assessment of practice data capacity, both broadly and specific to the needs of a project, is a crucial initial step. This includes determining the specific EHR version and other data systems in use, the ability of the practice to generate key measures and data, the ability of the practice to produce usable, clean, and accurate data, and the use of data in QI and other practice management activities.

This appendix illustrates the steps a Health IT Advisor might take to iteratively assess and support a practice as they implement a new measure. The illustration uses Screening for Unhealthy Alcohol Use, but the process is applicable for any measure.

Measure: Number of unique patients 18 years of age and over who have been screened for unhealthy alcohol use

First the Health IT Advisor needs to meet with the practice’s QI and IT reporting staff to discuss the meaning of the measure, and to confirm that the report should be run/built for all unique patients who are 18 and over. This group will be the denominator for the measure. If a patient is screened for unhealthy alcohol use during the reporting period, then they would be included in the numerator.

Next the Health IT Advisor needs to consider if there are variables that are missing from this definition that the QI and IT staff members might need to run or build this report. In this case we would want to define the time period for this measure. In this example we are going to select a 3-month time period that repeats on calendar quarters, like this: Jan – Mar, Apr – Jun, Jul – Sep, Oct – Dec.

Once everyone has agreed on the definition of the measure, the QI and IT staff members will need to determine if their EHR or Quality Registry are already able to run the measure. If the measure is available, then the practice will want to run the report and see if a numerator and denominator are being populated accurately. If the measure is not available in the EHR or Quality Registry, then the Health IT Advisor will work with the practice to determine what steps will be needed to build the report. If the report needs to be built, the Health IT Advisor should work with the practice and their IT/billing team to determine a realistic timeline in which to do this.

Once the measure is available, the Health IT Advisor and practice staff should review to ensure that the numerator and denominator look accurate. It is critical to have a staff member who is familiar with patient volumes look at these numbers to confirm that the numbers are reasonable in terms of what would be expected for the practice.

To ensure that the denominator (i.e., all unique patients 18 and over, seen during the specific timeframe) looks reasonable, review the following:

- Is the denominator accounting for all providers in the practice, is it counting all unique patients or all patient visits during that timeframe?
- Does the timeframe seem reasonable? For example, does it look like it includes all unique patients during a 3-month period or is it pulling all unique patients in a year?

Next you want to focus on the numerator (i.e., all patients screened for unhealthy alcohol use):

- Are you getting zero for your numerator? The practice might not have any providers using the unhealthy alcohol use screening tool, or providers may not be documenting the unhealthy alcohol use screening in the right place within the EHR.
- Is the numerator lower than expected? If so, review which providers are using the screening tool and look at their workflows. The Health IT Advisor should then talk to the practice staff about next steps based on the outcome of this review. Staff training may be needed to create consistency across the practice and improve performance on the measure.

Once the practice has a numerator and denominator they can trust, the Health IT Advisor should work with the practice to create or provide a feedback report. This feedback report shows how the practice is doing over time on the measure. It could also show how the practice is doing on the measure in comparison to other practices in the same system or it could show how specific providers in a clinic are performing in comparison to each other.

It is essential that the Health IT Advisor work closely with the practice’s QI staff so they are developing something the practice will use. Ideally the practice’s health IT staff should share these feedback reports with the clinic staff on a regular basis so everyone can see the progress on this measure.