# Appendix B Health IT Crosswalk for the Ten Building Blocks for Primary Care

The “10 Building Blocks for Primary care” is a useful framework for identifying the areas where an EHR can help support practice transformation.[119] Below, we review the implications for leveraging EHR technology for each of the 10 building blocks shown in Exhibit 59.

Exhibit 59 The Ten Building Blocks of High Performing Primary Care [119]

Graphic included with permission. © 2014 Annals of Family Medicine, Inc.

This graphic of the ten building blocks of high performing primary care shows four squares across the bottom, then three squares on top of that, two on top of that, and one on the very top. The numbering starts at the bottom and works up the graphic with each box containing a number and label: 1) Engaged leadership; 2) Data-driven improvement; 3) Empanelment; 4) Team-based care; 5) Patient-team partnership; 6) Population management; 7) Continuity of care; 8) Prompt access to care; 9) Comprehensiveness and care coordination; 10) Template of the future.

## One: Engaged Leadership

Health IT Advisors will often provide performance data to clinic leadership to help them prioritize QI projects and assess progress and outcomes. The EHR is often the best source of these data, although there are alternatives (see Section 4).

## Two: Data-driven Improvement

The Use Cases in Section 3 of the handbook show how demographic, clinical, administrative, and financial data managed by an EHR can support QI in two major ways: as a source of data and as a platform for delivering interventions.

## Three: Empanelment

Empanelment is the explicit assignment of individual patients to a provider or care team to create a cohort, or patient panel. EHRs often include this information by capturing demographic fields (primary care physician; care team) that can be used to attribute performance and accountability to organizations, groups, or individual clinicians.

## Four: Team Based Care

The EHR is an essential tool not only to support, but to facilitate, team-based care. For example, the use of an EHR to communicate and coordinate between healthcare providers increasingly includes roles outside of the traditional provider/medical assistant dyad, including care coordinators, health navigators, behavioral health clinicians, social and community service providers.

## Five: Patient-Team Partnership

The EHR is becoming central to establishing and maintaining patient-team relationships. An EHR portal provides patients with a technology platform that allows access to their medical record, secure messaging, delivery of test results, tailored educational materials, preventive care reminders, and the option to collect and incorporate questionnaires and biometric data.

## Six: Population Management

The EHR can be used to identify, assess, and monitor populations (or cohorts) defined by specific characteristics, needs, or health conditions. EHR or third-party population health tools can identify and manage cohorts based on demographics, medical or social conditions and risk factors, gaps in preventative care delivery, test results, insurance coverage by a specific payer, empanelment and payer attribution, and other criteria for targeting and measuring QI.

## Seven: Continuity of Care

EHRs, aided by Health Information Exchanges, are getting better at exchanging data. While data siloes (isolated islands of patient data) still exist, it is now possible for EHR users to see much of a patient’s medical data regardless of the provider and EHR vendor they use. Examples include immediate notification of acute care episodes, delivery of structured electronic discharge summaries, and adding two-way communication between providers for referrals and transitions of care.

## Eight: Prompt Access to Care

The use EHRs for telehealth and asynchronous care delivery expanded rapidly during the COVID pandemic and may permanently shift (at least some) medical care away from traditional office visits, thus increasing prompt access to care.

## Nine: Comprehensiveness and Care Coordination

The EHR serves a critical role in coordinating the care provided both in, and outside, of the clinic. Examples include sharing clinical information, communicating within the team, and exchanging information to support transitions of care (hospital admissions, transfer to long-term care).

## Ten: Template of the Future

The top building block holds space for emerging EHR features and capabilities and will create new opportunities to leverage the EHR and other health IT to transform healthcare quality. Health IT Advisors can look forward to:

- Advances in how diverse EHRs can exchange structured electronic data
- New options for extracting data for QI using FHIR APIs
- Incorporation of patient-generated data from apps, portals, and devices
- Use of natural language processing (NLP) and artificial intelligence tools to enhance clinical decision support
- Improved capture of structured data for health related behavioral and social needs.

The table below is a comprehensive summary of how each of the Ten Building Blocks can leverage EHRs as a tool for transformation.

Exhibit 60 How the Ten Building Blocks Can Leverage EHRs[119, 120]

Building Block | Topic/Process | EHR Functionality
Engaged Leadership | Strategy | Accurate and robust reporting capabilities
Engaged Leadership | Trust/Buy-in | Accurate and robust reporting capabilities
Engaged Leadership | Resources | Accurate and robust reporting capabilities
Engaged Leadership | Data integral to strategy/improvement | Accurate and robust reporting capabilities
Engaged Leadership | Financial Management/Fiscal Health | Accurate and robust reporting capabilities
Engaged Leadership | Financial reports - PM | Accurate and robust reporting capabilities
Engaged Leadership | Revenue cycle management | Accurate and robust reporting capabilities
Engaged Leadership | Normalized and integrated data | Accurate and robust reporting capabilities
Engaged Leadership | Performance reports | Accurate and robust reporting capabilities
Engaged Leadership | Risk sharing analytics | Accurate and robust reporting capabilities
Data Driven Improvement | Quality Monitoring and Improvement
Data Driven Improvement | Data for reporting | Allows for workflows that use discrete data
Data Driven Improvement | Data for decisions and improvement | Accurate and robust reporting for CQMs, clinical process and effectiveness measures
Data Driven Improvement | Internal data sharing | Reports can be built, managed, and viewed by care team members
Data Driven Improvement | External data sharing | Reports and datasets are exportable, interoperable with external partners; APIs
Data Driven Improvement | Robust Clinical Information Systems
Data Driven Improvement | Appropriate applications - EHR | Medication management, scheduling, referral management, reporting, CDS, computerized provider order entry (CPOE)
Data Driven Improvement | Habitual data validity review -audit | Ability to audit data for integrity, validity, and completeness
Data Driven Improvement | Standardized, Evidence Based Guidelines
Data Driven Improvement | Standing orders | Order sets
Data Driven Improvement | CDS | CDS
Empanelment | Management of Patient Panels
Empanelment | Assignation of patients to a particular clinician | Comprehensive assignment and tracking of patient/caregiver relationships
Empanelment | Workload balancing across care team | Identify high risk patients; dynamic scheduling
Team Based Care | Patient Centered care team
Team Based Care | Data supports action | Populate care plan
Team Based Care | Clinician/Care Team Engagement
Team Based Care | Access to standardized forms | Make forms/care plan/encounter summary accessible to the entire care team
Team Based Care | Communication tools for use with colleagues | Direct Secure Messaging
Team Based Care | Usability of clinical information technology | Produces lists of problems, diagnoses, allergies, interventions (labs, tests)
Patient-Team Partnership | Excellent Experience of Care
Patient-Team Partnership | Patient satisfaction | Patient access to manage information: results, schedule, encounter summary via patient portal and messaging
Patient-Team Partnership | Patient and Caregiver Relationship Management
Patient-Team Partnership | Patient education | Patient access to relevant, reliable, culturally sensitive, and linguistically appropriate online educational resources;
Patient-Team Partnership | Patient communication | Secure messaging; Patient Portal
Patient-Team Partnership | Patient engagement/self-management | Incorporates patient generated data and/or data from other caregivers; APIs to connect to a patient’s preferred health record and other provider portals
Patient-Team Partnership | Patient Empowerment
Patient-Team Partnership | Patients understand their condition - SDOH, assessments | Shared decision-making tools, assessments; ability to record patient preferences
Population Management | Cohort Management
Population Management | Assessment of the health of the organization’s population of patients | Accurate and Robust Analytics for tracked Clinical Topics (e.g., Diabetes, cardiovascular health
Population Management | Identify cohorts of patients/population | Extract data from multiple sources: claims, practice management and clinical systems, health risk assessments; Identify patients by demographic, diagnosis, medication, lab result or problems; identify high risk patients; maintain lists of cohort(s)
Population Management | Monitor individual patients | Integrate patient goals, interventions in a sharable and reportable format; patient monitoring; flag and communicate needed interventions as appropriate; trending
Population Management | Evidence based medicine (EBM) CDS | EBM alerts/prompts via CDS: drug-drug formulary interactions, drug formulary checks, drug-allergy interactions; customizable order sets
Population Management | Interventions | CPOE for medications, labs& radiology tests; Appropriate use alerts
Population Management | Follow up | Identify and alert for missing care gaps (e.g., missed appt); timely lab/test results, review, communication with patients, schedule interventions; update care plan
Population Management | Monitor cohort | Calculate CQMs; present results from entire patient population; provide benchmarks and progress over time
Continuity of Care | Cohesive Patient Care
Continuity of Care | Prevention of Fragmented Care | Incorporates information from each care team member; missed intervention or appointment alerts; supports care coordination workflows and data entry
Continuity of Care | Measurement of desired coordination outcomes | Accurate and robust reporting for CQMs, clinical process and effectiveness measures
Prompt Access to Care | Access
Prompt Access to Care | After hours communication- pt. portal, messaging | Patient portal
Prompt Access to Care | Access-telehealth | Telehealth
Prompt Access to Care | Access- Scheduling | Ability to access schedule and suggest
Comprehensiveness and care Coordination | Referral Management
Comprehensiveness and care Coordination | Referral tracking and mgmt. process | Referral Management Process
Comprehensiveness and care Coordination | Care Coordination
Comprehensiveness and care Coordination | Insurance eligibility checks | Auto-insurance eligibility checks
Comprehensiveness and care Coordination | Share data during transfer of care | Populate care plan and encounter summary
Comprehensiveness and care Coordination | Manage referrals | Referral management system
Comprehensiveness and care Coordination | Medication management and reconciliation | e-prescribing, Access to Medication lists (internal, external), auto-duplication alert, identify active medications, maintain history, evidence prescription was filled
Comprehensiveness and care Coordination | Clinical information reconciliation | Access to lists (external, internal) of problems, diagnoses, allergies, interventions (labs, tests); reconciliation signoff and reporting
Template of the Future | Continuous Improvement
Template of the Future | Evaluation and incorporation of new technical tools | APIs
Template of the Future | Incorporating and contributing to EBM/Learning Health System | Bidirectional HIE
Template of the Future | Advanced analytics | Risk Stratification; predictive modeling